# Isoprene

CAS No. 78-79-5

Reasonably anticipated to be a human carcinogen

First listed in the Ninth Report on Carcinogens (2000)

Figure 1

Chemical Structure of Isoprene

## Carcinogenicity

Isoprene is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Exposure to isoprene by inhalation caused tumors at several different tissue sites in mice and rats. In mice of both sexes, isoprene caused blood-vessel cancer (hemangiosarcoma) and benign or malignant tumors of the Harderian gland (adenoma or carcinoma) and the lung (alveolar/bronchiolar adenoma or carcinoma). In male mice, it also caused cancer of the hematopoietic system (histiocytic sarcoma) and benign or malignant tumors of the liver (hepatocellular adenoma or carcinoma) and forestomach (squamous-cell papilloma or carcinoma). In rats of both sexes, isoprene caused benign or malignant tumors of the mammary gland (fibroadenoma or carcinoma) and kidney (renal-cell adenoma or carcinoma). In male rats, it also caused benign tumors of the testis (adenoma) (Melnick and Sills 2001; NTP 1995; Placke et al. 1996).

### Studies on Mechanisms of Carcinogenesis

Isoprene is the 2-methyl analogue of 1,3-butadiene, an industrial chemical that has been identified as a carcinogen in humans and experimental animals (Gervasi et al. 1985; NTP 1999a; 1999b). The isoprene analogue isopentenyl pyrophosphate is a building block of cholesterol synthesis, and levels of exhaled isoprene correlate with cholesterol synthesis (IARC 1994; Rieder et al. 2001). Isoprene and butadiene are metabolized to monoepoxide and diepoxide intermediates by liver microsomal cytochrome P450-dependent monooxygenases from several species, including humans (Gervasi et al. 1985; IARC 1994; NTP 1999a). These intermediates may be detoxified by hydrolysis (catalyzed by epoxide hydrolase) or conjugation with glutathione (catalyzed by glutathione-S-transferase).

The diepoxide intermediates of isoprene and butadiene caused mutations in Salmonella typhimurium, whereas the monoepoxides of isoprene and parent compounds did not. In mammalian cells in in vitro, isoprene did not cause sister chromatid exchange, chromosomal aberrations, or micronucleus formation (NTP 1995; 1999a), but did cause DNA damage in human peripheral-blood mononuclear cells and human leukemia cells when incubated with microsomal enzymes (Fabiani et al. 2007). In mice exposed in vivo, isoprene and 1,3-butadiene caused sister chromatid exchange in bone-marrow cells and micronucleus formation in peripheral-blood erythrocytes (Tice 1988; Tice et al. 1988). Sites at which both isoprene and butadiene caused tumors in rodents include the liver, lung, Harderian gland, forestomach, hematopoietic tissue, and circulatory system in mice and the mammary gland, kidney, and testis in rats (NTP 1999a; 1999b). Harderian-gland tumors caused by isoprene in mice had a high frequency of unique mutations of the K-ras protooncogene (A to T transversions at codon 61) (Hong et al. 1997).

There is no evidence to suggest that mechanisms by which isoprene causes tumors in experimental animals would not also operate in humans.

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to isoprene.

## Properties

Isoprene is structurally similar to 1,3-butadiene and exists as a colorless, volatile liquid at room temperature (NTP 1999a). It occurs frequently in nature and is emitted to the environment by plants and trees. Isoprene is practically insoluble in water, but is soluble in ethanol, diethyl ether, benzene, and acetone. It is stable under normal conditions, but it is very flammable and will polymerize vigorously or decompose with abrupt changes in temperature or pressure (Akron 2009; IARC 1994). Physical and chemical properties of isoprene are listed in Table 1.

Table 1 Properties of Isoprene

Property | Information
Molecular weight | 68.1
Specific gravity | 0.681 at 20°C/4°C
Melting point | −145.95°C
Boiling point | 34.07°C at 760 mm Hg
Log K_ow_ | 2.42
Water solubility | 0.642 g/L at 25°C
Vapor pressure | 550 mm Hg at 25°C
Vapor density relative to air | 2.4

Source: HSDB (2009).

## Use

The majority of isoprene produced commercially is used to make synthetic rubber (cis-polyisoprene), most of which is used to produce vehicle tires. The second- and third-largest uses are in the production of styrene-isoprene-styrene block polymers and butyl rubber (isobutene-isoprene copolymer) (IARC 1994).

## Production

Isoprene is recovered as a by-product of thermal cracking of naphtha or gas oil from C5 streams (IARC 1994; NTP 1999a). The isoprene yield is about 2% to 5% of the ethylene yield. U.S. demand for isoprene grew 6.5% annually from 1985 to 1992 (NTP 1999a). In 1994, isoprene production in the United States was about 619 million pounds, almost 29% more than in 1992. Estimated isoprene production capacity for eight facilities was 598 million pounds in 1996, based on estimates of isoprene content of product stream available from ethylene production via heavy liquids. In 2009, isoprene was produced by 22 manufacturers worldwide, including 12 U.S. producers (SRI 2009), and was available from 23 suppliers, including 12 U.S. suppliers (ChemSources 2009). U.S. imports of isoprene (purity ≥ 95% by weight) increased from zero in 1989 to a peak of 144 million pounds in 2003. Imports declined to 19.6 million pounds in 2004, the lowest level since 1992, but remained near 32 million pounds from 2005 through 2008. During this period, U.S. exports of isoprene ranged from 7.9 million to 39.6 million pounds (in 2006) (USITC 2009). Reports filed from 1986 to 2002 under the U.S. Environmental Protection Agency’s Toxic Substances Control Act Inventory Update Rule indicated that U.S. production plus imports of isoprene totaled 100 million to 500 million pounds (EPA 2004).

## Exposure

Isoprene is formed endogenously in humans at a rate of 0.15 μmol/kg of body weight per hour, equivalent to approximately 2 to 4 mg/kg per day (Taalman 1996), and is the major hydrocarbon in human breath (accounting for up to 70% of exhaled hydrocarbons) (Gelmont et al. 1981). Concentrations in human blood range from 1.0 to 4.8 μg/L (Cailleux et al. 1992). Isoprene is produced at higher rates in males than females. The rate of isoprene production increases with age up to the age of 29 (Lechner et al. 2006); it is lower in young children than adults by a factor of about 2.4 (Taucher et al. 1997). In a study of 30 adult volunteers, the mean isoprene concentration measured in alveolar breath was 118 ppb, with a range of 0 to 474 ppb (Turner et al. 2006). After 20 to 30 minutes of exercise, isoprene concentration in exhaled air decreased to a range of 0 to 40 ppb (Senthilmohan et al. 2000). Smoking one cigarette increased the concentration of isoprene in exhaled air by 70% (Senthilmohan et al. 2001). Isoprene is also produced endogenously by other animals. Production rates reported for rats and mice were 1.9 and 0.4 μmol/kg of body weight per hour, respectively (Peter et al. 1987).

Foods of plant origin would be expected to be a source of daily exposure to isoprene, since isoprene is emitted by agricultural crops and is the basic structural unit in countless natural products found in foods, such as terpenes and vitamins A and K (NTP 1999a). Isoprene has been reported to occur in the essential oil of oranges, the fruit of hops, carrot roots, and roasted coffee (NTP 1999a; Taalman 1996).

Isoprene is emitted from plants and trees and is present in the general environment at low concentrations (Taalman 1996). Isoprene emissions from many types of plants have been estimated under various climatic conditions, to evaluate their importance in global climate change (Mayrhofer et al. 2004; Moukhtar et al. 2006; Parra et al. 2004; Pegoraro et al. 2005; Sasaki et al. 2005; Schnitzler et al. 2004; Schnitzler et al. 2005; Sharkey 2005; Simon et al. 2006; Tambunan et al. 2006). Annual global isoprene emissions, estimated at 175 billion to 503 billion kilograms (386 billion to 1,109 billion pounds), account for an estimated 57% of total global natural volatile organic compound emissions (Guenther et al. 1995). The average biogenic emission rate factor for isoprene in U.S. woodlands is 3 mg/m^2^ per hour (compared with 5.1 mg/m^2^ for total volatile organic compounds) (Guenther et al. 1994). Isoprene concentrations in biogenic emissions range from 8% to 91% of total volatile organic compounds, averaging 58%. Because isoprene biosynthesis is associated with photosynthesis, isoprene emissions are negligible at night (Lamb et al. 1993). Because isoprene is emitted primarily by deciduous trees, emissions are seasonal, being highest in the summer and lowest in the winter (Fuentes and Wang 1999; Guenther et al. 1994). The south central and southeastern areas of the United States have the highest biogenic emissions (Guenther et al. 1994; Lamb et al. 1993). The half-life of atmospheric isoprene has been estimated at 0.5 hours by reaction with nitric oxide, 4 hours by reaction with hydroxyl radicals, and 19 hours by reaction with ozone (HSDB 2009).

Anthropogenic sources of isoprene in the atmosphere include ethylene production by cracking naphtha, wood pulping, oil fires, wood-burning stoves and fireplaces, other biomass combustion, tobacco smoking (200 to 400 μg per cigarette), gasoline, and exhaust from turbines and automobiles (Adam et al. 2006; HSDB 2009). Isoprene has been measured as one of the volatile organic compounds in the ambient air in regions with industrial pollution, and in urban, residential, and rural areas as an indicator of the potential for ozone formation. Thus, isoprene is a key indicator for regional air quality, as well as being a component the global carbon cycle (Borbon et al. 2004; Guo et al. 2004; Hellén et al. 2006; Kuster et al. 2004; Warneke et al. 2005).

The reported concentration of isoprene in U.S. ambient air ranges from 1 to 21 parts per billion carbon and generally is less than 10 ppbC. Isoprene accounts for less than 10% of non-methane hydrocarbons in ambient air. Biogenic hydrocarbons may contribute more to total atmospheric hydrocarbons under stagnant atmospheric conditions (Altschuller 1983; Hagerman et al. 1997). The major sources of isoprene in ambient air appear to be biogenic emissions at rural sites and vehicular emissions in urban areas (Borbon et al. 2001; So and Wang 2004). Where the source is primarily biogenic, the isoprene concentration slowly increases during the day, reaching a peak in the middle of the day, when photosynthesis is greatest. Where vehicular emissions are the primary source, the isoprene concentration peaks during the morning and evening rush hours and is low in the middle of the day (Borbon et al. 2002). One study concluded that in summer, at least 80% of the isoprene at a rural site was due to biogenic emissions, but that in winter, more than 90% of residual isoprene was from urban air-mass mixing (Borbon et al. 2004). Where industrial emissions are the primary source of isoprene, the concentration may peak at night, or there may be no peak at all (Chiang et al. 2007; Zhao et al. 2004).

The primary source of isoprene in indoor air is environmental tobacco smoke. Isoprene was found to be the major component of hydrocarbons in the air of a smoky café (10 patrons smoking, 10 not smoking) (16.7%) and in sidestream smoke (29.2%) (Barrefors and Petersson 1993). A monitoring survey in November 1992 in homes and workplaces in the greater Philadelphia area found mean isoprene concentrations in personal air samples of 4.65 μg/m^3^ in 60 nonsmoking homes, 18.15 μg/m^3^ in 29 homes with smokers, 5.29 μg/m^3^ in 51 nonsmoking workplaces, and 22.80 μg/m^3^ in 28 workplaces that allowed smoking (Heavner 1996). A survey in the Lower Rio Grande Valley of Texas reported a median summertime isoprene concentration of 2.90 μg/m^3^ for three indoor air samples (it was not reported whether the occupants were smokers or nonsmokers), compared with 0.40 μg/m^3^ for three outdoor air samples (Mukerjee et al. 1997).

Air-monitoring data were collected at three U.S. facilities that produced isoprene monomers or polymers; 98.5% of the samples showed concentrations of less than 10 ppm, and 91.3% of less than 1 ppm (Leber 2001; Lynch 2001). The National Occupational Hazard Survey (conducted from 1972 to 1974) estimated that 58,000 workers in over 30 industries potentially were exposed to isoprene (NIOSH 1976). The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated in a more limited survey that 3,700 workers in four industries, including 578 women, potentially were exposed to isoprene (NIOSH 1990).

## Regulations

### Coast Guard (Dept. of Homeland Security)

Minimum requirements have been established for safe transport of isoprene on ships and barges.

### Department of Transportation (DOT)

Isoprene is considered a hazardous material and a marine pollutant, and special requirements have been set for marking, labeling, and transporting this material.

### Environmental Protection Agency (EPA)

#### Clean Air Act

New Source Performance Standards: Manufacture of isoprene is subject to certain provisions for the control of volatile organic compound emissions.

Prevention of Accidental Release: Threshold quantity (TQ) = 10,000 lb.

#### Clean Water Act

Isoprene has been designated a hazardous substance.

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 100 lb.

Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

## References

Adam T, Mitschke S, Streibel T, Baker RR, Zimmermann R. 2006. Quantitative puff-by-puff-resolved characterization of selected toxic compounds in cigarette mainstream smoke. Chem Res Toxicol. 19(4):511–520. 10.1021/tx050220w 16608162
Akron. 2009. The Chemical Database. Akron, OH: The Department of Chemistry at the University of Akron; http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Altshuller A. 1983. Natural volatile organic substances and their effect on air quality in the United States. Atmos Environ. 17(11):2131–2165. 10.1016/0004-6981(83)90211-1
Barrefors G, Petersson G. 1993. Assessment of ambient volatile hydrocarbons from tobacco smoke and from vehicle emissions. J Chromatogr. 643(1-2):71–76. 10.1016/0021-9673(93)80542-G 7689578
Borbon A, Coddeville P, Locoge N, Galloo JC. 2004. Characterising sources and sinks of rural VOC in eastern France. Chemosphere. 57(8):931–942. 10.1016/j.chemosphere.2004.07.034 15488583
Borbon A, Fontaine H, Veillerot M, Locoge N, Galloo JC, Guillermo R. 2001. An investigation into the traffic-related fraction of isoprene at an urban location. Atmos Environ. 35(22):3749–3760. 10.1016/S1352-2310(01)00170-4
Borbon A, Locoge N, Veillerot M, Galloo JC, Guillermo R. 2002. Characterisation of NMHCs in a French urban atmosphere: Overview of the main sources. Sci Total Environ. 292(3):177–191. 10.1016/S0048-9697(01)01106-8 12146518
Cailleux A, Cogny M, Allain P. 1992. Blood isoprene concentrations in humans and in some animal species. Biochem Med Metab Biol. 47(2):157–160. 10.1016/0885-4505(92)90019-U 1515173
ChemSources. 2009. Chem Sources - Chemical Search. Pendleton, SC: Chemical Sources International; http://www.chemsources.com/chemonline.html and search on isoprene.
Chiang HL, Tsai JH, Chen SY, Lin KH, Ma SY. 2007. VOC concentration profiles in an ozone non-attainment area: A case study in an urban and industrial complex metroplex in southern Taiwan. Atmos Environ. 41(9):1848–1860. 10.1016/j.atmosenv.2006.10.055
EPA. 2004. Non-confidential IUR Production Volume Information. Washington, DC: U.S. Environmental Protection Agency; https://www.epa.gov/oppt/iur/tools/data/2002-vol.html and search on CAS number.
Fabiani R, Rosignoli P, De Bartolomeo A, Fuccelli R, Morozzi G. 2007. DNA-damaging ability of isoprene and isoprene mono-epoxide (EPOX I) in human cells evaluated with the comet assay. Mutat Res. 629(1):7–13. 10.1016/j.mrgentox.2006.12.007 17317274
Fuentes JD, Wang D. 1999. On the seasonality of isoprene emissions from a mixed temperate forest. Ecol Appl. 9(4):1118–1131. 10.1890/1051-0761(1999)009[1118:OTSOIE]2.0.CO;2
Gelmont D, Stein RA, Mead JF. 1981. Isoprene – The main hydrocarbon in human breath. Biochem Biophys Res Commun. 99(4):1456–1460. 10.1016/0006-291X(81)90782-8 7259787
Gervasi PG, Citti L, Del Monte M, Longo V, Benetti D. 1985. Mutagenicity and chemical reactivity of epoxidic intermediates of the isoprene metabolism and other structurally related compounds. Mutat Res. 156(1-2):77–82. 10.1016/0165-1218(85)90009-6 3158813
Guenther A, Hewitt CN, Erickson D, Fall R, Geron C, Graedel T, Harley P, Klinger L, Lerdau M, McKay WA, et al. 1995. A global model of natural volatile organic compound emissions. J Geophys Res Atmos. 100(D5):8873–8892. 10.1029/94JD02950
Guenther A, Zimmerman P, Wildermuth M. 1994. Natural volatile organic-Compound emission rate estimates for U.S. woodland landscapes. Atmos Environ. 28(6):1197–1210. 10.1016/1352-2310(94)90297-6
Guo H, Lee SC, Louie PK, Ho KF. 2004. Characterization of hydrocarbons, halocarbons and carbonyls in the atmosphere of Hong Kong. Chemosphere. 57(10):1363–1372. 10.1016/j.chemosphere.2004.07.055 15519381
Hagerman LM, Aneja VP, Lonneman WA. 1997. Characterization of non-methane hydrocarbons in the rural southeast United States. Atmos Environ. 31(23):4017–4038. 10.1016/S1352-2310(97)00223-9
Heavner DL, Morgan WT, Ogden MW. 1996. Determination of volatile organic compounds and respirable suspended particulate matter in New Jersey and Pennsylvania homes and workplaces. Environ Int. 22(2):159–183. 10.1016/0160-4120(96)00003-7
Hellén H, Hakola H, Pirjola L, Laurila T, Pystynen KH. 2006. Ambient air concentrations, source profiles, and source apportionment of 71 different C_2_-C_10_ volatile organic compounds in urban and residential areas of Finland. Environ Sci Technol. 40(1):103–108. 10.1021/es051659d 16433339
Hong HL, Devereux TR, Melnick RL, Eldridge SR, Greenwell A, Haseman J, Boorman GA, Sills RC. 1997. Both K-ras and H-ras protooncogene mutations are associated with Harderian gland tumorigenesis in B6C3F_1_ mice exposed to isoprene for 26 weeks. Carcinogenesis. 18(4):783–789. 10.1093/carcin/18.4.783 9111215
HSDB. 2009. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine; http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1994. Isoprene. In Some Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 60. Lyon, France: International Agency for Research on Cancer. pp. 215–232.
Kuster WC, Jobson BT, Karl T, Riemer D, Apel E, Goldan PD, Fehsenfeld FC. 2004. Intercomparison of volatile organic carbon measurement techniques and data at La Porte during the TexAQS2000 Air Quality Study. Environ Sci Technol. 38(1):221–228. 10.1021/es034710r 14740739
Lamb B, Gay D, Westberg H, Pierce T. 1993. A biogenic hydrocarbon emission inventory for the U.S.A. using a simple forest canopy model. Atmos Environ Part A. 27(11):1673–1690. 10.1016/0960-1686(93)90230-V
Leber AP. 2001. Overview of isoprene monomer and polyisoprene production processes. Chem Biol Interact. 135-136:169–173. 10.1016/S0009-2797(01)00189-2 11397389
Lechner M, Moser B, Niederseer D, Karlseder A, Holzknecht B, Fuchs M, Colvin S, Tilg H, Rieder J. 2006. Gender and age specific differences in exhaled isoprene levels. Respir Physiol Neurobiol. 154(3):478–483. 10.1016/j.resp.2006.01.007 16510318
Lynch J. 2001. Occupational exposure to butadiene, isoprene and chloroprene. Chem Biol Interact. 135-136:207–214. 10.1016/S0009-2797(01)00191-0 11397391
Mayrhofer S, Heizmann U, Magel E, Eiblmeier M, Muller A, Rennenberg H, Hampp R, Schnitzler JP, Kreuzwieser J. 2004. Carbon balance in leaves of young poplar trees. Plant Biol. 6(6):730–739. 10.1055/s-2004-821268 15570479
Melnick RL, Sills RC. 2001. Comparative carcinogenicity of 1,3-butadiene, isoprene, and chloroprene in rats and mice. Chem Biol Interact. 135-136:27–42. 10.1016/S0009-2797(01)00213-7 11397379
Moukhtar S, Couret C, Rouil L, Simon V. 2006. Biogenic volatile organic compounds (BVOCs) emissions from Abies alba in a French forest. Sci Total Environ. 354(2-3):232–245. 10.1016/j.scitotenv.2005.01.044 16140360
Mukerjee S, Ellenson WD, Lewis RG, Stevens RK, Somerville MC, Shadwick DS, Willis RD. 1997. An environmental scoping study in the lower Rio Grande Valley of Texas—III. Residential microenvironmental monitoring for air, house dust, and soil. Environ Int. 23(5):657–673. 10.1016/S0160-4120(97)00068-8
NIOSH. 1976. National Occupational Hazard Survey (1972-74). Cincinnati, OH: National Institute for Occupational Safety and Health. DHEW (NIOSH) Publication No. 78-114.
NIOSH. 1990. National Occupational Exposure Survey (1981-83). Cincinnati, OH: National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/40940sic.html
NTP. 1995. NTP Technical Report on the Toxicity Studies of Isoprene (CAS No. 78-79-5) Administered by Inhalation to F344/N Rats and B6C3F1 Mice. Research Triangle Park, NC: National Toxicology Program. NTP Technical Report Series no. 31.
NTP. 1999 a. NTP Report on Carcinogens Background Document for Isoprene. Research Triangle Park, NC: National Toxicology Program.
NTP. 1999b. NTP Toxicology and Carcinogenesis Studies of Isoprene (CAS No. 78-79-5) in F344/N Rats (Inhalation Studies). Research Triangle Park, NC: National Toxicology Program. NTP Technical Report Series no. 486.
Parra R, Gassó S, Baldasano JM. 2004. Estimating the biogenic emissions of non-methane volatile organic compounds from the North Western Mediterranean vegetation of Catalonia, Spain. Sci Total Environ. 329(1-3):241–259. 10.1016/j.scitotenv.2004.03.005 15262170
Pegoraro E, Rey A, Barron-Gafford G, Monson R, Malhi Y, Murthy R. 2005. The interacting effects of elevated atmospheric CO_2_ concentration, drought and leaf-to-air vapour pressure deficit on ecosystem isoprene fluxes. Oecologia. 146(1):120–129. 10.1007/s00442-005-0166-5 16001217
Peter H, Wiegand HJ, Bolt HM, Greim H, Walter G, Berg M, Filser JG. 1987. Pharmacokinetics of isoprene in mice and rats. Toxicol Lett. 36(1):9–14. 10.1016/0378-4274(87)90035-X 3564074
Placke ME, Griffis L, Bird M, Bus J, Persing RL, Cox LA Jr. 1996. Chronic inhalation oncogenicity study of isoprene in B6C3F_1_ mice. Toxicology. 113(1-3):253–262. 10.1016/0300-483X(96)03454-3 8901906
Rieder J, Lirk P, Ebenbichler C, Gruber G, Prazeller P, Lindinger W, Amann A. 2001. Analysis of volatile organic compounds: Possible applications in metabolic disorders and cancer screening. Wien Klin Wochenschr. 113(5-6):181–185. 11293947
Sasaki M, Nakamura Y, Fujita K, Kinugawa Y, Iida T, Urahama Y. 2005. Relation between phase structure and peel adhesion of poly(styrene-isoprene-styrene) triblock copolymer/tackifier blend system. J Adhes Sci Technol. 19(16):1445–1457. 10.1163/156856105774805859
Schnitzler JP, Graus M, Kreuzwieser J, Heizmann U, Rennenberg H, Wisthaler A, Hansel A. 2004. Contribution of different carbon sources to isoprene biosynthesis in poplar leaves. Plant Physiol. 135(1):152–160. 10.1104/pp.103.037374 15122010
Schnitzler JP, Zimmer I, Bachl A, Arend M, Fromm J, Fischbach RJ. 2005. Biochemical properties of isoprene synthase in poplar (Populus x canescens). Planta. 222(5):777–786. 10.1007/s00425-005-0022-1 16052321
Senthilmohan ST, McEwan MJ, Wilson PF, Milligan DB, Freeman CG. 2001. Real time analysis of breath volatiles using SIFT-MS in cigarette smoking. Redox Rep. 6(3):185–187. 10.1179/135100001101536166 11523595
Senthilmohan ST, Milligan DB, McEwan MJ, Freeman CG, Wilson PF. 2000. Quantitative analysis of trace gases of breath during exercise using the new SIFT-MS technique. Redox Rep. 5(2-3):151–153. 10.1179/135100000101535537 10939300
Sharkey TD. 2005. Effects of moderate heat stress on photosynthesis: Importance of thylakoid reactions, rubisco deactivation, reactive oxygen species, and thermotolerance provided by isoprene. Plant Cell Environ. 28(3):269–277. 10.1111/j.1365-3040.2005.01324.x
Simon V, Dumergues L, Ponche JL, Torres L. 2006. The biogenic volatile organic compounds emission inventory in France: Application to plant ecosystems in the Berre-Marseilles area (France). Sci Total Environ. 372(1):164–182. 10.1016/j.scitotenv.2006.08.019 17011024
So KL, Wang T. 2004. C_3_-C_12_ non-methane hydrocarbons in subtropical Hong Kong: Spatial-temporal variations, source-receptor relationships and photochemical reactivity. Sci Total Environ. 328(1-3):161–174. 10.1016/j.scitotenv.2004.01.029 15207581
SRI. 2009. Directory of Chemical Producers, Database ed. Menlo Park, CA: SRI Consulting.
Taalman RD. 1996. Isoprene: Background and issues. Toxicology. 113(1-3):242–246. 10.1016/0300-483X(96)03452-X 8901904
Tambunan P, Baba S, Kuniyoshi A, Iwasaki H, Nakamura T, Yamasaki H, Oku H. 2006. Isoprene emission from tropical trees in Okinawa Island, Japan. Chemosphere. 65(11):2138–2144. 10.1016/j.chemosphere.2006.06.013 16860371
Taucher J, Hansel A, Jordan A, Fall R, Futrell JH, Lindinger W. 1997. Detection of isoprene in expired air from human subjects using proton-transfer-reaction mass spectrometry. Rapid Commun Mass Spectrom. 11(11):1230–1234. 10.1002/(SICI)1097-0231(199707)11:11<1230::AID-RCM3>3.0.CO;2-Z 9260307
Tice RR. 1988. The cytogenetic evaluation of in vivo genotoxic and cytotoxic activity using rodent somatic cells. Cell Biol Toxicol. 4(4):475–486. 10.1007/BF00117775 3228715
Tice RR, Boucher R, Luke CA, Paquette DE, Melnick RL, Shelby MD. 1988. Chloroprene and isoprene: Cytogenetic studies in mice. Mutagenesis. 3(2):141–146. 10.1093/mutage/3.2.141 3288837
Turner C, Spanel P, Smith D. 2006. A longitudinal study of breath isoprene in healthy volunteers using selected ion flow tube mass spectrometry (SIFT-MS). Physiol Meas. 27(1):13–22. 10.1088/0967-3334/27/1/002 16365507
USITC. 2009. USITC Interactive Tariff and Trade DataWeb. Washington, DC: United States International Trade Commission; https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2901242000.
Warneke C, Kato S, De Gouw JA, Goldan PD, Kuster WC, Shao M, Lovejoy ER, Fall R, Fehsenfeld FC. 2005. Online volatile organic compound measurements using a newly developed proton-transfer ion-trap mass spectrometry instrument during New England Air Quality Study –Intercontinental Transport and Chemical Transformation 2004: Performance, intercomparison, and compound identification. Environ Sci Technol. 39(14):5390–5397. 10.1021/es050602o 16082971
Zhao W, Hopke PK, Karl T. 2004. Source identification of volatile organic compounds in Houston, Texas. Environ Sci Technol. 38(5):1338–1347. 10.1021/es034999c 15046334