# Haloacetic Acids Found as Water Disinfection Byproducts (Selected)

Also known as HAAs

## Introduction

Disinfection of the public water supply is an important aspect of public health in the prevention of disease transmission in the United States and worldwide (Calderon 2000). Haloacetic acids are formed as byproducts during the disinfection of water, as the result of reactions between chlorine-based disinfection agents (chlorine, chloramine, and chlorine dioxide) and organic molecules in the source water (such as humic acid).

Humans are exposed to haloacetic acids in disinfected water, and exposure is to mixtures of disinfection byproducts, including haloacetic acids and other types of byproducts. Only one epidemiological study was identified that evaluated the relationship between human cancer risk and estimated exposures to several individual haloacetic acids and to a mixture of five regulated haloacetic acids (monochloroacetic, dichloroacetic, trichloroacetic, monobromoacetic, and dibromoacetic acids) (Jones et al. 2017). This study did not find an association between exposure to haloacetic acids in drinking water and the incidence of kidney cancer. Several epidemiological studies of exposure to chlorinated water or to other water disinfection byproducts (such as trihalomethanes) as proxies for mixtures of byproducts found an association with increased risk of urinary-bladder cancer (reviewed by IARC 2013; Villanueva et al. 2017). Although these studies did not investigate exposure specifically to haloacetic acids, they provided some information on the potential cancer risk of human exposure to water disinfection byproducts, and they supported the relevance to humans of the cancer studies of haloacetic acids at higher doses in experimental animals.

Currently, public exposure to disinfection byproducts in chlorinated water is limited through regulation of specific water disinfection byproducts or classes of byproducts. The existing epidemiological studies cannot separate the effects of different types of water disinfection byproducts. However, toxicological studies of specific byproducts, including haloacetic acids, are available to help inform public health decisions. Trihalomethanes and haloacetic acids are the largest groups of water disinfection byproducts by weight, making up about 50% to 75% of total halogenated disinfection byproducts and about 25% to 50% of total organic halides in drinking water (Krasner et al. 2006; Krasner et al. 2016). Two trihalomethanes—chloroform and bromodichloromethane—are listed in the Report on Carcinogens as reasonably anticipated to be a human carcinogen. The U.S. Environmental Protection Agency (EPA) regulates the mixture of five haloacetic acids mentioned above, two of which (dichloroacetic acid and dibromoacetic acid) are included in this listing.

NTP evaluated 13 haloacetic acids identified in chlorinated drinking water, six of which are individually listed as reasonably anticipated to be a human carcinogen in the Report on Carcinogens:

- bromochloroacetic acid
- bromodichloroacetic acid
- chlorodibromoacetic acid
- dibromoacetic acid
- dichloroacetic acid
- tribromoacetic acid

The available data (NTP 2018) were inadequate to evaluate haloacetic acids either as a class or as subclasses, such as those based on the number of halogen substitutions (one, two, or three) or the halogen atom(s) substituted (chlorine, bromine, or iodine) or to support listing of any of the other seven haloacetic acids identified in drinking water (monochloroacetic acid, monobromoacetic acid, monoiodoacetic acid, diiodoacetic acid, bromoiodoacetic acid, chloroiodoacetic acid, or trichloroacetic acid).

The profiles for the six listed haloacetic acids follow this introduction. The listings for bromochloroacetic acid, bromodichloroacetic acid, dibromoacetic acid, and dichloroacetic acid are based on cancer studies in experimental animals, and the listings for chlorodibromoacetic acid and tribromoacetic acid are based on other relevant data, including data on mechanisms of carcinogenesis. Most of the supporting mechanistic and other relevant information and the data on properties, use, production, exposure, and U.S. regulations to limit exposure are applicable to all six listed haloacetic acids. Therefore, the carcinogenicity data from cancer studies in experimental animals and in humans are discussed separately for each chemical, followed by combined discussions of absorption and metabolism, mechanisms of carcinogenesis, properties, use, formation and removal of disinfection byproducts, exposure, regulations, and guidelines for all six listed haloacetic acids.

## Bromochloroacetic Acid

CAS No. 5589-96-8

Reasonably anticipated to be a human carcinogen

First listed in the Fifteenth Report on Carcinogens (2021)

Figure 1

Chemical Structure of Bromochloroacetic Acid

### Carcinogenicity

Bromochloroacetic acid is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals and supporting evidence from mechanistic studies that demonstrate the biological plausibility of its carcinogenicity in humans.

#### Cancer Studies in Experimental Animals

Administration of bromochloroacetic acid in the drinking water caused liver tumors in mice of both sexes and tumors at several other tissue sites in rats of both sexes. The studies were considered to have high utility for evaluating carcinogenicity because they tested sufficient numbers of experimental animals for near-lifetime exposures using adequate study designs, dosing, and pathology methods. Bromochloroacetic acid significantly increased the incidences of benign and malignant liver tumors (hepatocellular adenoma and carcinoma) in male and female mice and caused significant dose-related increases in the incidence of another type of malignant liver tumor (hepatoblastoma) in male mice. Significantly increased incidences were observed in malignant mesothelioma of the abdominal-pelvic peritoneum in male rats and in multiple fibroadenomas of the mammary gland in female rats. In addition, very rare adenomas of the large intestine were reported in rats of both sexes; the incidences were significantly increased in males and showed significant dose-related trends in both sexes. Fibroadenoma of the mammary gland and adenoma of the large intestine can progress to malignancy (NTP 2009).

#### Cancer Studies in Humans

The data available from epidemiological studies are inadequate to evaluate the relationship between human cancer and exposure specifically to bromochloroacetic acid. A cohort study of post-menopausal women found no association between estimated exposure to bromochloroacetic acid in drinking water and the risk of kidney cancer (Jones et al. 2017).

## Bromodichloroacetic Acid

CAS No. 71133-14-7

Reasonably anticipated to be a human carcinogen

First listed in the Fifteenth Report on Carcinogens (2021)

Figure 2

Chemical Structure of Bromodichloroacetic Acid

### Carcinogenicity

Bromodichloroacetic acid is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals and supporting evidence fom mechanistic studies that demonstrate the biological plausibility of its carcinogenicity in humans.

#### Cancer Studies in Experimental Animals

Administration of bromodichloroacetic acid in the drinking water caused tumors at several different tissue sites in mice and rats. The studies were considered to have high utility for evaluating carcinogencity because they tested sufficient numbers of experimental animals for near-lifetime exposures using adequate study designs, dosing, and pathology methods. Significant dose-related increases in malignant liver tumors (hepatocellular carcinoma and hepatoblastoma) were observed in mice of both sexes, and increased incidences of benign liver tumors (hepatocellular adenoma) were observed in female mice. In male mice, increased incidences of benign tumors and combined benign and malignant tumors of the Harderian gland (an accessory tear gland) were observed, with dose-related trends in incidence. Tumors with significantly increased incidences in male rats included malignant mesothelioma of the abdominal-pelvic peritoneum and several types of skin tumors, including fibroma (a benign tumor) and the combined incidence of several types of malignant tumors or benign tumors that can progress to malignancy (squamous-cell papilloma, keratoacanthoma, sebaceous-gland adenoma, basal-cell adenoma, basal-cell carcinoma, or squamous-cell carcinoma). Female rats developed multiple fibroadenomas and carcinoma of the mammary gland, which increased in incidence with increasing dose of bromodichloroacetic acid (NTP 2015).

#### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to bromodichloroacetic acid.

## Chlorodibromoacetic Acid

CAS No. 5278-95-5

Reasonably anticipated to be a human carcinogen

First listed in the Fifteenth Report on Carcinogens (2021)

Also known as dibromochloroacetic acid

Figure 3

Chemical Structure of Chlorodibromoacetic Acid

### Carcinogenicity

Chlorodibromoacetic acid is reasonably anticipated to be a human carcinogen based on (1) metabolism studies providing convincing evidence that chlorodibromoacetic acid is metabolized to bromochloroacetic acid, (2) sufficient evidence for the carcinogenicity of bromochloroacetic acid from studies in experimental animals, and (3) supporting evidence from mechanistic studies that demonstrate the biological plausibility of its carcinogenicity in humans. No cancer studies in humans or experimental animals exposed to chlorodibromoacetic acid were identified.

Findings from a toxicokinetics study of rats orally exposed to chlorodibromoacetic acid suggest that it is highly metabolized in vivo; however, this study modeled rates of metabolism and excretion without identifying specific metabolites (Schultz et al. 1999). In vitro studies found that all metabolism of chlorodibromoacetic acid resulted from loss of a bromide ion to form bromochloroacetic acid, indicating that bromochloroacetic acid is the only metabolite (Saghir et al. 2011). These studies used rat and human microsomes (enzymes extracted from liver cells as small particles) exposed to chlorodibromoacetic acid under conditions that mimic those in vivo (e.g., at oxygen levels similar to those measured in liver tissue).

In the case of bromochloroacetic acid, administration in the drinking water caused liver and Harderian-gland tumors in mice and malignant mesothelioma, mammary-gland tumors, and skin tumors in rats (NTP 2009), as described above. Mechanistic studies show that chlorodibromoacetic acid (like bromochloroacetic acid) causes mutations in bacteria and oxidative stress and DNA damage in cultured mammalian cells. These effects are characteristic of other human carcinogens, supporting the biological plausibility of the carcinogenicity of chlorodibromoacetic acid in humans. Therefore, it is reasonably anticipated that chronic oral exposure of humans to chlorodibromoacetic acid could cause cancer.

## Dibromoacetic Acid

CAS No. 631-64-1

Reasonably anticipated to be a human carcinogen

First listed in the Fifteenth Report on Carcinogens (2021)

Figure 4

Chemical Structure of Dibromoacetic Acid

### Carcinogenicity

Dibromoacetic acid is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals and supporting evidence from mechanistic studies that demonstrate the biological plausibility of its carcinogenicity in humans.

#### Cancer Studies in Experimental Animals

Administration of dibromoacetic acid in the drinking water caused tumors at several different tissue sites in mice and rats. The studies were considered to have high utility for evaluating carcinogenicity because they tested sufficient numbers of experimental animals for near-lifetime exposures using adequate study designs, dosing, and pathology methods. Dibromoacetic acid caused significant dose-related increases in the incidences of benign and malignant liver tumors (hepatocellular adenoma and carcinoma) in male and female mice and another type of malignant liver tumor (hepatoblastoma) in male mice. In addition, significant increases were observed in the combined incidence of benign and malignant lung tumors (alveolar/bronchiolar adenoma and carcinoma) in male mice. In rats, significant dose-related increases were observed in the incidence of malignant mesothelioma of the abdominal-pelvic peritoneum (the lining of the abdominal cavity) in males and in mononuclear-cell leukemia in females (NTP 2007). Although the background rates of mononuclear-cell leukemia in rats are high and variable, the incidence of these neoplasms in the mid- and high-dose exposure groups exceeded the background rates (historical controls), which increases confidence that dibromoacetic acid caused this type of leukemia.

#### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to dibromoacetic acid. A cohort study of post-menopausal women found no association between the risk of kidney cancer and estimated exposure via drinking water to a mixture of haloacetic acids that contained dibromoacetic acid (Jones et al. 2017).

## Dichloroacetic Acid

CAS No. 79-43-6

Reasonably anticipated to be a human carcinogen

First listed in the Fifteenth Report on Carcinogens (2021)

Figure 5

Chemical Structure of Dichloroacetic Acid

### Carcinogenicity

Dichloroacetic acid is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals and supporting evidence from mechanistic studies that demonstrate the biological plausibility of its carcinogenicity in humans.

#### Cancer Studies in Experimental Animals

Administration of dichloroacetic acid in the drinking water caused liver tumors in rats and mice. All of the studies were considered to have moderate to high utility for evaluating carcinogenicity, and the findings could not be explained by potential biases. In mice of both sexes, significant increases in benign and malignant liver tumors (hepatocellular adenoma and carcinoma) were observed in several studies (Daniel et al. 1992; DeAngelo et al. 1991; DeAngelo et al. 1999; Herren-Freund et al. 1987; Pereira 1996). In a stop-exposure study, male and female mice were exposed at weaning (four weeks of age) to dichloroacetic acid in drinking water for 10 weeks, followed by no further exposure to this chemical for 80 weeks. Significant increases in benign and malignant liver tumors were reported for both sexes, and tumor incidences approached levels found with near-lifetime exposures (Wood et al. 2015). Dichloroacetic acid also significantly increased the incidence of hepatocellular carcinoma and combined hepatocellular adenoma and carcinoma in male rats in two drinking-water studies (DeAngelo et al. 1996). (Female rats were not tested for carcinogenicity in these studies.)

#### Cancer Studies in Humans

The data available from epidemiological studies are inadequate to evaluate the relationship between human cancer and exposure specifically to dichloroacetic acid. A cohort study of post-menopausal women found no association between estimated exposure to dichloroacetic acid in drinking water and the risk of kidney cancer (Jones et al. 2017).

## Tribromoacetic Acid

CAS No. 75-96-7

Reasonably anticipated to be a human carcinogen

First listed in the Fifteenth Report on Carcinogens (2021)

Figure 6

Chemical Structure of Tribromoacetic Acid

### Carcinogenicity

Tribromoacetic acid is reasonably anticipated to be a human carcinogen based on (1) metabolism studies providing convincing evidence that tribromoacetic acid is metabolized to dibromoacetic acid, (2) sufficient evidence for the carcinogenicity of dibromoacetic acid from studies in experimental animals, and (3) supporting evidence from mechanistic studies that demonstrate the biological plausibility of its carcinogenicity in humans. No cancer studies in humans or experimental animals exposed to tribromoacetic acid were identified.

Findings from a toxicokinetics study of rats orally exposed to tribromoacetic acid suggest that it is highly metabolized in vivo; however, this study modeled rates of metabolism and excretion without identifying specific metabolites (Schultz et al. 1999). An in vitro study found that half of the total metabolism of tribromoacetic acid resulted from the loss of a bromide ion to form dibromoacetic acid (Saghir et al. 2011), indicating that dibromoacetic acid is the major metabolite. These studies used rat and human microsomes exposed to tribromoacetic acid under conditions that mimic those in vivo (e.g., at oxygen levels similar to those measured in liver tissue).

Administration of dibromoacetic acid in the drinking water caused liver and lung tumors in mice and malignant mesothelioma and mononuclear-cell leukemia in rats (NTP 2007), and as described above. Mechanistic studies showed that tribromoacetic acid (like dibromoacetic acid) causes mutations in bacteria and oxidative stress and DNA damage in cultured mammalian cells. These effects are characteristic of other human carcinogens, supporting the biological plausibility of the carcinogenicity of tribromoacetic acid in humans. Therefore, it is reasonably anticipated that chronic oral exposure of humans to tribromoacetic acid could cause cancer.

## Selected Haloacetic Acids

### Carcinogenicity: Mechanistic and Other Relevant Data

The mechanisms by which these haloacetic acids cause cancer in experimental animals are not known and most likely involve several modes of action. Although many of the haloacetic acids cause similar effects in vitro and in vivo, the available mechanistic and other relevant data are insufficient to enable evaluation of the carcinogenicity of haloacetic acids as a class or subclass (NTP 2018, section 7).

#### Absorption and Metabolism

Ingested haloacetic acids are rapidly absorbed from the gastrointestinal tract and are found in the blood and tissues at approximately equal concentrations. Metabolism of dihaloacetic and trihaloacetic acids is complex, but the limited data available suggest that metabolism of a trihaloacetic acid to dihaloacetic acid is similar in rodents and humans (Merdink et al. 2000; Saghir and Schultz 2005; Saghir et al. 2011; Stacpoole et al. 1998). Dihaloacetic acids are metabolized to a greater extent than trihaloacetic acids, and their metabolism results in formation of the metabolites glyoxylate, glycolate, oxylate, glycine, and carbon dioxide.

The three trihaloacetic acids discussed here (bromodichloroacetic acid, chlorodibromoacetic acid, and tribromoacetic acid) are metabolized by liver enzymes (cytochrome P450) to remove one of the halogens, forming a dihaloacetic acid (dichloroacetic, bromochloroacetic, or dibromoacetic acid). An important effect of this metabolism relevant to potential mechanism(s) of carcinogenesis is the formation of a highly reactive free radical as part of the process. The chemical nature of bromine makes it the halogen most likely to be removed in this conversion (Saghir et al. 2011).

#### Studies on Mechanisms of Carcinogenesis

Haloacetic acids have a weak positive charge (i.e., are weak electrophiles) and are attracted to macromolecules (proteins, lipids, DNA, or RNA) with a weak negative charge (i.e., weak nucleophiles), such as thiol or amino groups on proteins; stronger electrophiles can also bind with oxygen in DNA and RNA. The body of data suggests that these listed haloacetic acids may induce cancer through reactions with macromolecules leading to oxidative stress, mutagenic and genotoxic effects, inhibition of enzymes leading to oxidative stress, and/or regulation of genes involved in carcinogenicity.

Most of the available mechanistic data on the haloacetic acids are from in vitro studies measuring oxidative stress, genotoxicity, and toxicity. In general, in vitro studies indicate that dihaloacetic acids are more genotoxic, cytotoxic, and mutagenic than trihaloacetic acids, and that substitution of bromine for one of the hydrogen atoms on the alpha carbon (as shown in Figure 7 in Properties, below) has a more potent effect on these properties than substitution of chlorine (Kargalioglu et al. 2002; Plewa et al. 2004; Stalter et al. 2016). All of the listed haloacetic acids cause oxidative stress (assessed in various types of in vitro assays), which leads to the generation of reactive oxygen species that can damage DNA and cause mutations. In addition, exposure of experimental animals to some dihaloacetic and trihaloacetic acids (dichloroacetic, dibromoacetic, bromochloroacetic, and bromodichloroacetic acids, the only ones tested) caused oxidative stress (as evidenced by formation of 8-hydroxydeoxyguanosine DNA adducts and lipid peroxidation); the strongest response was to the brominated haloacetic acids (Austin et al. 1996; Larson and Bull 1992). The types of pathways that generate oxidative stress may vary across the haloacetic acids, and several pathways may be involved (Celik et al. 2009; Cemeli et al. 2006; Dad et al. 2013; El Arem et al. 2014a; El Arem et al. 2014b; El Arem et al. 2014c; Ondricek et al. 2012; Pals et al. 2011; Stalter et al. 2016).

Figure 7

Dihaloacetic Acids (Left) and Trihaloacetic Acids (Right)

α = alpha carbon; X = halogen atom (chlorine or bromine).

Overall, the data suggest that haloacetic acids do not bind to DNA, and most likely cause genotoxicity through oxidative stress. Both the dihaloacetic acids (dichloroacetic, dibromoacetic, and bromochloroacetic acids) and trihaloacetic acids (tribromoacetic, bromodichloroacetic, and chlorodibromoacetic acids) listed here caused mutations in bacteria (NTP 2018, section 6). Evidence for other types of genotoxicity is limited, because only a few haloacetic acids (mostly the dihaloacetic acids) were tested for each type of damage, and the findings for each end point were not always consistent across different haloacetic acids. The strongest evidence is that bromine-containing haloacetic acids (dibromoacetic, tribromoacetic, and bromochloroacetic acids) damage DNA (e.g., cause DNA strand breaks) and that dibromoacetic acid and dichloroacetic acid damage chromosomes (as indicated by micronucleus formation) and cause gene mutations in vitro (NTP 2018, section 6).

Studies provide some insight into one of the mechanisms leading to oxidative stress. Dichloroacetic acid has been shown to affect energy metabolism within the cell by inhibiting a mitochondrial enzyme complex (pyruvate dehydrogenase complex), thus enhancing oxidative metabolism and potentially increasing the formation of reactive oxygen species and DNA damage and mutations, if not correctly repaired (Pals et al. 2011). This mechanism could potentially operate with other haloacetic acids as well. Another mechanism by which some haloacetic acids (dichloroacetic, dibromoacetic, and bromochloroacetic acids) can cause oxidative stress is via the inhibition of an enzyme involved in dihaloacetic acid metabolism (glutathione S-transferase zeta), which results in reduced metabolism and clearance of dihaloacetic acids, induction of oxidative stress, and activation of stress-response pathways (Anderson et al. 1999; Gonzalez-Leon et al. 1999).

Other studies suggest that dichloroacetic acid and dibromoacetic acid might cause cancer by regulating genes related to carcinogenicity (e.g., c-myc, c-jun, or IGF-II, which can promote cell growth, division, or death). Dichloroacetic acid induced hypomethylation (loss of methyl groups in DNA nucleotides) in the promoter region of the c-myc gene in liver, kidney, and urinary-bladder tissues in mice; enhanced cellular proliferation in mouse liver (Ge et al. 2001); and promoted liver tumors (Tao et al. 2000) and kidney tumors (Pereira et al. 2001) in mice.

### Properties

Haloacetic acids are nonvolatile water-soluble chemicals (i.e., they do not readily evaporate). They vary in the number and type of halogen (fluorine, chlorine, bromine, or iodine) substitutions at the alpha carbon of acetic acid (as shown in Figure 7). The selected haloacetic acids listed here have either two or three halogen substitutions of either chlorine or bromine. The physicochemical characteristics of each haloacetic acid depend on the numbers of chlorine and bromine atoms in the molecule.

At physiological pH, these haloacetic acids are in ionized form (i.e., they lose a hydrogen ion and have a negative charge). The negative log of the acid dissociation constant (pK_a_, shown in the table on the next page) is a measure of the strength of an acid in solution, which increases as pK_a_ decreases. Therefore, trihaloacetic acids, which have lower pK_a_ values, are stronger acids than dihaloacetic acids. The pK_a_ and two other physicochemical properties are likely to be related to the toxicity of haloacetic acids, because they describe the ability of the molecules to enter cells and their potential reactivity with other molecules within a cell. Uncharged molecules enter cells much more readily than charged ones, so the potential for ionization as measured by pK_a_ helps predict that movement. In addition, the relative solubility of the molecule in lipids (fatty substances) compared with water also determines how readily that molecule will cross the lipid-rich cell membranes; chemists define this as the “octanol-water partition coefficient” (log K_ow_), with octanol representing the lipids. Both pK_a_ and log K_ow_ also affect the potential reactivity of a molecule, along with the energy of the lowest unoccupied molecular orbital (E_LUMO_) where an electron could exist, which is a measure of its ability to exchange electrons with other molecules. The toxic potency of a haloacetic acid correlates with its reactivity in accepting electrons from other molecules, and is higher for brominated than chlorinated haloacetic acids (Pals et al. 2011; Plewa et al. 2004). A haloacetic acid molecule’s reactivity increases as the energy required to break the bonds with the alpha carbon and its E_LUMO_ value decrease. Physical and chemical properties of the six listed haloacetic acids are shown in Table 1.

Table 1 Properties of Selected Haloacetic Acids

Haloacetic acid | Molecular weight^a^ | Water solubility (g/100 mL)^a,b^ | Vapor pressure (mm Hg)^a,b^ | Log K_ow_^a^ | Dissociation constant (pK_a_)^c^ | E_LUMO_ (eV)^c,d^
Bromochloroacetic acid | 173.4 | 25 | 0.14 | 0.61 | 1.40 | 7.78
Bromodichloroacetic acid | 207.8 | 0.49 | 0.036 | 1.53 | 0.05 | 6.65
Chlorodibromoacetic acid | 252.3 | 0.24 | 0.0052 | 1.62 | 0.04 | 6.42
Dibromoacetic acid | 217.8 | 211 | 0.023 | 0.70 | 1.39 | 7.51
Dichloroacetic acid | 128.9 | 100 at 20°C | 0.179 | 0.92 | 1.41 | 8.44
Tribromoacetic acid | 296.7 | 20 | 0.00028 | 1.71 | 0.03 | 6.12

Sources: ^a^PubChem (2020a; 2020b; 2020c; 2020d; 2020e; 2020f) ^c^Stalter et al. (2016).

^b^ Reported at 25°C (298.15°K) except as indicated.

^d^ Deprotonated (acetate form).

### Use

Although the focus of this profile is exposure to haloacetic acids found in drinking water, some of these haloacetic acids are also used for commercial purposes. Dichloroacetic acid is used as a chemical manufacturing intermediate (e.g., in the production of glyoxylic acid), a laboratory reagent in polyethylene terephthalate production, a skin cauterizing agent, a medical disinfectant (e.g., a substitute for formalin), and treatment for congenital lactic acidosis, and it has been proposed as a targeted cancer therapeutic agent (IARC 2014). Tribromoacetic acid has been used in organic synthesis (PubChem 2020f), and dibromoacetic acid and bromochloroacetic acid have been reported to be used in research (IARC 2013).

### Formation and Removal of Disinfection Byproducts

The purpose of water disinfection is to remove contaminants and disease-causing agents from drinking water (CDC 2015). The most common steps in conventional water treatment are coagulation and flocculation, sedimentation, filtration, disinfection, and storage (CDC 2015; EPA 2016a). Water disinfection is regulated by EPA through Surface Water Treatment Rules, which established maximum contaminant level goals for viruses, bacteria (such as Legionella), and other microorganisms (such as the protozoans Giardia lamblia and Cryptosporidium). EPA regulates five of the most common haloacetic acids (HAA5) in the public water supply: monochloroacetic acid, dichloroacetic acid, monobromoacetic acid, dibromoacetic acid, and trichloroacetic acid. In order to support national drinking water standards, EPA has more recently required monitoring of nine common haloacetic acids (HAA9): monochloroacetic acid, dichloroacetic acid, monobromoacetic acid, dibromoacetic acid, trichloroacetic acid, bromochloroacetic acid, chlorodibromoacetic acid, bromodichloroacetic acid, and tribromoacetic acid.

The presence of haloacetic acids in disinfected drinking water in the United States is well established, and knowledge of the chemical and physical processes that lead to their formation is important to help control their levels as required by law and to protect public health. The factors that determine the types and amounts of disinfection byproducts formed during water treatment include (1) the presence of organic matter and inorganic matter in the source water, which varies daily and seasonally in concentration, (2) the disinfecting chemicals used, (3) how long the organic matter is exposed to the disinfecting chemicals, (4) the temperature at which the disinfection process takes place, and (5) the pH of the water during the disinfection process. (The relationships among these factors are summarized in the diagram below.) The organic molecules in source water are often large, complex molecules, from which intermediate molecules are formed as a result of exposure to disinfecting chemicals. Further reaction between these intermediate molecules and disinfecting chemicals during disinfection and storage result in the formation of halogenated byproducts, including haloacetic acids (NTP 2018, section 2).

Figure 8

Major Factors Affecting the Formation of Halogenated Disinfection By-products

Organic molecules in source water plus naturally occurring or anthropogenic bromide and iodide react with various chlorine-containing disinfecting chemicals to form halogenated intermediate molecules and ultimately the halogenated HAAs.

HOCl = hypochlorous acid; HOBr = hypobromous acid; HOI = hypoiodous acid; NOM = natural organic matter; DBPs = disinfection byproducts.

Three general approaches are used for remediation of haloacetic acid disinfection byproducts: (1) removal of precursors before disinfection, (2) optimization or modification of disinfection practices (e.g., altering disinfectant type, dose, or application point in the water treatment process), and (3) removal of disinfection byproducts after formation. Before treatment, alum coagulation combined with the use of ion-exchange resins can remove up to 80% of precursors, activated charcoal filtration can remove up to 91%, and membrane nanofiltration can remove up to 99%. Disinfection practices can be modified through the use of ozone and ultraviolet irradiation, which do not leave residual chlorine in the water, or by using a non-chlorinated pre-oxidation chemical. Haloacetic acids can be removed after their formation through biologically active granular activated charcoal filtration.

### Exposure

Disinfection of water has achieved tremendous public health benefits in the United States and worldwide through reduction in exposure of individuals to disease-causing microorganisms. Over 250 million people in the United States potentially are exposed to chlorinated drinking water, indicating that a significant number of people in the United States are exposed to haloacetic acids found as water disinfection byproducts. Humans are exposed to haloacetic acids though drinking of tap water, consumption of beverages and food that have come in contact with treated water, and ingestion, dermal, and inhalation exposure to disinfected water in swimming pools and spas (both occupational and recreational). In addition, people can be occupationally exposed to dichloroacetic acid at workplaces where it is used as a chemical intermediate or through its use as a medical disinfectant.

#### Occurrence of Haloacetic Acids in Treated Water

The listed haloacetic acids that have been detected at the highest levels are dichloroacetic acid, bromochloroacetic acid, and bromodichloroacetic acid. The concentration ranges at which they have been detected are shown in Table 2.

Table 2 Concentration Ranges of Selected Haloacetic Acids

Listed haloacetic acid | Concentration range (µg/L)^a^ | Reference
Bromochloroacetic acid | <LOD–18 | IARC (2013); PubChem (2020a)
Bromodichloroacetic acid | 5.28–12.2 | PubChem (2020b)
Chlorodibromoacetic acid | <LOD–5.37 | PubChem (2020d)
Dibromoacetic acid | 2.1(0.63–12)^b^ | EPA (2016b)
Dichloroacetic acid | 10.4(1.3–32)^b^ | EPA (2016b)
Tribromoacetic acid | 0–approx.10 | McGuire et al. (2002)

^a^ LOD = limit of detection(not specified).

^b^ Median (5th percentile–95th percentile).

According to national occurrence data from the American Water Works Association for HAA5 in U.S. water disinfection systems serving populations greater than 100,000 people from 1997 to 2014, 95th percentile HAA5 concentrations generally have been decreasing since 2000 and have been at or below the EPA maximum contaminant level (MCL) of 60 µg/L since 2004 (Seidel et al. 2017). However, there is evidence that smaller facilities might have had more difficulty meeting this regulatory limit; EPA data indicate that from 1997 to 2004, at least 5% of smaller systems (serving fewer than 10,000 people) exceeded the HAA5 MCL. Data on HAA5 for U.S. water facilities serving communities of all sizes in 2011 indicate a median concentration of 20.1 µg/L, with the 5th percentile at 2.0 µg/L and the 95th percentile at 59.0 µg/L.

#### Overall Potential Exposure to Haloacetic Acids

Average daily exposure to mixtures of haloacetic acids from consumption of chlorinated tap water in the United States can be estimated as about 69 µg (5% to 95% = 6.9 to 204 µg) for men and 55 µg (5% to 95% = 5.5 to 162.2 µg) for women, based on median levels of mixtures of haloacetic acids in U.S. water facilities (2011 levels for facilities of all sizes). Daily consumption of water from all foods and liquids by adults over the age of 20 has been estimated by the Centers for Disease Control and Prevention (Rosinger and Herrick 2016) to be 3.46 L for men and 2.75 L for women, with plain tap water accounting for about one third of the total.

#### Sources of Exposure Other Than Drinking Water

In addition to ingesting haloacetic acids by drinking plain tap water, humans can be exposed to them in other beverages prepared with chlorinated water, such as tea, coffee, fruit drinks, and soft drinks, or by eating food that has come in contact with treated water, such as by being rinsed or washed before or after cooking or cooked in chlorinated water. Low levels of haloacetic acids may also be present in natural foods. The median amounts of haloacetic acids in food range from less than 1 µg/kg in milk to over 10 µg/kg in soft drinks, prepared salads, and minimally processed vegetables, such as fruits or vegetables washed with chlorine-based chemicals in water (Cardador and Gallego 2016). The levels of haloacetic acids in canned vegetables, fruit juices, and cheese fall between these levels. The Institute of Medicine has estimated that 20% of total water consumption is derived from foods; in addition to the 33% from tap water, the remaining 47% would derive from beverages such as tea, coffee, soft drinks, and fruit drinks (IOM 2005).

The disinfection of water in swimming pools and spas often results in higher levels of haloacetic acids than in disinfected tap water, because of the use of a higher chlorine residual (level of chlorine remaining after initial treatment) and higher temperatures than in typical water distribution systems (Chowdhury et al. 2014; Parinet et al. 2012). Dichloroacetic acid is the most abundant haloacetic acid detected in swimming pools (Teo et al. 2015); in U.S. swimming pools disinfected with chlorine, its concentration has been reported to range from 52 to 6,800 μg/L (Kanan 2010; Teo et al. 2015). Brominated haloacetic acids (including dibromoacetic, bromodichloroacetic, and chlorodibromoacetic acid) occur at the highest concentrations in seawater swimming pools treated with chlorine bleach as disinfectant; levels of mixtures of haloacetic acids (HAA9) ranged from 417 to 2,233 μg/L in seawater pools tested (Parinet et al. 2012). Dermal exposure (accounting for about 1% of total exposure to haloacetic acids from swimming pools and spas) and inhalation exposure (accounting for about 5% of the exposure) are not considered major routes of exposure, as haloacetic acids are neither volatile nor appreciably absorbed through the skin (Regli et al. 2015; Xu et al. 2002). About 94% of exposure to haloacetic acids from swimming pools is through ingestion of pool water (Cardador and Gallego 2011), and haloacetic acids have been detected in the urine of swimming pool attendants and swimmers. Urinary dichloroacetic acid levels for indoor swimming pool attendants were positively correlated with length of exposure (increasing from 313 ng/L at 2 hours to 450 ng/L at 4 hours) and were higher than those for outdoor pool attendants (51 ng/L at 2 hours) (Cardador and Gallego 2011).

### Regulations

#### Department of Transportation (DOT)

Dichloroacetic acid is considered a hazardous material, and special requirements have been set for marking, labeling, and transporting this material.

#### Environmental Protection Agency (EPA)

##### Safe Drinking Water Act

Maximum contaminant level (MCL) for HAA5 = 60 µg/L.

#### Food and Drug Administration (FDA)

Maximum permissible level of HAA5 in bottled water = 60 µg/L.

### Guidelines

#### American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 0.5 ppm for dichloroacetic acid.

Dichloroacetic acid is listed as a confirmed animal carcinogen with unknown relevance to humans.

Potential for dermal absorption for dichloroacetic acid.

#### Environmental Protection Agency (EPA)

Integrated Risk Information System (IRIS) oral reference dose (RfD) = 4 × 10^−3^ mg/kg b.w. per day for dichloroacetic acid.

IRIS oral cancer slope factor = 5 × 10^−2^ per mg/kg b.w. per day for dichloroacetic acid.

IRIS drinking water unit risk = 1.4 × 10^−6^ per µg/L for dichloroacetic acid.

## References

Anderson WB, Board PG, Gargano B, Anders MW. 1999. Inactivation of glutathione transferase zeta by dichloroacetic acid and other fluorine-lacking α-haloalkanoic acids. Chem Res Toxicol. 12(12):1144–1149. 10.1021/tx990085l 10604862
Austin EW, Parrish JM, Kinder DH, Bull RJ. 1996. Lipid peroxidation and formation of 8-hydroxydeoxyguanosine from acute doses of halogenated acetic acids. Fundam Appl Toxicol. 31(1):77–82. 10.1006/faat.1996.0078 8998956
Calderon RL. 2000. The epidemiology of chemical contaminants of drinking water. Food Chem Toxicol. 38 Suppl 1:S13–S20. 10.1016/S0278-6915(99)00133-7 10717366
Cardador MJ, Gallego M. 2011. Haloacetic acids in swimming pools: Swimmer and worker exposure. Environ Sci Technol. 45(13):5783–5790. 10.1021/es103959d 21648437
Cardador MJ, Gallego M. 2017. Control of disinfection by-products in canned vegetables caused by water used in their processing. Food Addit Contam Part A Chem Anal Control Expo Risk Assess. 34(1):10–23. 10.1080/19440049.2016.1241897 27689419
CDC. 2015. Water Treatment. Atlanta, GA: Centers for Disease Control and Prevention; https://www.cdc.gov/healthywater/drinking/public/water_treatment.html
Celik I, Temur A, Isik I. 2009. Hepatoprotective role and antioxidant capacity of pomegranate (Punica granatum) flowers infusion against trichloroacetic acid-exposed in rats. Food Chem Toxicol. 47(1):145–149. 10.1016/j.fct.2008.10.020 19022327
Cemeli E, Wagner ED, Anderson D, Richardson SD, Plewa MJ. 2006. Modulation of the cytotoxicity and genotoxicity of the drinking water disinfection byproduct iodoacetic acid by suppressors of oxidative stress. Environ Sci Technol. 40(6):1878–1883. 10.1021/es051602r 16570611
Chowdhury S, Alhooshani K, Karanfil T. 2014. Disinfection byproducts in swimming pool: Occurrences, implications and future needs. Water Res. 53:68–109. 10.1016/j.watres.2014.01.017 24509344
Dad A, Jeong CH, Pals JA, Wagner ED, Plewa MJ. 2013. Pyruvate remediation of cell stress and genotoxicity induced by haloacetic acid drinking water disinfection by-products. Environ Mol Mutagen. 54(8):629–637. 10.1002/em.21795 23893730
Daniel FB, DeAngelo AB, Stober JA, Olson GR, Page NP. 1992. Hepatocarcinogenicity of chloral hydrate, 2-chloroacetaldehyde, and dichloroacetic acid in the male B6C3F1 mouse. Fundam Appl Toxicol. 19(2):159–168. 10.1016/0272-0590(92)90147-A 1516771
DeAngelo AB, Daniel FB, Most BM, Olson GR. 1996. The carcinogenicity of dichloroacetic acid in the male Fischer 344 rat. Toxicology. 114(3):207–221. 10.1016/S0300-483X(96)03510-X 8980710
DeAngelo AB, Daniel FB, Stober JA, Olson GR. 1991. The carcinogenicity of dichloroacetic acid in the male B6C3F1 mouse. Fundam Appl Toxicol. 16(2):337–347. 10.1016/0272-0590(91)90118-N 2055364
DeAngelo AB, George MH, House DE. 1999. Hepatocarcinogenicity in the male B6C3F1 mouse following a lifetime exposure to dichloroacetic acid in the drinking water: Dose-response determination and modes of action. J Toxicol Environ Health A. 58(8):485–507. 10.1080/009841099157115 10632141
El Arem A, Ghrairi F, Lahouar L, Thouri A, Saafi EB, Ayed A, Zekri M, Ferjani H, Haouas Z, Zakhama A, et al. 2014 a. Hepatoprotective activity of date fruit extracts against dichloroacetic acid-induced liver damage in rats. J Funct Foods. 9:119–130. 10.1016/j.jff.2014.04.018
El Arem A, Saafi EB, Ghrairi F, Thouri A, Zekri M, Ayed A, Zakhama A, Achour L. 2014 b. Aqueous date fruit extract protects against lipid peroxidation and improves antioxidant status in the liver of rats subchronically exposed to trichloroacetic acid. J Physiol Biochem. 70(2):451–464. 10.1007/s13105-014-0323-6 24573459
El Arem A, Zekri M, Thouri A, Saafi EB, Ghrairi F, Ayed A, Zakhama A, Achour L. 2014 c. Oxidative damage and alterations in antioxidant enzyme activities in the kidneys of rat exposed to trichloroacetic acid: Protective role of date palm fruit. J Physiol Biochem. 70(2):297–309. 24338383
EPA. 2016a. Conventional Treatment. Washington, DC: U.S. Environmental Protection Agency; https://tdb.epa.gov/tdb/treatmentprocess?treatmentProcessId=1934681921
EPA. 2016b. Six-Year Review 3 Compliance Monitoring Data (2006-2011). Washington, DC: U.S. Environmental Protection Agency; https://www.epa.gov/dwsixyearreview/six-year-review-3-compliance-monitoring-data-2006-2011
Ge R, Yang S, Kramer PM, Tao L, Pereira MA. 2001. The effect of dichloroacetic acid and trichloroacetic acid on DNA methylation and cell proliferation in B6C3F1 mice. J Biochem Mol Toxicol. 15(2):100–106. 10.1002/jbt.5 11284051
Gonzalez-Leon A, Merdink JL, Bull RJ, Schultz IR. 1999. Effect of pre-treatment with dichloroacetic or trichloroacetic acid in drinking water on the pharmacokinetics of a subsequent challenge dose in B6C3F1 mice. Chem Biol Interact. 123(3):239–253. 10.1016/S0009-2797(99)00140-4 10654841
Herren-Freund SL, Pereira MA, Khoury MD, Olson G. 1987. The carcinogenicity of trichloroethylene and its metabolites, trichloroacetic acid and dichloroacetic acid, in mouse liver. Toxicol Appl Pharmacol. 90(2):183–189. 10.1016/0041-008X(87)90325-5 3629594
IARC. 2013. Some chemicals present in industrial and consumer products, food and drinking-water. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans, vol. 101. Lyon, France: International Agency for Research on Cancer.
IARC. 2014. Dichloroacetic acid. In Trichloroethylene, Tetrachloroethylen, and Some Other Chlorinated Agents. IARC Monographs on the Evaluation of Carcinogenic Risks to Humansm, vol. 106. Lyon, France: International Agency for Research on Cancer. pp. 353–391.
IOM. 2005. Dietary Reference Intakes: Water, Potassium, Sodium, Chloride, and Sulfate. Washington, DC: National Academies Press; https://www.nationalacademies.org/hmd/Reports/2004/Dietary-Reference-Intakes-Water-Potassium-Sodium-Chloride-and-Sulfate.aspx
Jones RR, Weyer PJ, Dellavalle CT, Robein K, Cantor KP, Krasner S, Beane Freeman LE, Ward MH. 2017. Ingested nitrate, disinfection by-products, and kidney cancer risk in older women. Epidemiology. 28(5):703–711. 10.1097/EDE.0000000000000647 28252454
Kanan A. 2010. Occurrence and Formation of Disinfection By-products in Indoor Swimming Pools Water [dissertation]. Clemson, SC: Clemson University; https://tigerprints.clemson.edu/cgi/viewcontent.cgi?article=1532&context=all_dissertations.
Kargalioglu Y, McMillan BJ, Minear RA, Plewa MJ. 2002. Analysis of the cytotoxicity and mutagenicity of drinking water disinfection by-products in Salmonella typhimurium. Teratog Carcinog Mutagen. 22(2):113–128. 10.1002/tcm.10010 11835289
Krasner SW, Kostopoulou M, Toledano MB, Wright J, Patelarou E, Kogevinas M, Villanueva CM, Carrasco-Turigas G, Santa Marina L, Fernández-Somoano A, et al. 2016. Occurrence of DBPs in drinking water of european regions for epidemiology studies. J Am Water Works Assoc. 108(10):E501–E512. 10.5942/jawwa.2016.108.0152
Krasner SW, Weinberg HS, Richardson SD, Pastor SJ, Chinn R, Sclimenti MJ, Onstad GD, Thruston AD Jr. 2006. Occurrence of a new generation of disinfection byproducts. Environ Sci Technol. 40(23):7175–7185. 10.1021/es060353j 17180964
Larson JL, Bull RJ. 1992. Metabolism and lipoperoxidative activity of trichloroacetate and dichloroacetate in rats and mice. Toxicol Appl Pharmacol. 115(2):268–277. 10.1016/0041-008X(92)90332-M 1641860
McGuire MJ, McLain JL, Obolensky A. 2002. Information Collection Rule Data Analysis. Denver, CO: AWWA Research Foundation and American Water Works Association.
Merdink JL, Bull RJ, Schultz IR. 2000. Trapping and identification of the dichloroacetate radical from the reductive dehalogenation of trichloroacetate by mouse and rat liver microsomes. Free Radic Biol Med. 29(2):125–130. 10.1016/S0891-5849(00)00330-0 10980401
NTP. 2007. Toxicology and Carcinogenesis Studies of Dibromoacetic Acid (CAS No. 631-64-1) in F344/N Rats and B6C3F1 Mice (Drinking Water Studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 537. NIH Publication No. 07-4475.
NTP. 2009. Toxicology and Carcinogenesis Studies of Bromochloroacetic Acid (CAS No. 5589-96-8) in F344/N Rats and B6C3F1 Mice (Drinking Water Studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 549. NIH Publication No. 09-5890.
NTP. 2015. Toxicology Studies of Bromodichloroacetic Acid (CAS No. 71133-14-7) in F344/N Rats and B6C3F1/N Mice and Toxicology and Carcinogenesis Studies of Bromodichloroacetic Acid in F344/Ntac Rats and B6C3F1/N Mice (Drinking Water Studies). Research Triangle Park, NC: National Toxicology Program. NTP TR 583.
NTP. 2018. Report on Carcinogens Monograph on Haloacetic Acids Found as Water Disinfection By-products. Research Triangle Park, NC: National Toxicology Program; https://ntp.niehs.nih.gov/ntp/roc/monographs/haafinal_508.pdf
Ondricek AJ, Kashyap AK, Thamake SI, Vishwanatha JK. 2012. A comparative study of phytoestrogen action in mitigating apoptosis induced by oxidative stress. In Vivo. 26(5):765–775. 22949589
Pals JA, Ang JK, Wagner ED, Plewa MJ. 2011. Biological mechanism for the toxicity of haloacetic acid drinking water disinfection byproducts. Environ Sci Technol. 45(13):5791–5797. 10.1021/es2008159 21671678
Parinet J, Tabaries S, Coulomb B, Vassalo L, Boudenne JL. 2012. Exposure levels to brominated compounds in seawater swimming pools treated with chlorine. Water Res. 46(3):828–836. 10.1016/j.watres.2011.11.060 22153961
Pereira MA. 1996. Carcinogenic activity of dichloroacetic acid and trichloroacetic acid in the liver of female B6C3F1 mice. Fundam Appl Toxicol. 31(2):192–199. 10.1006/faat.1996.0091 8789785
Pereira MA, Kramer PM, Conran PB, Tao L. 2001. Effect of chloroform on dichloroacetic acid and trichloroacetic acid-induced hypomethylation and expression of the c-myc gene and on their promotion of liver and kidney tumors in mice. Carcinogenesis. 22(9):1511–1519. 10.1093/carcin/22.9.1511 11532874
Plewa MJ, Cemeli E, Anderson D, Wagner E. 2004. The genotoxicity of the drinking water disinfection by-product iodoacetic acid is reduced by modulators of oxidative stress. Environ Mol Mutagen. 44(3):220.
PubChem. 2020a. Compound Summary: Bromochloroacetic Acid. Bethesda, MD: National Library of Medicine; https://pubchem.ncbi.nlm.nih.gov/compound/542762
PubChem. 2020b. Compound Summary: Bromodichloroacetic Acid. Bethesda, MD: National Library of Medicine; https://pubchem.ncbi.nlm.nih.gov/compound/114809
PubChem. 2020c. Compound Summary: Dibromoacetic Acid. Bethesda, MD: National Library of Medicine; https://pubchem.ncbi.nlm.nih.gov/compound/12433
PubChem. 2020d. Compound Summary: Dibromochloroacetic Acid. Bethesda, MD: National Library of Medicine; https://pubchem.ncbi.nlm.nih.gov/compound/115266
PubChem. 2020e. Compound Summary: Dichloroacetic Acid. Bethesda, MD: National Library of Medicine; https://pubchem.ncbi.nlm.nih.gov/compound/6597
PubChem. 2020f. Compound Summary: Tribromoacetic Acid. Bethesda, MD: National Library of Medicine; https://pubchem.ncbi.nlm.nih.gov/compound/6415
Regli S, Chen J, Messner M, Elovitz MS, Letkiewicz FJ, Pegram RA, Pepping TJ, Richardson SD, Wright JM. 2015. Estimating potential increased bladder cancer risk due to increased bromide concentrations in sources of disinfected drinking waters. Environ Sci Technol. 49(22):13094–13102. 10.1021/acs.est.5b03547 26489011
Rosinger A, Herrick K. 2016. Daily Water Intake Among U.S. Men and Women, 2009-2012. Hyattsville, MD: CDC, National Center for Health Statistics. NCHS Data Brief No. 242.
Saghir SA, Ghanayem BI, Schultz IR. 2011. Kinetics of trihalogenated acetic acid metabolism and isoform specificity in liver microsomes. Int J Toxicol. 30(5):551–561. 10.1177/1091581811414213 21933969
Saghir SA, Schultz IR. 2005. Toxicokinetics and oral bioavailability of halogenated acetic acids mixtures in naive and GSTzeta-depleted rats. Toxicol Sci. 84(2):214–224. 10.1093/toxsci/kfi070 15625187
Schultz IR, Merdink JL, Gonzalez-Leon A, Bull RJ. 1999. Comparative toxicokinetics of chlorinated and brominated haloacetates in F344 rats. Toxicol Appl Pharmacol. 158(2):103–114. 10.1006/taap.1999.8698 10406925
Seidel CJ, Samson CC, Bartrand T, Ergul A, Summers RS. 2017. Disinfection byproduct occurrence at large water systems after stage 2 DBPR. J Am Water Works Assoc. 109(7):17–30. 10.5942/jawwa.2017.109.0082
Stacpoole PW, Henderson GN, Yan Z, James MO. 1998. Clinical pharmacology and toxicology of dichloroacetate. Environ Health Perspect. 106 Suppl 4:989–994. 9703483
Stalter D, O’Malley E, von Gunten U, Escher BI. 2016. Fingerprinting the reactive toxicity pathways of 50 drinking water disinfection by-products. Water Res. 91:19–30. 10.1016/j.watres.2015.12.047 26773486
Tao L, Yang S, Xie M, Kramer PM, Pereira MA. 2000. Hypomethylation and overexpression of c-jun and c-myc protooncogenes and increased DNA methyltransferase activity in dichloroacetic and trichloroacetic acid-promoted mouse liver tumors. Cancer Lett. 158(2):185–193. 10.1016/S0304-3835(00)00518-8 10960769
Teo TL, Coleman HM, Khan SJ. 2015. Chemical contaminants in swimming pools: Occurrence, implications and control. Environ Int. 76:16–31. 10.1016/j.envint.2014.11.012 25497109
Villanueva CM, Gracia-Lavedan E, Bosetti C, Righi E, Molina AJ, Martín V, Boldo E, Aragonés N, Perez-Gomez B, Pollan M, et al. 2017. Colorectal cancer and long-term exposure to trihalomethanes in drinking water: A multicenter case-control study in Spain and Italy. Environ Health Perspect. 125(1):56–65. 10.1289/EHP155 27383820
Wood CE, Hester SD, Chorley BN, Carswell G, George MH, Ward W, Vallanat B, Ren HZ, Fisher A, Lake AD, et al. 2015. Latent carcinogenicity of early-life exposure to dichloroacetic acid in mice. Carcinogenesis. 36(7):782–791. 10.1093/carcin/bgv057 25913432
Xu X, Mariano TM, Laskin JD, Weisel CP. 2002. Percutaneous absorption of trihalomethanes, haloacetic acids, and haloketones. Toxicol Appl Pharmacol. 184(1):19–26. 10.1006/taap.2002.9494 12392965