# Dimethylvinyl Chloride

CAS No. 513-37-1

Reasonably anticipated to be a human carcinogen

First listed in the Sixth Annual Report on Carcinogens (1991)

Also known as 1-chloro-2-methylpropene

Figure 1

Chemical Structure of Dimethylvinyl Chloride

## Carcinogenicity

Dimethylvinyl chloride is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Oral exposure to dimethylvinyl chloride caused tumors in mice and rats at several different tissue sites. Administration of dimethylvinyl chloride by stomach tube caused forestomach cancer (squamous-cell carcinoma) in both sexes of both species, preputial-gland cancer (squamous-cell carcinoma) in male mice, nasal-cavity cancer (carcinoma and adenocarcinoma) in rats of both sexes, and oral-cavity cancer (squamous-cell carcinoma) in male rats. It also increased the combined incidence of benign and malignant tumors (squamous-cell papilloma and carcinoma) of the oral cavity in females and the esophagus in males (NTP 1986).

Since dimethylvinyl chloride was listed in the Sixth Annual Report on Carcinogens, one additional study in mice has been identified. In female Tg.AC mice (a transgenic mouse strain that carries the v-Ha-ras oncogene), exposure to dimethylvinyl chloride by stomach tube caused benign forestomach tumors (papilloma) (Cannon et al. 2000).

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to dimethylvinyl chloride.

## Properties

Dimethylvinyl chloride is a halogenated alkene that is a structural analogue of vinyl chloride monomer. It exists as a clear, colorless to brown liquid at room temperature (IARC 1995). It is slightly soluble in water, soluble in alcohol, ether, and acetone, and very soluble in chloroform. Dimethylvinyl chloride is flammable and polymerizes easily (Akron 2009). Physical and chemical properties of dimethylvinyl chloride are listed in Table 1.

Table 1 Properties of Dimethylvinyl Chloride

Property | Information
Molecular weight | 90.6^a^
Specific gravity | 0.92 at 20°C/4°C^a^
Boiling point | 68°C at 754 mm Hg^a^
Log K_ow_ | 2.58^b^
Water solubility | 1 g/L at 25°C^b^
Vapor pressure | 158 mm Hg at 25°C^a^

Sources: ^a^HSDB (2009), ^b^ChemIDplus (2009).

## Use

Dimethylvinyl chloride is not used commercially, but is used for research purposes. It has been used in organic syntheses and as a chemical intermediate for the production of isobutylene compounds for laboratory use (HSDB 2009; IARC 1995).

## Production

Dimethylvinyl chloride is not produced for commercial use in the United States (HSDB 2009). In 2009, no commercial producers were identified worldwide, but dimethylvinyl chloride was available from seven suppliers, including four U.S. suppliers (ChemSources 2009). Dimethylvinyl chloride is a by-product in the production of 3-chloro-2-methylpropene from isobutylene (HSDB 2009; NTP 1986).

## Exposure

Inhalation is the primary route of potential human exposure to dimethylvinyl chloride. In 1982, it was detected at concentrations ranging from 90 to 670 μg/m^3^ in ambient-air samples collected near industrial complexes and chemical-waste-disposal sites (IARC 1995). In air, dimethylvinyl chloride will exist in the vapor phase and is expected to degrade with a half-life of about 21 hours by reaction with photochemically produced hydroxyl radicals or 26 hours by reaction with atmospheric ozone, or to be removed by wet deposition. In water, dimethylvinyl chloride is not expected to adsorb to sediment or to bioconcentrate, but is expected to volatilize rapidly, with a half-life of 2.9 hours in a model river and 3.8 days in a model lake. Dimethylvinyl chloride is expected to have high mobility in soil and to volatilize from either moist or dry soil.

Occupational exposure may occur during the production of 3-chloro-2-methylpropene, of which dimethylvinyl chloride is an unintended by-product. The U.S. Environmental Protection Agency estimated that 8 to 12 workers potentially were exposed to dimethylvinyl chloride during the production of 3-chloro-2-methylpropene (EPA 1985; HSDB 2009).

## Regulations

No specific regulations or guidelines relevant to reduction of exposure to dimethylvinyl chloride were identified.

## References

Akron. 2009. The Chemical Database. Akron, OH: The Department of Chemistry at the University of Akron; http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Cannon RE, Graves S, Spalding JW, Trempus CS, Tennant RW. 2000. Oral administration of dimethylvinyl chloride increases frequency of forestomach papillomas in Tg.AC mice. Mol Carcinog. 29(4):229–235. 10.1002/1098-2744(200012)29:4<229::AID-MC1005>3.0.CO;2-9 11170261
ChemIDplus. 2009. ChemIDplus Advanced. Bethesda, MD: National Library of Medicine; http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Pendleton, SC: Chemical Sources International; http://www.chemsources.com/chemonline.html and search on dimethylvinyl chloride.
EPA. 1985. Existing Chemical Evaluation, Summary Report on 3-Chloro-2-Methylpropene. Washington, DC: U.S. Environmental Protection Agency.
HSDB. 2009. Hazardous Substances Data Bank. Bethesda, MD: National Library of Medicine; http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS Number.
IARC. 1995. 1-Chloro-2-methylpropene. In Dry Cleaning, Some Chlorinated Solvents and Other Industrial Chemicals. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 63. Lyon, France: International Agency for Research on Cancer. pp. 315–324.
NTP. 1986. Toxicology and Carcinogenesis Studies of Dimethylvinyl Chloride (1-Chloro-2-methylpropene) (CAS No. 513-37-1) in F344/N Rats and B6C3F_1_ Mice (Gavage Studies). Research Triangle Park, NC: National Toxicology Program. Technical Report Series No. 316. NIH Publication No. 86-2572.