# Cyclophosphamide

CAS No. 50-18-0

Known to be a human carcinogen

First listed in the First Annual Report on Carcinogens (1980)

Figure 1

Chemical Structure of Cyclophosphamide

## Carcinogenicity

Cyclophosphamide is known to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in humans.

### Cancer Studies in Humans

Several epidemiological studies consistently found excesses of urinary-bladder cancer and leukemia among people treated with cyclophosphamide for various medical conditions. A case-control study in Germany found that the risk of leukemia increased with increasing dose of cyclophosphamide (IARC 1981; 1987). More recently, a nested case-control study of non-Hodgkin lymphoma patients reported that the risk of urinary-bladder cancer increased with increasing cumulative dose of cyclophosphamide (Travis et al. 1995).

### Cancer Studies in Experimental Animals

There is sufficient evidence for the carcinogenicity of cyclophosphamide from studies in experimental animals. Exposure to cyclophosphamide caused tumors in two rodent species, at several different tissue sites, and by several different routes of exposure (IARC 1981). In rats, exposure to cyclophosphamide in drinking water or by intravenous injection caused benign and malignant tumors at various tissue sites, including the urinary bladder. Cyclophosphamide administered by intraperitoneal injection to female rats caused benign and malignant mammary-gland tumors. In mice, cyclophosphamide administered by subcutaneous or intraperitoneal injection caused leukemia, lymphoma, and benign and malignant tumors at various sites, including the lung, liver, mammary gland, and injection site (IARC 1981; 1987).

## Properties

Cyclophosphamide is an antineoplastic and immunosuppressant agent that is usually a fine white crystalline powder at room temperature. The substance liquefies and becomes an oily semisolid mass when water is removed under high vacuum. It is soluble in water, alcohol, chloroform, dioxane, and glycols, slightly soluble in benzene and carbon tetrachloride, very slightly soluble in ether and acetone, and insoluble in carbon disulfide. Cyclophosphamide is sensitive to oxidation, moisture, and light (Akron 2009). Physical and chemical properties of cyclophosphamide are listed in Table 1.

Table 1 Properties of Cyclophosphamide

Property | Information
Molecular weight | 261.1^a^
Density | 1.479 g/cm^3b^
Melting point | 49.5°C to 53°C^a^
Boiling point | 336°C^b^
Log K_ow_ | 0.63^a^
Water solubility | 40 g/L at 20°C^a^
Vapor pressure | 4.45 × 10^−5^ mm Hg at 25°C^c^
Dissociation constant (pK_b_) | 9.91^b^

Sources: ^a^HSDB (2009), ^b^Akron (2009), ^c^ChemIDplus (2009).

## Use

Cyclophosphamide is used as a drug to treat cancer and other medical conditions. In chemotherapy, it may be used alone, but more frequently is used concurrently or sequentially with other anticancer drugs. Cyclophosphamide is available in the United States as 25- or 50-mg tablets, as an oral solution, or in a crystalline hydrate form for injection in strengths of 100 to 2,000 mg. It is used to treat malignant lymphoma, multiple myeloma, leukemia, breast and ovarian cancer, neuroblastoma, retinoblastoma, and mycosis fungoides (MedlinePlus 2009; RxList 2010). Cyclophosphamide is also used as an immunosuppressive agent following organ transplants or to treat autoimmune disorders such as rheumatoid arthritis, Wegener granulomatosis, and nephrotic syndrome in children (Chabner et al. 2001). Researchers have tested cyclophosphamide for use as an insect chemosterilant and in the chemical shearing of sheep (IARC 1975).

## Production

Cyclophosphamide is not produced in the United States, and no data on U.S. imports were found. Total U.S. sales were 600 kg (1,300 lb) annually in the mid 1970s (IARC 1975); more recent data were not found. In 2009, cyclophosphamide was available from seven U.S. suppliers (ChemSources 2009), and drug products approved by the U.S. Food and Drug Administration containing cyclophosphamide as the active ingredient were produced by eleven U.S. pharmaceutical companies (FDA 2009).

## Exposure

The general population is not expected to be exposed to cyclophosphamide, because its use is limited to medical treatment. An estimated 500,000 patients worldwide are treated with cyclophosphamide annually (Travis et al. 1995). Doses used in medical treatment depend on the patient and the specific disease. Cyclophosphamide may be given orally (in 25- or 50-mg tablet form) or by intravenous injection (from 100-, 200-, or 500-mg or 1- or 2-g vials) (FDA 2009). The initial treatment for cancer patients with no hematologic deficiency may be 40 to 50 mg/kg of body weight in divided intravenous doses over two to five days; other regimens are 10 to 15 mg/kg every seven to ten days or 3 to 5 mg/kg twice a week. The adult dosage for tablets typically is 1 to 5 mg/kg per day for both initial and maintenance treatment of cancer. For nonmalignant diseases, an oral dose of 2.5 to 3 mg/kg per day is administered for 60 to 90 days (RxList 2010). In 2009, 1,564 clinical trials using cyclophosphamide were in progress or recently completed (ClinicalTrials 2009).

Occupational exposure may occur from skin contact or inhalation of dust during drug formulation or packaging. Health professionals who handle cyclophosphamide, such as pharmacists, nurses, and physicians, could potentially be exposed during drug preparation, administration, or cleanup; however, exposure can be avoided through the use of appropriate containment equipment and work practices (Zimmerman et al. 1981). In a cross-sectional study of hospital workers, handling of cyclophosphamide was clearly related to its detection in the urine (Evelo et al. 1986). Of 62 urine samples collected from 17 nurses and pharmacy technicians who prepared or administered antineoplastic drugs, including cyclophosphamide, 18 contained cyclophosphamide, at concentrations ranging from 50 ng/L (the limit of detection) to 10,030 ng/L. The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 30,026 workers, including 20,745 women, potentially were exposed to cyclophosphamide (NIOSH 1990).

## Regulations

### Consumer Product Safety Commission (CPSC)

Any orally administered prescription drug for human use requires child-resistant packaging.

### Environmental Protection Agency (EPA)

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 10 lb.

#### Resource Conservation and Recovery Act

Listed Hazardous Waste: Waste code for which the listing is based wholly or partly on the presence of cyclophosphamide = U058.

Listed as a hazardous constituent of waste.

### Food and Drug Administration (FDA)

Cyclophosphamide is a prescription drug subject to labeling and other requirements.

## Guidelines

### National Institute for Occupational Safety and Health (NIOSH)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

### Occupational Safety and Health Administration (OSHA)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 11/14/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Chabner BA, Ryan DP, Paz-Ares L, Garcia-Carbonero R, Calabresi P. 2001. Antineoplastic agents. In Hardman JG, Limbird LE, Gilman AG, editors. Goodman & Gilman’s The Pharmacological Basis of Therapeutics, 10th ed. New York, NY: McGraw Hill. pp. 1389–1459.
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 11/14/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 10/22/09. http://www.chemsources.com/chemonline.html and search on cyclophosphamide.
ClinicalTrials. 2009. Cyclophosphamide. ClinicalTrials.gov. National Institutes of Health; Last accessed: 10/29/09. http://clinicaltrials.gov/ct2/results?term=azacitidine
Evelo CTA, Bos RP, Peters JGP, Henderson PT. 1986. Urinary cyclophosphamide assay as a method for biological monitoring of occupational exposure to cyclophosphamide. Int Arch Occup Environ Health. 58(2):151–155. 10.1007/BF00380766 3744569
FDA. 2009. The Electronic Orange Book. U.S. Food and Drug Administration; Last accessed: 10/26/09. https://www.fda.gov/cder/ob/default.htm and select Search by Active Ingredient and search on cyclophosphamide.
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 10/22/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search CAS on number.
IARC. 1975. Cyclophosphamide. In Some Aziridines, N-, S-, and O-Mustards and Selenium. IARC Monographs on the Evaluation of Carcinogenic Risk of Chemicals to Humans, vol. 9. Lyon, France: International Agency for Research on Cancer. pp. 135–156.
IARC. 1981. Cyclophosphamide. In Some Antineoplastic and Immunosuppressive Agents. IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans, vol. 26. Lyon, France: International Agency for Research on Cancer. pp. 165–202.
IARC. 1987. Cyclophosphamide. In Overall Evaluations of Carcinogenicity. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, suppl. 7. Lyon, France: International Agency for Research on Cancer. pp. 182–184.
MedlinePlus. 2009. Cyclophosphamide. National Library of Medicine; Last accessed: 1/7/10. https://www.nlm.nih.gov/medlineplus/druginfo/meds/a682080.html
NIOSH. 1990. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/x3688sic.html
RxList. 2010. Cytoxan. RxList: The Internet Drug Index; Last accessed: 1/7/10. https://www.rxlist.com/cytoxan-drug.htm
Travis LB, Curtis RE, Glimelius B, Holowaty EJ, Van Leeuwen FE, Lynch CF, Hagenbeek A, Stovall M, Banks PM, Adami J, et al. 1995. Bladder and kidney cancer following cyclophosphamide therapy for non-Hodgkin’s lymphoma. J Natl Cancer Inst. 87(7):524–530. 10.1093/jnci/87.7.524 7707439
Zimmerman PF, Larsen RK, Barkley EW, Gallelli JF. 1981. Recommendations for the safe handling of injectable antineoplastic drug products. Am J Hosp Pharm. 38(11):1693–1695. 10.1093/ajhp/38.11.1693 7304621