# Chloroform

CAS No. 67-66-3

Reasonably anticipated to be a human carcinogen

First listed in the Second Annual Report on Carcinogens (1981)

Figure 1

Chemical Structure of Chloroform

## Carcinogenicity

Chloroform is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals.

### Cancer Studies in Experimental Animals

Oral exposure to chloroform caused tumors in two rodent species and at two different tissue sites. Administration of chloroform by stomach tube caused liver cancer (hepatocellular carcinoma) in mice of both sexes (NCI 1976) and kidney tumors (epithelial tumors) in male mice and rats (IARC 1979; Roe et al. 1979).

Since chloroform was listed in the Second Annual Report on Carcinogens, additional studies in rodents have been identified, which reported that chloroform caused liver and kidney tumors by additional routes of exposure. Benign liver tumors (adenoma) were observed in female rats administered chloroform in the drinking water (IARC 1987; 1999) and female mice exposed by inhalation (Yamamoto et al. 2002). Benign and malignant kidney tumors (tubular-cell adenoma, carcinoma, or adenocarcinoma) were observed in male rats exposed via the drinking water (IARC 1987; 1999), male mice exposed by inhalation (Yamamoto et al. 2002), and male rats following combined exposure via inhalation and the drinking water (Nagano et al. 2006).

### Cancer Studies in Humans

No epidemiological studies were identified that evaluated the relationship between human cancer and exposure specifically to chloroform. Two community-based studies of exposure to chlorinated water found excesses of cancer at several tissue sites, particularly the urinary bladder (Cantor et al. 1978; Hogan et al. 1979), but a causal relationship could not be inferred (IARC 1982).

Since chloroform was listed in the Second Annual Report on Carcinogens, additional epidemiological studies have been identified, mostly involving exposure to chlorinated water, which may contain chloroform and other chlorinated hydrocarbons, via drinking, bathing, showering, or swimming. The International Agency for Research on Cancer (IARC 1999) concluded that a causal relationship between cancer and chloroform could not be inferred, because of the use of indirect methods of assessing exposure, incomplete control for confounding by exposure to other water impurities or other risk factors, and differing results for men and women. Overall, cohort and case-control studies found a relationship between exposure to chlorinated water and the risk of some types of cancer, particularly of the urinary bladder and rectum and possibly of the colon (IARC 1982; 1987; 1999).

Since the last IARC review, additional community-based studies have been identified, which have examined cancer risks associated with estimated exposure to chlorinated drinking water. Several studies, including a pooled analysis of six case-control studies, reported associations of urinary-bladder cancer with overall trihalomethane exposure (Chang et al. 2007; Michaud et al. 2007; Villanueva et al. 2004; Villanueva et al. 2007); two studies found an exposure-response relationship for men but not women (Villanueva et al. 2004; Villanueva et al. 2007). One study also found an association in men between urinary-bladder cancer and exposure to trihalomethanes via bathing, showering, or swimming in pools (Villanueva et al. 2007). Some studies also reported associations between colorectal cancer and overall trihalomethane exposure (King et al. 2000; Kuo et al. 2009; Kuo et al. 2010). Few studies of drinking-water exposure attempted to distinguish the risk associated specifically with exposure to chloroform, and none controlled adequately for exposure to other trihalomethanes or other risk factors. However, one study found a significantly elevated risk of urinary-bladder cancer associated with high levels of chloroform in drinking water (Bove et al. 2007).

## Properties

Chloroform is a trihalomethane that exists at room temperature as a clear, colorless, highly refractive heavy liquid with a pleasant ethereal odor (Akron 2009; HSDB 2009). It is slightly soluble in water, soluble in carbon disulfide, and miscible with alcohol, ether, benzene, carbon tetrachloride, and fixed and volatile oils (HSDB 2009). Chloroform is stable under normal temperatures and pressures in a closed container (Akron 2009). It is light sensitive and may decompose slowly in the presence of sunlight and in the dark in the presence of air (IARC 1979). Physical and chemical properties of chloroform are listed in Table 1.

Table 1 Properties of Chloroform

Property | Information
Molecular weight | 119.4^a^
Specific gravity | 1.4888 at 25°C/25°C^a^
Melting point | −63.41°C^a^
Boiling point | 61.2°C^a^
Log K_ow_ | 1.97^a^
Water solubility | 7.950 g/L at 25°C^b^
Vapor pressure | 197 mm Hg at 25°C^a^
Vapor density relative to air | 4.12^a^

Sources: ^a^HSDB (2009), ^b^ChemIDplus (2009).

## Use

In 2007, about 95% of the chloroform produced in the United States was used to make chlorodifluoromethane (HCFC-22, also known as R-22); 62% of HCFC-22 was used as a refrigerant, and 33% was used in the production of fluoropolymers (HSDB 2009). However, the use of HCFC-22 is being phased out under the 1987 Montreal Protocol, and as of January 1, 2010, manufacturers were not allowed to produce new air conditioners or heat pumps containing HCFC-22 (EPA 2010). The remaining chloroform produced has miscellaneous uses, including as a solvent or an extraction solvent for lacquers, floor polishes, adhesives in artificial silk manufacturing, resins, fats, greases, gums, waxes, oils, alkaloids, penicillin, vitamins, flavors, and rubber; as a dry-cleaning spot remover; in fire extinguishers; as an intermediate in the preparation of dyes and pesticides; and as a fumigant for stored grain crops (ATSDR 1997; HSDB 2009; IARC 1979). It may also be used as a local anesthetic in certain dental endodontic surgeries and in aspirin-chloroform mixtures applied topically to relieve pain from severe cases of herpes or post-therapeutic neuralgia (ATSDR 1997; HSDB 2009).

Before 1976, chloroform was used in a wide variety of drug products, including cough syrups, antihistamines, and decongestants (IARC 1979). In the 1970s, the U.S. Food and Drug Administration banned drugs containing chloroform and also banned its use in cosmetics because of its carcinogenicity. However, it did not ban drug products that contain chloroform in residual amounts resulting from its use as a solvent in manufacturing or its presence as a by-product from the synthesis of drug ingredients (ATSDR 1997; IARC 1979). An approved new drug application is required for marketing any drug product containing chloroform (FDA 1999).

## Production

One U.S. manufacturer began chloroform production in 1903, but commercial production was not reported until 1922 (IARC 1979). From the early 1980s to the mid 1990s, the annual production of chloroform increased by 20% to 25%, primarily because of the great demand for the refrigerant HCFC-22 (ATSDR 1997). The U.S. Environmental Protection Agency (EPA 2016) estimated that in 2015, combined U.S. production plus imports fell in the range of 1 to 5 billion pounds. In 2009, chloroform was available from 105 suppliers, including 42 U.S. suppliers (ChemSources 2009). In the late 1980s, U.S. imports of chloroform were as high as 38 million pounds and exports as low as 33.5 million pounds. Since then, both imports and exports have fluctuated considerably, with exports greatly exceeding imports. More recent volumes of U.S. chloroform production, imports, and exports are shown in Table 2.

Table 2 Production, Imports, and Exports of Chloroform

Category | Year | Quantity (lb)
Production + imports^a^ | 2015 | 1 billion to 5 billion
U.S. imports^b^ | 2017 | 2.5 million
U.S. exports^b^ | 2017 | 74.3 million

Sources: ^a^EPA (2016). ^b^USITC (2018).

## Exposure

Evidence that people in the United States are exposed to chloroform is provided by the 2013–2014 National Health and Nutrition Examination Survey, which found that the 95th-percentile concentration of chloroform in whole blood for the U.S. general population was 40.0 pg/mL, based on samples from 3,136 individuals of all ages, both genders, and all race and ethnicity groups (CDC 2018). Exposure to chlorinated water is expected to be a primary source of human exposure to chloroform, because many public water supplies and swimming pools contain trihalomethanes as by-products of chlorination for disinfection purposes. Chloroform is the most prevalent trihalomethane in treated water. Most exposure of the general population occurs during the use of chlorine-treated water for showering, swimming, cleaning, drinking, or cooking (ATSDR 1997; HSDB 2009; IARC 1979; 1999).

Chloroform’s concentration in water systems is not constant over time or location, because trihalomethane concentrations increase with the length of time the water remains in the distribution system (Ashley et al. 2005). Typical daily levels of adult exposure to chloroform from drinking water are estimated to range from 0.199 to 1.89 μg/kg of body weight (WHO 2004). Foods such as dairy products, oils and fats, vegetables, bread, and beverages may also contain small amounts of chloroform (HSDB 2009; IARC 1999), resulting in an estimated average daily intake of 0.043 to 0.478 μg/kg of body weight for adults aged 20 to 59 years (WHO 2004).

Chloroform is also present in the ambient air, surface water, ground water, and soil. According to EPA’s Toxics Release Inventory, environmental releases of chloroform declined steadily from about 28 million pounds in 1988 to 706,555 lb in 2007, when it was released from 67 facilities (TRI 2009). Chloroform has been detected in the atmosphere at concentrations ranging from 0.10 to 10.0 μg/m^3^ in urban areas in the United States and in indoor air at 0.17 to 43.9 μg/m^3^ (WHO 2004). It has also been measured in surface water in rivers, lakes, and oceans, and in precipitation. The highest concentration recently measured in a U.S. river was 2.1 μg/L (McCulloch 2003). In open oceans and estuaries, the highest reported concentration was 70 μg/L in the estuary of the Mersey River, in England (Zok et al. 1998). Chloroform has also been measured in snowpack in the Antarctic, Italy, and Germany, at a maximum concentration of 380 ng/kg (0.00038 mg/kg) in Antarctic snow (Zoccolillo et al. 2007). Contamination of groundwater by chloroform was found at the site of a plutonium processing facility near Knoxville, Tennessee, at a mean concentration of 0.108 mg/L (Datskou and North 1996). Chloroform was measured at 1.1 mg/kg in soil samples taken from a small garden in Spain irrigated with chlorine-treated tap water (Campillo et al. 2004).

If exposure to chloroform through inhalation of ambient air and indoor air and through ingestion of food are added to exposure through ingestion of drinking water, daily adult exposure is estimated to range from 0.70 μg/kg to over 3.0 μg/kg of body weight. Exposure due to daily showering (inhalation and dermal) alone is estimated to add 0.36 to 3.4 μg/kg. Two studies reported changes in chloroform concentrations in the blood as a result of household water use, including showering, bathing, and hand washing of dishes (Ashley et al. 2005; Nuckols et al. 2005). The concentration of chloroform in the blood increased 2- to 7-fold after showering; at two study sites, the median water concentrations of chloroform were 8 and 85 ppb, and the median blood concentrations after showering were 57 and 280 ppt (ng/L) (Nuckols et al. 2005). Ingestion of drinking water caused little elevation in blood levels of chloroform; however, the use of hot water during showering, bathing, and hand washing of dishes caused significant peaks in chloroform blood concentrations. Dermal absorption of chloroform is affected by water temperature during bathing. Among 10 subjects, the mean amount of chloroform exhaled was 0.2 μg at the lowest bath-water temperature (30°C) and 7 μg at the highest temperature (40°C), for a 35-fold increase (Gordon et al. 1998).

Several studies have shown that inhalation and dermal exposure to chloroform are important during swimming. Lindstrom et al. (1997) measured dermal and inhalation exposure to chloroform from swimming in a chlorinated pool; two college students (one male and one female) were monitored during a typical two-hour workout. The mean concentration of chloroform in their breath was as high as 371 μg/m^3^ and 339 μg/m^3^, over twice the maximum possible concentration from inhalation exposure only. Furthermore, the maximum alveolar breath concentrations ultimately reached over twice the ambient indoor chloroform concentration, suggesting that dermal absorption was more important than inhalation. The dermal contribution was estimated at over 90% of total exposure. Other studies found that inhalation exposure to chloroform resulted in 80% absorption. Placental transfer of chloroform also has been demonstrated (IPCS 1994).

Occupational exposure may occur during the manufacture or use of chloroform (ATSDR 1997). Workers at wastewater and other treatment plants can be exposed to significant levels of chloroform. The National Occupational Exposure Survey (conducted from 1981 to 1983) estimated that 95,772 workers, including 41,394 women, in 20 industrial categories potentially were exposed to chloroform (NIOSH 1990).

## Regulations

### Department of Transportation (DOT)

Chloroform is considered a hazardous material, and special requirements have been set for marking, labeling, and transporting this material.

### Environmental Protection Agency (EPA)

#### Clean Air Act

National Emission Standards for Hazardous Air Pollutants: Listed as a hazardous air pollutant.

New Source Performance Standards: Manufacture is subject to certain provisions for the control of volatile organic compound emissions.

Prevention of Accidental Release: Threshold quantity (TQ) = 20,000 lb.

Urban Air Toxics Strategy: Identified as one of 33 hazardous air pollutants that present the greatest threat to public health in urban areas.

#### Clean Water Act

Designated a hazardous substance.

Effluent Guidelines: Listed as a toxic pollutant.

Water Quality Criteria: Based on fish or shellfish and water consumption = 60 μg/L; based on fish or shellfish consumption only = 2,000 μg/L.

#### Comprehensive Environmental Response, Compensation, and Liability Act

Reportable quantity (RQ) = 10 lb.

#### Emergency Planning and Community Right-to-Know Act

Toxics Release Inventory: Listed substance subject to reporting requirements.

Reportable quantity (RQ) = 10 lb.

Threshold planning quantity (TPQ) = 10,000 lb.

#### Resource Conservation and Recovery Act

Characteristic Hazardous Waste: Toxicity characteristic leaching procedure (TCLP) threshold = 6.0 mg/L.

Listed Hazardous Waste: Waste codes for which the listing is based wholly or partly on the presence of chloroform = U044, F024, F025, K009, K010, K019, K020, K021, K029, K073, K116, K149, K150, K151, K158.

Listed as a hazardous constituent of waste.

#### Safe Drinking Water Act

Maximum contaminant level (MCL) = 0.080 mg/L for the sum of chloroform, bromodichloromethane, dibromochloromethane, and bromoform.

### Food and Drug Administration (FDA, an HHS agency)

All drug products containing chloroform have been removed from the market and a new drug application is required for approval.

Chloroform may not be used as an ingredient in cosmetic products.

### Occupational Safety and Health Administration (OSHA, Dept. of Labor)

While this section accurately identifies OSHA’s legally enforceable PELs for this substance in 2018, specific PELs may not reflect the more current studies and may not adequately protect workers.

Ceiling concentration = 50 ppm (240 mg/m^3^).

## Guidelines

### American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 10 ppm.

### National Institute for Occupational Safety and Health (NIOSH, CDC, HHS)

Short-term exposure limit (STEL) = 2 ppm (9.78 mg/m^3^) (60-min exposure).

Immediately dangerous to life and health (IDLH) limit = 500 ppm.

Listed as a potential occupational carcinogen.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 9/30/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Ashley DL, Blount BC, Singer PC, Depaz E, Wilkes C, Gordon S, Lyu C, Masters J. 2005. Changes in blood trihalomethane concentrations resulting from differences in water quality and water use activities. Arch Environ Occup Health. 60(1):7–15. 10.3200/AEOH.60.1.7-15 16961003
ATSDR. 1997. Toxicological Profile for Chloroform. Atlanta, GA: Agency for Toxic Substances and Disease Registry; https://www.atsdr.cdc.gov/toxprofiles/tp6.pdf
Bove GE Jr, Rogerson PA, Vena JE. 2007. Case-control study of the effects of trihalomethanes on urinary bladder cancer risk. Arch Environ Occup Health. 62(1):39–47. 10.3200/AEOH.62.1.39-47 18171646
Campillo N, Viñas P, López-García I, Aguinaga N, Hernández-Córdoba M. 2004. Determination of volatile halogenated organic compounds in soils by purge-and-trap capillary gas chromatography with atomic emission detection. Talanta. 64(3):584–589. 10.1016/j.talanta.2004.03.028 18969645
Cantor KP, Hoover R, Mason TJ, McCabe LJ. 1978. Associations of cancer mortality with halomethanes in drinking water. J Natl Cancer Inst. 61(4):979–985. 702538
CDC. 2018. Trichloromethane. In Fourth National Report on Human Exposure to Environmental Chemicals, Updated Tables, March 2018, vol. 1. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention. pp. 35–36.
Chang CC, Ho SC, Wang LY, Yang CY. 2007. Bladder cancer in Taiwan: Relationship to trihalomethane concentrations present in drinking-water supplies. J Toxicol Environ Health A. 70(20):1752–1757. 10.1080/15287390701459031 17885932
ChemIDplus. 2009. ChemIDplus Advanced. National Library of Medicine; Last accessed: 9/30/09. http://chem.sis.nlm.nih.gov/chemidplus/chemidheavy.jsp and select Registry Number and search on CAS number.
ChemSources. 2009. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 9/30/09. http://www.chemsources.com/chemonline.html and search on chloroform.
Datskou I, North K. 1996. Risks due to groundwater contamination at a plutonium processing facility. Water Air Soil Pollut. 90:133–141. 10.1007/BF00619275
EPA. 2010. What You Should Know about Refrigerants When Purchasing or Repairing a Residential A/C System or Heat Pump. U.S. Environmental Protection Agency; https://www.epa.gov/Ozone/title6/phaseout/22phaseout.html
EPA. 2016. Chemical Data Reporting: Trichloromethane. U.S. Environmental Protection Agency; https://chemview.epa.gov/chemview and search on CAS number or substance name and select Manufacturing, Processing, Use, and Release Data Maintained by EPA and select Chemical Data Reporting Details.
FDA. 1999. Certain Drugs Accorded New Drug Status Through Rulemaking Procedures. 21 CFR 310.502; https://edocket.access.gpo.gov/cfr_2006/aprqtr/pdf/21cfr310.502.pdf
Gordon SM, Wallace LA, Callahan PJ, Kenny DV, Brinkman MC. 1998. Effect of water temperature on dermal exposure to chloroform. Environ Health Perspect. 106(6):337–345. 10.1289/ehp.98106337 9618350
Hogan MD, Chi PY, Hoel DG, Mitchell TJ. 1979. Association between chloroform levels in finished drinking water supplies and various site-specific cancer mortality rates. J Environ Pathol Toxicol. 2(3):873–887. 422940
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 9/30/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS Number.
IARC. 1979. Chloroform. In Some Halogenated Hydrocarbons. IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans, vol. 20. Lyon, France: International Agency for Research on Cancer. pp. 401–427.
IARC. 1982. Chloroform. In Chemicals, Industrial Processes and Industries Associated with Cancer in Humans. IARC Monographs on the Evaluation of the Carcinogenic Risk of Chemicals to Humans, suppl. 4. Lyon, France: International Agency for Research on Cancer. pp. 87–88.
IARC. 1987. Chloroform. In Overall Evaluations of Carcinogenicity. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, suppl. 7. Lyon, France: International Agency for Research on Cancer. pp. 152–154.
IARC. 1999. Chloroform. In Some Chemicals That Cause Tumors of the Kidney or Urinary Bladder in Rodents and Some Other Substances. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 73. Lyon, France: International Agency for Research on Cancer. pp. 131–182.
IPCS. 1994. Environmental Health Criteria 163. Chloroform. International Programme on Chemical Safety; https://inchem.org/documents/ehc/ehc/ehc163.htm
King WD, Marrett LD, Woolcott CG. 2000. Case-control study of colon and rectal cancers and chlorination by-products in treated water. Cancer Epidemiol Biomarkers Prev. 9(8):813–818. 10952098
Kuo HW, Chen PS, Ho SC, Wang LY, Yang CY. 2010. Trihalomethanes in drinking water and the risk of death from rectal cancer: Does hardness in drinking water matter? J Toxicol Environ Health A. 73(12):807–818. 10.1080/15287391003689267 20391122
Kuo HW, Tiao MM, Wu TN, Yang CY. 2009. Trihalomethanes in drinking water and the risk of death from colon cancer in Taiwan. J Toxicol Environ Health A. 72(20):1217–1222. 10.1080/15287390903129176 20077190
Lindstrom AB, Pleil JD, Berkoff DC. 1997. Alveolar breath sampling and analysis to assess trihalomethane exposures during competitive swimming training. Environ Health Perspect. 105(6):636–642. 10.1289/ehp.97105636 9288498
McCulloch A. 2003. Chloroform in the environment: Occurrence, sources, sinks and effects. Chemosphere. 50(10):1291–1308. 10.1016/S0045-6535(02)00697-5 12586161
Michaud DS, Kogevinas M, Cantor KP, Villanueva CM, Garcia-Closas M, Rothman N, Malats N, Real FX, Serra C, Garcia-Closas R, et al. 2007. Total fluid and water consumption and the joint effect of exposure to disinfection by-products on risk of bladder cancer. Environ Health Perspect. 115(11):1569–1572. 10.1289/ehp.10281 18007986
Nagano K, Kano H, Arito H, Yamamoto S, Matsushima T. 2006. Enhancement of renal carcinogenicity by combined inhalation and oral exposures to chloroform in male rats. J Toxicol Environ Health A. 69(20):1827–1842. 10.1080/15287390600630146 16952903
NCI. 1976. Report on the Carcinogenesis Bioassay of Chloroform. Bethesda, MD: National Institutes of Health. DHEW (NIH) Publication No. 76-1279. https://ntp.niehs.nih.gov/ntp/htdocs/LT_rpts/trChloroform.pdf
NIOSH. 1990. National Occupational Exposure Survey (1981-83). National Institute for Occupational Safety and Health; https://www.cdc.gov/noes/noes1/18500sic.html
Nuckols JR, Ashley DL, Lyu C, Gordon SM, Hinckley AF, Singer P. 2005. Influence of tap water quality and household water use activities on indoor air and internal dose levels of trihalomethanes. Environ Health Perspect. 113(7):863–870. 10.1289/ehp.7141 16002374
Roe FJ, Palmer AK, Worden AN, Van Abbé NJ. 1979. Safety evaluation of toothpaste containing chloroform. I. Long-term studies in mice. J Environ Pathol Toxicol. 2(3):799–819. 422936
TRI. 2009. TRI Explorer Chemical Report. U.S. Environmental Protection Agency; https://www.epa.gov/triexplorer/ and select Chloroform.
USITC. 2018. USITC Interactive Tariff and Trade DataWeb. United States International Trade Commission; https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2903130000.
Villanueva CM, Cantor KP, Cordier S, Jaakkola JJK, King WD, Lynch CF, Porru S, Kogevinas M. 2004. Disinfection byproducts and bladder cancer: A pooled analysis. Epidemiology. 15(3):357–367. 10.1097/01.ede.0000121380.02594.fc 15097021
Villanueva CM, Cantor KP, Grimalt JO, Malats N, Silverman D, Tardon A, Garcia-Closas R, Serra C, Carrato A, Castaño-Vinyals G, et al. 2007. Bladder cancer and exposure to water disinfection by-products through ingestion, bathing, showering, and swimming in pools. Am J Epidemiol. 165(2):148–156. 10.1093/aje/kwj364 17079692
WHO. 2004. Concise International Chemical Assessment Document 58. Chloroform. Geneva, Switzerland: World Health Organization; http://www.inchem.org/documents/cicads/cicads/cicad58.htm
Yamamoto S, Kasai T, Matsumoto M, Nishizawa T, Arito H, Nagano K, Matsushima T. 2002. Carcinogenicity and chronic toxicity in rats and mice exposed to chloroform by inhalation. J Occup Health. 44(5):283–293. 10.1539/joh.44.283
Zoccolillo L, Amendola L, Cafaro C, Insogna S. 2007. Volatile chlorinated hydrocarbons in Antarctic superficial snow sampled during Italian ITASE expeditions. Chemosphere. 67(10):1897–1903. 10.1016/j.chemosphere.2006.12.050 17287006
Zok S, Boutonnet JC, De Rooij C, Garny V, Lecloux A, Papp R, Thompson RS, Van Wijk D. 1998. Euro Chlor risk assessment for the marine environment OSPARCOM region: North Sea – Chloroform. Environ Monit Assess. 53(3):401–424. 10.1023/A:1006010515371