# Chloramphenicol

CAS No. 56-75-7

Reasonably anticipated to be a human carcinogen

First listed in the Tenth Report on Carcinogens (2002)

Figure 1

Chemical Structure of Chloramphenicol

## Carcinogenicity

Chloramphenicol is reasonably anticipated to be a human carcinogen, based on limited evidence of carcinogenicity from studies in humans.

### Cancer Studies in Humans

Numerous case reports have shown leukemia to occur after medical treatment for chloramphenicol-induced aplastic anemia, and three case reports have documented the occurrence of leukemia after chloramphenicol therapy in the absence of intervening aplastic anemia (IARC 1990). A case-control study in China found an increased risk of leukemia in children who had been treated with chloramphenicol; the risk increased significantly with increasing number of days the drug was taken (Shu et al. 1987; Shu et al. 1988). Two case-control studies found large but statistically nonsignificant increases in the risk of aplastic anemia associated with use of chloramphenicol in the six months before the onset of aplastic anemia (Issaragrisil et al. 1997; Laporte et al. 1998). However, two other case-control studies found no association between the use of chloramphenicol and the risk of leukemia in adults, suggesting that children may be a particularly susceptible subgroup (Doody et al. 1996; Zheng et al. 1993). One case-control study found an association between chloramphenicol use and increased risk of soft-tissue sarcoma (Zahm et al. 1989). Considered together, the many case reports implicating chloramphenicol as a cause of aplastic anemia, the evidence of a link between aplastic anemia and leukemia, and the increased risk of leukemia found in some case-control studies support the conclusion that chloramphenicol exposure is associated with an increased risk of cancer in humans.

### Studies on Mechanisms of Carcinogenesis

Chloramphenicol inhibits protein synthesis in the mitochondria of mammalian cells (by binding to ribosomes), which accounts for the sensitivity of proliferating tissues, such as those that promote the formation of blood cells, to its toxicity. Anemia, including aplastic anemia, is a recognized hazard associated with chloramphenicol treatment in humans. In genotoxicity studies, chloramphenicol gave mainly negative results in bacterial systems and mixed results in mammalian systems. The most consistently positive results were observed for cytogenetic effects in mammalian cells, including DNA single-strand breaks and increased frequencies of sister chromatid exchange and chromosomal aberrations. Overall, chloramphenicol appears to be genotoxic (NTP 2000). Several studies have suggested that dehydrochloramphenicol, a chloramphenicol metabolite produced by intestinal bacteria, may be responsible for DNA damage and carcinogenicity (Isildar et al. 1988a; Isildar et al. 1988b; Jimenez et al. 1990; Kitamura et al. 1997). This metabolite can undergo nitroreduction in the bone marrow and has been shown to cause DNA single-strand breaks in bone-marrow cells. Mitochondrial abnormalities caused by chloramphenicol are similar to those observed in preleukemia, suggesting that mitochondrial DNA is involved in the pathogenesis of secondary leukemia.

### Cancer Studies in Experimental Animals

No adequate studies of the carcinogenicity of chloramphenicol in experimental animals were identified. In male mice given chloramphenicol by intraperitoneal injection in combination with busulfan (the known human carcinogen 1,4-butanediol dimethanesulfonate), the incidence of lymphoma was significantly higher than in mice receiving either busulfan or chloramphenicol alone (Robin et al. 1981).

## Properties

Chloramphenicol is a naturally occurring antibiotic derivative of dichloroacetic acid that is a white to grayish or yellowish-white fine crystalline powder at room temperature. It is soluble in water and very soluble in methanol, ethanol, butanol, ethyl acetate, chloroform, and acetone. It is fairly soluble in ether, but insoluble in benzene, petroleum ether, and vegetable oils (HSDB 2009; IARC 1990). It is stable under normal shipping and handling conditions (Akron 2009). The biologically active form of chloramphenicol is levorotatory (Chambers 2001). Physical and chemical properties of chloramphenicol are listed in Table 1.

Table 1 Properties of Chloramphenicol

Property | Information
Molecular weight | 323.1
Melting point | 150°C to 152°C
Log K_ow_ | 1.14
Water solubility | 25 g/L at 25°C
Vapor pressure | 1.7 × 10^−12^ mm Hg at 25°C

Source: HSDB (2009).

## Use

Chloramphenicol is an antimicrobial agent with restricted use, because it causes blood abnormalities. It is used to combat serious infections for which other antibiotics are either ineffective or contraindicated. It can be used against gram-positive cocci and bacilli and gram-negative aerobic and anaerobic bacteria (Burnham et al. 2000). Chloramphenicol has been used since the 1950s to combat a wide range of microbial infections, including typhoid fever, meningitis, and certain infections of the central nervous system (IARC 1990). It currently is used in eye ointments and drops to treat superficial ocular infections involving the conjunctiva or cornea, in topical ointments or drops to treat the external ear or skin, in tablets for oral administration, and in intravenous suspensions to treat internal infections (FDA 2009; MedlinePlus 2009). Chloramphenicol has also been used in veterinary medicine as a highly effective and well-tolerated broad-spectrum antibiotic. Because of its tendency to cause blood abnormalities in humans, the U.S. Food and Drug Administration in 1997 banned its use in food-producing animals. Chloramphenicol continues to be used to treat both systemic and local infections in cats, dogs, and horses (Brooks 2008; FDA 1997).

## Production

Chloramphenicol is produced naturally by the bacterium Streptomyces venezuelae. It may be produced by chemical synthesis followed by a step to isolate stereoisomers. A fermentation process also has been described that does not require separation of stereoisomers (IARC 1990). Chloramphenicol was first produced in the United States in 1948 (IARC 1990). Annual U.S. production was estimated to exceed 908 kg (2,000 lb) in 1977 and 1979 (HSDB 2009). In 2009, chloramphenicol was produced by 16 manufacturers worldwide, including 11 in India, 1 in China, 2 in East Asia, and 2 in Europe (SRI 2009). U.S. imports of chloramphenicol were estimated at 8,150 kg (17,970 lb) in 1977 and 8,200 kg (18,080 lb) in 1979 (HSDB 2009). In 2002, less than 10,000 lb of chloramphenicol (U.S. production plus imports) was reported under the U.S. Environmental Protection Agency’s Toxic Substances Control Act Inventory Update Rule; no inventory update reports for chloramphenicol were filed before 2002 (EPA 2004). Recent volumes of U.S. chloramphenicol imports and exports are listed in Table 2.

Table 2 Imports and Exports of Chloramphenicol

Category | Year | Quantity (lb)
U.S. imports | 2017 | 30,955
U.S. exports | 2017 | 2,621

Source: USITC (2018) (import and export categories reported as “chloramphenicol and its derivatives; salts thereof”).

## Exposure

The primary routes of human exposure to chloramphenicol are oral and dermal, through its use as a drug. Exposure also may occur through inhalation, dermal contact, ingestion, or contact with contaminated water or soil (HSDB 2009). For adults, a typical dosage of chloramphenicol is 50 to 100 mg/kg of body weight per day, divided into four oral or intravenous doses (MedlinePlus 2009). Chloramphenicol also is used in ophthalmic ointments, solutions, and drops. It usually is taken for two to five days or until the infection is diminished. For many infections, continued treatment with chloramphenicol after the infection has resolved is suggested, for periods ranging from 48 hours for eye infections to 8 to 10 days for typhoid fever. No information was found on the number of prescriptions currently written for chloramphenicol in the United States. Children, especially newborns and young infants, metabolize chloramphenicol much more slowly than do adults. Pediatric doses must be lower so as to avoid gray-baby syndrome; this syndrome is characterized by cardiovascular collapse in infants, apparently caused by accumulation of active, unconjugated chloramphenicol in the serum, resulting from low inactivation through glucuronide conjugation in the liver (Chambers 2001). Initial dosages are 25 mg/kg of body weight every 24 hours for infants under one week old, 25 mg/kg every 12 hours for infants aged one to four weeks, and 50 mg/kg every 6 hours for children weighing less than about 25 kg (55 lb) (Sills and Boenning 1999).

Chloramphenicol can be detected in blood serum, plasma, cerebrospinal fluid, and urine. It is rapidly absorbed from the gastrointestinal tract and is distributed extensively through the human body, regardless of administration route. It has been found in the heart, lung, kidney, liver, spleen, pleural fluid, seminal fluid, ascitic fluid, and saliva. Upon metabolism, chloramphenicol yields D-threo-2-amino-1-(p-nitrophenyl)-1,3-propanediol and chloramphenicol-β-D-glucuronide (IARC 1990). Following degradation of chloramphenicol by intestinal bacteria via amidolysis, 18 metabolites were observed, the major ones being 2-amino-1-(p-nitrophenyl)-1,3-propanediol and its p-aminophenyl reduction by-product (HSDB 2009). Approximately 90% of chloramphenicol is excreted in urine, mostly as metabolites, including conjugated derivatives; only 15% is excreted as the parent compound (IARC 1990). The half-life of chloramphenicol in adult humans ranges from 1.6 to 4.6 hours. Peak levels appear two to three hours after oral administration of chloramphenicol. In adults given eight 1-g doses, once every six hours, the average peak serum level was 11.2 μg/mL one hour after the first dose and 18.4 μg/mL after the fifth dose. Mean serum levels ranged from 8 to 14 μg/mL over the 48-hour period (Burnham et al. 2000). In infants, chloramphenicol’s half-life is much longer, ranging from 10 to more than 48 hours in infants aged one to eight days and from 5 to 16 hours in infants aged eleven days to eight weeks (IARC 1990).

Chloramphenicol is released to the environment and may be found in various waste streams as a result of its use as a medicinal and research antimicrobial agent. Chloramphenicol may also be isolated from S. venezuelae in the soil (HSDB 2009). If released to air, chloramphenicol will exist primarily as an aerosol and will be removed mainly through dry deposition. Chloramphenicol in the atmosphere reacts with photochemically produced hydroxyl radicals, with a half-life of 12 hours. If released to water, chloramphenicol will be essentially nonvolatile. Adsorption to sediment and bioconcentration in aquatic organisms are not expected to be important processes. If released to soil, chloramphenicol is expected to have high mobility. It is not expected to evaporate from either dry or wet soils. Various studies indicate that chloramphenicol may biodegrade in soil and water. It was found to degrade in adapted activated waste sludge (HSDB 2009).

Occupational exposure during the manufacture of chloramphenicol may occur through inhalation, dermal contact, or ingestion (HSDB 2009). Medical and veterinary personnel who administer drugs containing chloramphenicol also may be exposed (Brooks 2008; Burnham et al. 2000).

## Regulations

### Food and Drug Administration (FDA, an HHS agency)

Chloramphenicol is a prescription drug subject to specific labeling requirements.

Extra-label use of chloramphenicol in food-producing animals is prohibited.

Chloramphenicol in ophthalmic, topical dosage, tablet, capsule, palmitate oral suspension, implantation, or injectable dosage form must not be used in animals producing meat, eggs, or milk.

## Guidelines

### National Institute for Occupational Safety and Health (NIOSH, CDC, HHS)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

### Occupational Safety and Health Administration (OSHA, Dept. of Labor)

A comprehensive set of guidelines has been established to prevent occupational exposures to hazardous drugs in health-care settings.

## References

Akron. 2009. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 5/09. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
Brooks WC. 2008. Chloramphenicol (Chloromycetin, CHPC). The Pet Pharmacy. Veterinary Information Network; http://www.veterinarypartner.com/Content.plx?P=A&S=0&C=0&A=624
Burnham TH, Snitker JA, Kastrup EK. 2000. Drug Facts and Comparisons. St. Louis, MO: Facts and Comparisons. pp. 1278–1279.
Chambers HF. 2001. Antimicrobial agents (continued): Protein synthesis inhibitors and miscellaneous antibacterial agents. In Hardman JG, Limbird LE, editors. The Pharmacological Basis of Therapeutics, 10th ed. New York, NY: McGraw-Hill. pp. 1239–1271.
Doody MM, Linet MS, Glass AG, Curtis RE, Pottern LM, Rush BB, Boice JD Jr, Fraumeni JF Jr, Friedman GD. 1996. Risks of non-Hodgkin’s lymphoma, multiple myeloma, and leukemia associated with common medications. Epidemiology. 7(2):131–139. 10.1097/00001648-199603000-00005 8834551
EPA. 2004. Inventory Update Rule 2002. U.S. Environmental Protection Agency; Last accessed: 4/21/05. https://www.epa.gov/oppt/iur/tools/data/2002-vol.htm
FDA. 1997. Extralabel animal drug use; fluoroquinolones and glycopeptides; order of prohibition. Fed Regist. 62(99):27944–27947.
FDA. 2009. The Electronic Orange Book. U.S. Food and Drug Administration; Last accessed: 5/09. https://www.fda.gov/cder/ob/default.htm and select Search by Active Ingredient and search on chloramphenicol.
HSDB. 2009. Hazardous Substances Data Bank. National Library of Medicine; Last accessed: 5/09. http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1990. Chloramphenicol. In Pharmaceutical Drugs. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 50. Lyon, France: International Agency for Research on Cancer. pp. 169–193.
Isildar M, Abou-Khalil WH, Jimenez JJ, Abou-Khalil S, Yunis AA. 1988 a. Aerobic nitroreduction of dehydrochloramphenicol by bone marrow. Toxicol Appl Pharmacol. 94(2):305–310. 10.1016/0041-008X(88)90272-4 3388427
Isildar M, Jimenez JJ, Arimura GK, Yunis AA. 1988 b. DNA damage in intact cells induced by bacterial metabolites of chloramphenicol. Am J Hematol. 28(1):40–46. 10.1002/ajh.2830280109 3369435
Issaragrisil S, Kaufman DW, Anderson T, Chansung K, Thamprasit T, Sirijirachai J, Piankijagum A, Porapakkham Y, Vannasaeng S, Leaverton PE, et al. 1997. Low drug attributability of aplastic anemia in Thailand. The Aplastic Anemia Study Group. Blood. 89(11):4034–4039. 9166842
Jimenez JJ, Jimenez JG, Daghistani D, Yunis AA. 1990. Interaction of chloramphenicol and metabolites with colony stimulating factors: Possible role in chloramphenicol-induced bone marrow injury. Am J Med Sci. 300(6):350–353. 10.1097/00000441-199012000-00002 2264572
Kitamura T, Ando J, Ishihara R, Takano S, Iijima T, Nishimura S, Yoshida M, Takahashi M, Maekawa A. 1997. Lack of carcinogenicity of thiamphenicol in F344 rats. Food Chem Toxicol. 35(10-11):1075–1080. 10.1016/S0278-6915(97)00114-2 9463541
Laporte JR, Vidal X, Ballarín E, Ibáñez L. 1998. Possible association between ocular chloramphenicol and aplastic anaemia—the absolute risk is very low. Br J Clin Pharmacol. 46(2):181–184. 10.1046/j.1365-2125.1998.00773.x 9723830
MedlinePlus. 2009. Chloramphenicol Injection. National Library of Medicine; Last accessed: 5/09. https://www.nlm.nih.gov/medlineplus/druginfo/meds/a608008.html
NTP. 2000. Report on Carcinogens Background Document for Chloramphenicol. Research Triangle Park, NC: National Toxicology Program.
Robin E, Berman M, Bhoopalam N, Cohen H, Fried W. 1981. Induction of lymphomas in mice by busulfan and chloramphenicol. Cancer Res. 41(9 Pt 1):3478–3482. 7260910
Shu XO, Gao YT, Brinton LA, Linet MS, Tu JT, Zheng W, Fraumeni JF Jr. 1988. A population-based case-control study of childhood leukemia in Shanghai. Cancer. 62(3):635–644. 10.1002/1097-0142(19880801)62:3<635::AID-CNCR2820620332>3.0.CO;2-3 3164642
Shu XO, Gao YT, Linet MS, Brinton LA, Gao RN, Jin F, Fraumeni JF Jr. 1987. Chloramphenicol use and childhood leukaemia in Shanghai. Lancet. 2(8565):934–937. 10.1016/S0140-6736(87)91420-6 2889862
Sills MR, Boenning D. 1999. Chloramphenicol. Pediatr Rev. 20(10):357–358. 10.1542/pir.20.10.357 10512892
SRI. 2009. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 5/09.
USITC. 2018. USITC Interactive Tariff and Trade DataWeb. United States International Trade Commission; https://dataweb.usitc.gov/scripts/user_set.asp and search on HTS no. 2941400000.
Zahm SH, Blair A, Holmes FF, Boysen CD, Robel RJ, Fraumeni JF Jr. 1989. A case-control study of soft-tissue sarcoma. Am J Epidemiol. 130(4):665–674. 10.1093/oxfordjournals.aje.a115388 2773915
Zheng W, Linet MS, Shu XO, Pan RP, Gao YT, Fraumeni JF Jr. 1993. Prior medical conditions and the risk of adult leukemia in Shanghai, People’s Republic of China. Cancer Causes Control. 4(4):361–368. 10.1007/BF00051339 8347786