# Captafol

CAS No. 2425-06-1

Reasonably anticipated to be a human carcinogen

First listed in the Twelfth Report on Carcinogens (2011)

Also known as Difolatan (formerly a registered trademark of Chevron Chemical Company)

Figure 1

Chemical Structure of Captafol

## Carcinogenicity

Captafol is reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity from studies in experimental animals and supporting data on mechanisms of carcinogenesis.

### Cancer Studies in Experimental Animals

Oral exposure to captafol caused tumors at several different tissue sites in rats and mice. Long-term feeding studies were conducted with two mouse strains (CD-1 and B6C3F_1_) (Ito et al. 1984; NTP 2008; Quest et al. 1993) and two rat strains (Crl:CD and F344) (NTP 2008; Nyska et al. 1989; Quest et al. 1993; Tamano et al. 1990). In mice of both sexes, tumors were predominantly of the vascular system, gastrointestinal system, and liver; they included (1) cancer of the lymphoid tissue (lymphosarcoma) in CD-1 mice, (2) blood-vessel cancer (hemangiosarcoma) in B6C3F_1_ and CD-1 mice, (3) benign tumors of blood vessels of the spleen (splenic hemangioma) in B6C3F_1_ mice, (4) benign and malignant tumors of the small intestine in B6C3F_1_ mice, and (5) liver cancer (hepatocellular carcinoma) in B6C3F_1_ mice. Benign Harderian-gland tumors (adenoma) also were observed in CD-1 males (Ito et al. 1984; Quest et al. 1993). In rats, captafol caused liver and kidney tumors in several studies and benign mammary-gland tumors (fibroadenoma) in female Crl:CD rats in one study (Nyska et al. 1989; Quest et al. 1993; Tamano et al. 1990). Benign liver tumors (hepatocellular adenoma) were observed in female Crl:CD rats and in F344 rats of both sexes, and a significant dose-related trend was observed for malignant liver tumors (hepatocellular carcinoma) in female F344 rats (NTP 2008; Quest et al. 1993; Tamano et al. 1990). Captafol caused benign kidney tumors (renal-cell adenoma) in F344 rats of both sexes and malignant kidney tumors (renal-cell carcinoma) in F344 males (Nyska et al. 1989; Tamano et al. 1990). In Crl:CD rats, the combined incidence of benign and malignant kidney tumors (renal-cell adenoma and carcinoma) was increased in males, and a significant dose-related trend was observed for malignant kidney tumors (renal-cell carcinoma) in both sexes (NTP 2008; Quest et al. 1993).

Captafol was shown to be hepatotoxic and to induce potentially preneoplastic glutathione S-transferase placental form positive (GST-P+) foci in the liver of male F344 rats (NTP 2008) in both the initiation and promotion phases of studies of tumor development. In addition, promotion with captafol increased the incidences of hyperplasia of the forestomach and adenoma of the small intestine (Uwagawa et al. 1991), thyroid follicular-cell adenoma (Ito et al. 1996), and the expression of a marker of cell proliferation (proliferating-cell nuclear antigen) in the kidney (Kim et al. 1997) in F344 rats.

### Studies on Mechanisms of Carcinogenesis

In rodents, captafol is absorbed through the gastrointestinal tract and lung and to a lesser extent through the skin; however, the available data indicate that captafol and its metabolites do not accumulate in the tissues of animals and are rapidly eliminated, primarily in the urine. The metabolism and disposition of captafol after oral absorption is anticipated to be similar in experimental animals and humans (NTP 2008). Two metabolic pathways, based primarily on oral absorption, have been proposed; one pathway involves reaction of captafol with cellular thiol-containing molecules such as glutathione and cysteine, and the other involves hydrolysis of the N-S bond. Both pathways are relevant to the mechanism of carcinogenesis, as the reaction of captafol with thiol groups can lead to cytotoxicity, and metabolites derived from the side chain have been shown to be carcinogenic. Tetrahydrophthalimide is a product of both reaction pathways and has been identified in blood, urine, and feces of rats, dogs, and monkeys (Hayes 1982). However, tetrahydrophthalimide has not been tested in carcinogenicity bioassays. Dichloroacetic acid (previously shown to be carcinogenic in mice) was identified as a minor metabolite of captafol in rodents (NTP 2008). Another reported metabolite of captafol is 2-chloro-2-methyl-thioethylene sulfonic acid (which is derived from the side chain) (IPCS 1990). The proposed mechanism for formation of this metabolite is through transient formation of an episulfonium ion, a DNA alkylating agent (Bernard and Gordon 2000; IPCS 1990; Williams 1992).

Short-term in vitro and in vivo genotoxicity studies support mutagenicity as a mechanism of carcinogenesis. Captafol is an alkylating agent and has produced genotoxic effects in a variety of systems (NTP 2008). It caused mutations in Salmonella typhimurium (base-pair mutations) and Escherichia coli and in non-mammalian in vivo systems (Aspergillus nidulans and Drosophila melanogaster). In in vitro studies with cell lines from rodents and other mammals, captafol caused DNA single-strand breaks, sister chromatid exchange, chromosomal aberrations, micronucleus formation, polyploidy (in one of two studies), mitotic spindle disturbances, and cell transformation. In human cells in vitro, it caused DNA single-strand breaks, sister chromatid exchange, micronucleus formation, and chromosomal aberrations. In rodents exposed in vivo, captafol caused DNA strand breaks, micronucleus formation (Robbiano et al. 2004), and dominant lethal mutations in rats (Collins 1972) but did not cause mutations in the host-mediated assay in rats or dominant lethal mutations in albino mice (Kennedy et al. 1975).

In addition to direct genotoxic activity, epigenetic mechanisms, such as cytotoxicity as a result of reduced cellular content of thiol groups (nonprotein and protein), inhibition of enzymes involved in DNA replication (DNA topoisomerases and polymerases), inhibition of DNA and RNA synthesis, and induction of cytochrome P450 mono-oxygenases may also be involved in the pathogenesis of tumor formation (NTP 2008).

### Cancer Studies in Humans

The data available from epidemiological studies are inadequate to evaluate the relationship between human cancer and exposure specifically to captafol. One case-control study (Clary and Ritz 2003) directly addressed captafol exposure. This study was based upon an ecologic (group-level) exposure assessment and included 17 other chlorinated pesticides. A statistically nonsignificant increase in pancreatic cancer was reported among residents who had lived for over 20 years in geographical areas with high captafol use; however, confounding by other cancer risk factors could not be ruled out, and the study was limited by imprecise measures of exposure and diseases.

## Properties

Captafol is a broad-spectrum nonsystemic fungicide that is categorized as a phthalimide fungicide based on its tetrahydrophthalimide chemical ring structure (other phthalimide fungicides include captan and folpet). Captafol exists as white, colorless to pale-yellow or tan (technical grade) crystals or as a crystalline solid or powder, with a slight characteristic pungent odor. It is practically insoluble in water but is soluble or slightly soluble in most organic solvents. Captafol reacts with bases, acids, acid vapors, and strong oxidizers (HSDB 2010). It hydrolyzes slowly in aqueous emulsions or suspensions, but rapidly in acidic and basic aqueous alkaline media (Akron 2010). Captafol will not burn, but when heated to decomposition, it emits toxic fumes, including nitrogen oxides, sulfur oxides, phosgene, and chlorine (IPCS 1993). Physical and chemical properties of captafol are listed in Table 1.

Table 1 Properties of Captafol

Property | Information
Molecular weight | 349.1^a^
Density | 1.64 ± 0.1 g/cm^3^ at 20°C (calculated from molar volume)^b^
Melting point | 160°C to 161°C (decomposes slowly)^c^
Log K_ow_ | 3.8 at 25°C^a^
Water solubility | 1.4 mg/L at 20°C; 2.24 mg/L at 25°C^d^
Vapor pressure (mm Hg) | 8.27 × 10^−9^ at 20°C^d^
Vapor density relative to air | 12^e^
Dissociation constant (pK_a_) | −2.67 ± 0.20 at 25°C^b^

Sources: ^a^HSDB (2010), ^b^CAS (2008), ^c^BCPC (2006), ^d^Kim et al. (1997), ^e^Akron (2010).

## Use

Captafol is a nonsystemic fungicide used to control fungal diseases of fruits, vegetables, ornamental plants, and grasses and as a seed treatment. It also was used in the timber industry to control wood-rot fungi on logs and wood products (IARC 1991; IPCS 1990). Captafol was produced and used as a fungicide in the United States until 1987, when all registrants of captafol products requested voluntary cancellation of their registrations. Legal use of existing stocks was allowed after 1987; however, in 1999, the U.S. Environmental Protection Agency further restricted its use, and all captafol tolerances were revoked except those for onions, potatoes, and tomatoes. These remaining tolerances were revoked in 2006. Although many countries banned its use, captafol was still used as of the mid 2000s in several countries that exported agricultural products to the United States, including Mexico and Brazil; however, by 2010, no countries were identified that still allowed the use of captafol on food crops.

## Production

Captafol is produced by the reaction of tetrahydrophthalimide and 1,1,2,2-tetrachloroethylsulfenyl chloride in the presence of aqueous sodium hydroxide (IARC 1991). It was first registered and produced commercially in the United States in 1961 as Difolatan (IPCS 1993). From 1979 to 1981, annual U.S. production of captafol was estimated to be 3,600 to 4,500 metric tons (8 million to 10 million pounds) (as active ingredient), of which about half was exported (IARC 1991). In 1983, captafol was produced by one U.S. company, whose annual production capacity was 12 million pounds (SRI 1984). Production in 1985 was estimated at 6,600 metric tons (14.5 million pounds) (IARC 1991). In 2010, no producers of captafol were identified worldwide (SRI 2010), but Difolatan (a captafol fungicide) was available from ten suppliers, including five in the United States, one in France, one in Hong Kong, two in India, and one in South Africa. In addition, Captafol Pestanal (an analytical standard for captafol) was available from two U.S. suppliers and one Swiss supplier (ChemSources 2010).

## Exposure

In the past, exposure to captafol occurred by ingestion, inhalation, or dermal contact. The potential for exposure of both the general population and agricultural workers would have been greatest from the late 1970s through the mid-1980s, when annual domestic usage was estimated to be at least 4 million pounds. In the past, the general population was potentially exposed to captafol through ingestion of contaminated groundwater or agricultural products sprayed with captafol, through exposure to topsoil, or through its application in nearby agricultural settings. In the United States, captafol was no longer produced after 1987 or used after 2006. It is possible, though highly unlikely, that individuals could be exposed by ingestion of imported fruits or vegetables treated with captafol. The U.S. Food and Drug Administration’s Pesticide Residue Monitoring Program and the U.S. Department of Agriculture’s Pesticide Data Program detected captafol at low levels in food samples in the 1980s and 1990s but have not detected it since 1998. No captafol residues were detected in the FDA’s Total Diet Study (FDA 1988; 1989; 1993; Gunderson 1995; Yess et al. 1993). Between 1993 and 2003, captafol was detected once in animal feed, at a concentration of 0.036 ppm in a barley sample from Maryland in 1999 (FDA 2000).

In air, captafol is expected to exist solely in the particulate phase, based on its vapor pressure; however, some reports suggest that it exists in the vapor phase. In water, captafol is expected to adsorb to sediment and suspended solids. In soil, captafol is expected to have slight mobility, based on its soil organic carbon–water partition coefficient (HSDB 2010). Volatilization from soil is not expected to be an important fate process. Reported values for captafol’s half-life in soil vary among sources, ranging from less than 3 days to around 11 days (Extoxnet 1995; HSDB 2010). Captafol has been detected in the vicinity of agricultural uses outside the United States; it was detected in air in Canada (Frank et al. 1994), in surface water in Spain (Picó et al. 1994; Vioque-Fernández et al. 2007) and Italy (Readman et al. 1997), and in soil in India (Venkatramesh and Agnihothrudu 1988). Runoff losses of captafol with natural rainfall were less than 0.1% of the amount applied (Kim et al. 1996).

U.S. workers previously were exposed to captafol during its production, formulation, or application to agricultural fields; on reentry to a sprayed field; or when working with treated timber products (HSDB 2010; IPCS 1993). In a study of worker exposure to Difolatan 80 Sprills (80% captafol) in central Florida orange groves, aerosolized captafol concentrations averaged 56 μg/m^3^ for mixer-loaders and 34 μg/m^3^ for spray applicators. Hourly dermal exposure levels were approximately 1 to 10 μg/cm^2^ for the hands, legs, and arms; however, levels of up to 20 μg/cm^2^ were seen when direct contact with captafol solution was evident. Whole-body exposures ranged from 15 to 116 mg/h, with a mean of 40 mg/h; the hands accounted for about 40% of total exposure (Popendorf 1988).

Captafol toxicity was reported in exposed workers. Peoples et al. (1978) presented 37 brief case reports of exposure during the manufacture and application of captafol that had been reported to the California Department of Food and Agriculture from 1974 through 1976. The reports reflected toxic outcomes of possible captafol exposure that were reported by physicians, including systemic, skin, and eye toxicity. Positive patch tests for captafol or a history of occupationally induced dermatitis were reported in studies of workers who packed captafol (Camarasa 1975), workers exposed to captafol in timber-treatment plants (Stoke 1979), agricultural workers and former agricultural workers (Guo et al. 1996; Lisi et al. 1986; 1987; Rademaker 1998), flower-shop workers (Thiboutot et al. 1990), and laboratory chemists (Brown 1984).

## Regulations

### Environmental Protection Agency (EPA)

#### Clean Water Act

Effluent Limitations: Daily discharge maximum = 4.24 × 10^–6^ kg/kkg (kg/metric ton); monthly average discharge maximum = 1.31 × 10^–6^ kg/kkg.

#### Federal Insecticide, Fungicide, and Rodenticide Act

Classified as Group B, probable human carcinogen based on mammary-gland and liver tumors in female Sprague-Dawley rats, kidney tumors in both male and female rats, and lymphosarcoma and hemangiosarcoma in both male and female CD-1 mice, with Harderian-gland tumors in male mice.

### Food and Drug Administration (FDA, an HHS agency)

Tolerance levels have been revoked for all foods, thereby making it illegal to import or introduce into commerce any foods with captafol residue.

## Guidelines

### American Conference of Governmental Industrial Hygienists (ACGIH)

Threshold limit value – time-weighted average (TLV-TWA) = 0.1 mg/m^3^.

Potential for dermal absorption.

### National Institute for Occupational Safety and Health (NIOSH, CDC, HHS)

Recommended exposure limit (REL) = 0.1 mg/m^3^.

Potential for dermal absorption.

Listed as a potential occupational carcinogen.

## References

Akron. 2010. The Chemical Database. The Department of Chemistry at the University of Akron; Last accessed: 7/1/10. http://ull.chemistry.uakron.edu/erd/ and search on CAS number.
BCPC. 2006. Captafol. In Tomlin CDS, editor. The Pesticide Manual, 14th ed. Hampshire, UK: British Crop Protection Council. pp. 140–141.
Bernard BK, Gordon EB. 2000. An evaluation of the common mechanism approach to the Food Quality Protection Act: Captan and four related fungicides, a practical example. Int J Toxicol. 19(1):43–61. 10.1080/109158100225033
Brown R. 1984. Contact sensitivity to Difolatan (captafol). Contact Dermatitis. 10(3):181–182. 10.1111/j.1600-0536.1984.tb00031.x 6232106
Camarasa G. 1975. Difolatan dermatitis. Contact Dermatitis. 1(2):127. 10.1111/j.1600-0536.1975.tb05350.x 233886
CAS. 2008. STN Database. Columbus, OH: Chemical Abstracts Service; Last accessed: 4/15/08.
ChemSources. 2010. Chem Sources - Chemical Search. Chemical Sources International; Last accessed: 8/2/10. http://www.chemsources.com/chemonline.html and search on difolatan and on captafol pestanal.
Clary T, Ritz B. 2003. Pancreatic cancer mortality and organochlorine pesticide exposure in California, 1989-1996. Am J Ind Med. 43(3):306–313. 10.1002/ajim.10188 12594778
Collins TFX. 1972. Dominant lethal assay. II. Folpet and difolatan. Food Cosmet Toxicol. 10(3):363–371. 10.1016/S0015-6264(72)80254-2 5045679
Extoxnet. 1995. Captafol. Extension Toxicology Network, Pesticide Information Profiles; Last accessed: 10/6/04. http://extoxnet.orst.edu/pips/captafol.htm
FDA. 1988. Food and Drug Administration Pesticide Program. Residues in foods – 1987. J Assoc Off Anal Chem. 71(6):156A–174A. 3240981
FDA. 1989. Food and Drug Administration Pesticide Program. Residues in foods – 1988. J Assoc Off Anal Chem. 72(5):133A–152A. 2681132
FDA. 1993. FDA Monitoring Program. J AOAC Int. 76(5):127A–148A. 10.1093/jaoac/76.5.127A 8241821
FDA. 2000. Pesticide Residue Monitoring Program 1999. U.S. Food and Drug Administration; http://www.fda.gov/Food/FoodSafety/FoodContaminantsAdulteration/Pesticides/ResidueMonitoringReports/ucm125168.htm#feeds2
Frank R, Ripley BD, Lampman W, Morrow D, Collins H, Gammond GR, McCubbin P. 1994. Comparative spray drift studies of aerial and ground applications 1983-1985. Environ Monit Assess. 29(2):167–181. 10.1007/BF00546873 24221295
Gunderson EL. 1995. Dietary intakes of pesticides, selected elements, and other chemicals: FDA Total Diet Study, June 1984-April 1986. J AOAC Int. 78(4):910–921. 10.1093/jaoac/78.4.910 7580329
Guo YL, Wang BJ, Lee CC, Wang JD. 1996. Prevalence of dermatoses and skin sensitisation associated with use of pesticides in fruit farmers of southern Taiwan. Occup Environ Med. 53(6):427–431. 10.1136/oem.53.6.427 8758040
Hayes WJ Jr. 1982. Pesticides Studied in Man. Baltimore, MD: Williams & Wilkins. pp. 582–584.
HSDB. 2010. Hazardous Substances Data Bank. National Library of Medicine; http://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB and search on CAS number.
IARC. 1991. Occupational Exposures in Insecticide Application, and Some Pesticides. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans, vol. 53. Lyon, France: International Agency for Research on Cancer. pp. 353–369.
IPCS. 1990. Captafol. Health and Safety Guide No. 49. International Programme on Chemical Safety; Last accessed: 7/9/04. http://www.inchem.org/documents/hsg/hsg/hsg049.htm
IPCS. 1993. Captafol. Poisons Information Monograph 097. International Programme on Chemical Safety; Last accessed: 7/9/04. http://www.inchem.org/documents/pims/chemical/pim097.htm
Ito N, Hagiwara A, Tamano S, Futacuchi M, Imaida K, Shirai T. 1996. Effects of pesticide mixtures at the acceptable daily intake levels on rat carcinogenesis. Food Chem Toxicol. 34(11-12):1091–1096. 10.1016/S0278-6915(97)00079-3 9119320
Ito N, Ogiso T, Fukushima S, Shibata M, Hagiwara A. 1984. Carcinogenicity of captafol in B6C3F_1_ mice. Gann. 75(10):853–865. 6510634
Kennedy GL Jr, Arnold DW, Keplinger ML. 1975. Mutagenicity studies with captan, captofol, folpet and thalidomide. Food Cosmet Toxicol. 13(1):55–61. 10.1016/0015-6264(75)90082-6 1091537
Kim K, Kim J-H, Lee SK, Kim Y-H. 1997. [Physiochemical properties of pesticide. (I) Water solubility, hydrolysis, vapor pressure and n-octanol/water partition coefficient of captafol]. Han'guk Nonghwa Hakhoechi. 40(1):71–75.
Kim K, Kim Y-H, Kim J-H, Park C-K. 1996. [Pesticide runoff from soil surface. I. Runoff of captafol by natural rainfall in field]. Han'guk Nonghwa Hakhoechi. 39(6):488–493.
Lisi P, Caraffini S, Assalve D. 1986. A test series for pesticide dermatitis. Contact Dermatitis. 15(5):266–269. 10.1111/j.1600-0536.1986.tb01365.x 2949929
Lisi P, Caraffini S, Assalve D. 1987. Irritation and sensitization potential of pesticides. Contact Dermatitis. 17(4):212–218. 10.1111/j.1600-0536.1987.tb02715.x 2962818
NTP. 2008. Report on Carcinogens Background Document for Captafol. Research Triangle Park, NC: National Toxicology Program; https://ntp.niehs.nih.gov/files/Captafol_BD_(20Jun08-for_web)_508-1.pdf
Nyska A, Waner T, Pirak M, Gordon E, Bracha P, Klein B. 1989. The renal carcinogenic effect of Merpafol in the Fischer 344 rat. Isr J Med Sci. 25(8):428–432. 2767949
Peoples SA, Maddy KT, Tochilin S, Edmiston S. 1978. Human health problems associated with exposure to the fungicide captafol (difolatan) in California. Vet Hum Toxicol. 20(3):184–189.
Picó Y, Moltó JC, Redondo MJ, Viana E, Mañes J, Font G. 1994. Monitoring of the pesticide levels in natural waters of the Valencia community (Spain). Bull Environ Contam Toxicol. 53(2):230–237. 10.1007/BF00192038 8086705
Popendorf W. 1988. Mechanisms of clothing exposure and dermal dosing during spray application. In Mansdorf SZ, Sager R, Nielsen AP, editors. Performance of Protective Clothing: Second Symposium. ASTM STP, vol. 989. Philadelphia: American Society for Testing and Materials. pp. 611-624.
Quest JA, Fenner-Crisp PA, Burnam W, Copley M, Dearfield KL, Hamernik KL, Saunders DS, Whiting RJ, Engler R. 1993. Evaluation of the carcinogenic potential of pesticides. 4. Chloroalkylthiodicarboximide compounds with fungicidal activity. Regul Toxicol Pharmacol. 17(1):19–34. 10.1006/rtph.1993.1003 8441825
Rademaker M. 1998. Occupational contact dermatitis among New Zealand farmers. Australas J Dermatol. 39(3):164–167. 10.1111/j.1440-0960.1998.tb01273.x 9737042
Readman JW, Albanis TA, Barceló D, Galassi S, Tronczynski J, Gabrielides GP. 1997. Fungicide contamination of Mediterranean estuarine waters: Results from a MED POL pilot survey. Mar Pollut Bull. 34(4):259–263. 10.1016/S0025-326X(97)00101-X
Robbiano L, Baroni D, Carrozzino R, Mereto E, Brambilla G. 2004. DNA damage and micronuclei induced in rat and human kidney cells by six chemicals carcinogenic to the rat kidney. Toxicology. 204(2-3):187–195. 10.1016/j.tox.2004.06.057 15388244
SRI. 1984. Chemical Economics Handbook. Menlo Park, CA: SRI International. pp. 573.5002 B-5573.5002 R.
SRI. 2010. Directory of Chemical Producers. Menlo Park, CA: SRI Consulting. Database edition; Last accessed: 8/2/10.
Stoke JC. 1979. Captafol dermatitis in the timber industry. Contact Dermatitis. 5(5):284–292. 10.1111/j.1600-0536.1979.tb04880.x 159800
Tamano S, Kurata Y, Kawabe M, Yamamoto A, Hagiwara A, Cabral R, Ito N. 1990. Carcinogenicity of captafol in F344/DuCrj rats. Jpn J Cancer Res. 81(12):1222–1231. 10.1111/j.1349-7006.1990.tb02683.x 2125991
Thiboutot DM, Hamory BH, Marks JG Jr. 1990. Dermatoses among floral shop workers. J Am Acad Dermatol. 22(1):54–58. 10.1016/0190-9622(90)70007-5 2137139
Uwagawa S, Tsuda H, Inoue T, Tagawa Y, Aoki T, Kagawa M, Ogiso T, Ito N. 1991. Enhancing potential of 6 different carcinogens on multiorgan tumorigenesis after initial treatment with N-methyl-N-nitrosourea in rats. Jpn J Cancer Res. 82(12):1397–1405. 10.1111/j.1349-7006.1991.tb01812.x 1778764
Venkatramesh M, Agnihothrudu V. 1988. Persistence of captafol in soils with and without amendments and its effects on soil microflora. Bull Environ Contam Toxicol. 41(4):548–555. 10.1007/BF02020999 3224173
Vioque-Fernández A, de Almeida EA, Ballesteros J, García-Barrera T, Gómez-Ariza JL, López-Barea J. 2007. Doñana National Park survey using crayfish (Procambarus clarkii) as bioindicator: Esterase inhibition and pollutant levels. Toxicol Lett. 168(3):260–268. 10.1016/j.toxlet.2006.10.023 17157454
Williams GM. 1992. DNA reactive and epigenetic carcinogens. Exp Toxicol Pathol. 44(8):457–463. 10.1016/S0940-2993(11)80158-2 1493364
Yess NJ, Gunderson EL, Roy RR. 1993. U.S. Food and Drug Administration monitoring of pesticide residues in infant foods and adult foods eaten by infants/children. J AOAC Int. 76(3):492–507. 10.1093/jaoac/76.3.492 8318840