# References

1 Ackermann K, Plomp R, Lao O, Middleton B, Revell VL, Skene DJ, Kayser M. 2013. Effect of sleep deprivation on rhythms of clock gene expression and melatonin in humans. Chronobiol Int 30(7): 901–909. (Supported by Philips Lighting, the Netherlands Forensic Institute, the Netherlands Genomics Initiative [NGI]/Netherlands Organization for Scientific Research [NOW] within the framework of the Forensic Genomics Consortium Netherlands [FGCN], by the 6th Framework project EUCLOCK, and by the UK Biotechnology and Biological Sciences Research Council [BBSRC]. Authors affiliated with Erasmus MC University Medical Center Rotterdam, Netherlands; University of Surrey, UK.)23738906
2 Adams CD, Jordahl KM, Copeland W, Mirick DK, Song X, Sather CL, Kelsey K, Houseman A, Davis S, Randolph T, Bhatti P. 2017. Nightshift work, chronotype, and genome-wide DNA methylation in blood. Epigenetics 12(10): 833–840. (Supported by NIEHS, NCI, the Safeway Foundation, Cancer Research UK and the Medical Research Council. Authors affiliated with University of Bristol, UK; Fred Hutchinson Cancer Research Center, WA; Brown University, RI; Oregon State University, OR.)28837395
3 Adams SL, Roxe DM, Weiss J, Zhang F, Rosenthal JE. 1998. Ambulatory blood pressure and Holter monitoring of emergency physicians before, during, and after a night shift. Acad Emerg Med 5(9): 871–877. (Supported by Mr. and Mrs. Everett P. Weaver. Authors affiliated with Northwestern University Medical School, IL. )9754499
4 Åkerstedt T, Knutsson A, Narusyte J, Svedberg P, Kecklund G, Alexanderson K. 2015. Night work and breast cancer in women: a Swedish cohort study. BMJ Open 5(4): e008127. (Supported by the AFA Insurance Company. Authors affiliated with Karolinska Institutet, Sweden; Stockholm University, Sweden; Mid Sweden University, Sweden; Radboud University, Netherlands.)
5 Åkerstedt T, Narusyte J, Svedberg P, Kecklund G, Alexanderson K. 2017. Night work and prostate cancer in men: a Swedish prospective cohort study. BMJ Open 7(6): e015751. (Supported by the AFA Insurance Company. Authors affiliated with Karolinska Institutet, Sweden; Stockholm University, Sweden; Radboud University, Netherlands.)
6 Aktan E, Kaleli B, Alatas E. 1997. Is there any change in the prolactin levels of nurses in the morning after night shift? Aust N Z J Obstet Gynaecol 37(4): 429–430. (Support not reported. Authors affiliated with Pamukkale University Medical Faculty, Turkey.)9429707
7 Alefishat E, Abu Farha R. 2016. Determinants of vitamin D status among Jordanian employees: Focus on the night shift effect. Int J Occup Med Environ Health 29(5): 859–870. (Supported by the University of Jordan. Authors affiliated with University of Jordan, Jordan; Applied Science Private University, Jordan.)27518893
8 Allott EH, Masko EM, Freedland SJ. 2013. Obesity and prostate cancer: weighing the evidence. Eur Urol 63(5): 800–809. (Supported by NCI, the Department of Defense Prostate Cancer Research Program, and NIH. Authors affiliated with Duke University Medical Center, NC.)23219374
9 Alterman T, Luckhaupt SE, Dahlhamer JM, Ward BW, Calvert GM. 2013. Prevalence rates of work organization characteristics among workers in the U.S.: data from the 2010 National Health Interview Survey. Am J Ind Med 56(6): 647–659. (Support not reported. Authors affiliated with CDC, OH and MD.)22911666
10 Altman BJ. 2016. Cancer clocks out for lunch: Disruption of circadian rhythm and metabolic oscillation in cancer. Front Cell Dev Biol 4: 62. (Supported by NCI and NIH. Authors affiliated with Abramson Family Cancer Research Institute, PA; Abramson Cancer Center, PA; University of Pennsylvania Perelman School of Medicine, PA.)27500134
11 AMA. 2016. AMA Adopts Guidance to Reduce Harm from High Intensity Street Lights. American Medical Association. Updated on 6/14/16. https://www.ama-assn.org/ama-adopts-guidance-reduce-harm-high-intensity-street-lights
12 Anders CK, Johnson R, Litton J, Phillips M, Bleyer A. 2009. Breast cancer before age 40 years. Semin Oncol 36(3): 237–249. (Support not reported. Authors affiliated with University of North Carolina at Chapel Hill, NC; Seattle Children’s Hospital, WA; University of Texas M.D. Anderson Cancer Center, TX; Princess Margaret Hospital for Children, Australia; St. Charles Medical Center, OR.)19460581
13 Andersen M, Mardaljevic J, Lockley SW. 2012. A framework for predicting the non-visual effects of daylight - part I: Photobiology-based model. Light Res Technol 44(1): 37–53. (Supported by the Velux Corporation, the Ecole Polytechnique Fédérale de Lausanne and John Mardaljevic by De Montfort University. Authors affiliated with Ecole Polytechnique Fédérale de Lausanne, Switzerland; De Montfort University, UK.)
14 Anderson LE, Morris JE, Sasser LB, Stevens RG. 2000. Effect of constant light on DMBA mammary tumorigenesis in rats. Cancer Lett 148(2): 121–126. (Support not reported. Authors affiliated with Pacific Northwest National Laboratory, WA.)10695987
15 Anderson WF, Rosenberg PS, Prat A, Perou CM, Sherman ME. 2014. How many etiological subtypes of breast cancer: two, three, four, or more? J Natl Cancer Inst 106(8). (Supported by NIH and NCI. Authors affiliated with National Cancer Institute, MD; Vall d´Hebron Institute of Oncology, Spain; University of North Carolina at Chapel Hill, NC.)
16 Anisimov VN, Baturin DA, Popovich IG, Zabezhinski MA, Manton KG, Semenchenko AV, Yashin AI. 2004. Effect of exposure to light-at-night on life span and spontaneous carcinogenesis in female CBA mice. Int J Cancer 111(4): 475–479. (Supported by the Russian Foundation for Basic Research and Duke University. Authors affiliated with N.N. Petrov Research Institute of Oncology, Russia; Duke University, NC; Max-Planck Institute for Demographic Research, Germany.)15239122
17 Anisimov VN, Popovich IG, Shtylik AV, Zabezhinski MA, Ben-Huh H, Gurevich P, Berman V, Tendler Y, Zusman I. 2000. Melatonin and colon carcinogenesis. III. Effect of melatonin on proliferative activity and apoptosis in colon mucosa and colon tumors induced by 1,2-dimethylhydrazine in rats. Exp Toxicol Pathol 52(1): 71–76. (Supported by the Russian Ministry of Science State Program “National Priorities in Medicine and Health.” Authors affiliated with N.N. Petrov Research Institute of Oncology, Russia; Kaplan Hospital, Israel; Hebrew University of Jerusalem, Israel; Rambam Medical Center, Israel.)10779155
18 Anisimov VN, Popovich IG, Zabezhinski MA. 1997. Melatonin and colon carcinogenesis: I. Inhibitory effect of melatonin on development of intestinal tumors induced by 1,2-dimethylhydrazine in rats. Carcinogenesis 18(8): 1549–1553. (Supported by the The Russian Ministry of Science State Program ‘National Priorities in Medicine and Health.’ Authors affiliated with N.N. Petrov Research Institute of Oncology, Russia.)9276629
19 Anisimov VN, Vinogradova IA, Panchenko AV, Popovich IG, Zabezhinski MA. 2012. Light-at-night-induced circadian disruption, cancer and aging. Curr Aging Sci 5(3): 170–177. (Supported by the Russian Federation and The Program of the Strategic Development 2012-2016 “Petrozavodsk State University Complex in Scientific-Education Space of European North”; from the Russian Foundation for Humantarian Research. Authors affiliated with N.N. Petrov Research Institute of Oncology, Russia; Petrozavodsk State University, Russia.)23237593
20 Anisimov VN, Zhukova OV, Beniashvili DS, Bilanishvili VG, Menabde MZ. 1994. Light deprivation, electromagnetic fields and mammary carcinogenesis. Adv Pineal Res 7: 229–234. (Support not reported. Authors affiliated with N.N. Petrov Research Institute of Oncology, Russia; Oncology Research Center, Republic of Georgia.)
21 Anjum B, Singh RB, Verma N, Singh R, Mahdi AA, Singh RK, de Meester F, Wilczynska A, Takahashi T, Dharwadkar S, Wilson DW. 2012. Associations of circadian disruption of sleep and nutritional factors with risk of cancer. Open Nutraceuticals J 5(Suppl.1): 124–135. (Support not reported. Authors affiliated with C S M Medical University, India; Halberg Hospital and Research Institute, India; SGRRIM & HS, India; Tsim Tsoum Institute, Poland; Fukuoka Women’s University, Japan; SB College of Science, India; School of Medicine and Health, UK.)
22 Anjum B, Verma NS, Tiwari S, Singh R, Fatima G, Singh P, Mishra S, Mahdi AA. 2013. Light exposure at night and rotating night shift associated with circadian disruption of 6-sulfatoxy melatonin. Int J Med Res Health Sci 2(4): 809–815. (Supported by the Council of Science & Technology, UP. Authors affiliated with King George’s Medical University, India.)
23 Antoch MP, Gorbacheva VY, Vykhovanets O, Toshkov IA, Kondratov RV, Kondratova AA, Lee C, Nikitin AY. 2008. Disruption of the circadian clock due to the Clock mutation has discrete effects on aging and carcinogenesis. Cell Cycle 7(9): 1197–1204. (Supported by NCI and a NCRR/NIH Midcareer Award in Mouse Pathobiology. Authors affiliated with Roswell Park Cancer Institute, NY; Cleveland Clinic Foundation, OH; Cornell University, NY; Cleveland State University, OH; Florida State University, FL.)18418054
24 Arble DM, Ramsey KM, Bass J, Turek FW. 2010. Circadian disruption and metabolic disease: findings from animal models. Best Pract Res Clin Endocrinol Metab 24(5): 785–800. (Supported by NIH/NIA and NIH/NHLBI. Authors affiliated with Northwestern University, IL.)21112026
25 Archer SN, Laing EE, Moller-Levet CS, van der Veen DR, Bucca G, Lazar AS, Santhi N, Slak A, Kabiljo R, von Schantz M, Smith CP, Dijk DJ. 2014. Mistimed sleep disrupts circadian regulation of the human transcriptome. Proc Natl Acad Sci U S A 111(6): E682–691. (Supported by the Biotechnology and Biological Sciences Research Council, the Air Force Office of Scientific Research, and the Royal Society. Authors affiliated with University of Surrey, UK.)24449876
26 Archer SN, Oster H. 2015. How sleep and wakefulness influence circadian rhythmicity: effects of insufficient and mistimed sleep on the animal and human transcriptome. J Sleep Res 24(5): 476–493. (Supported by the UK Biotechnology and Biological Sciences Research Council, the Air Force Office of Scientific Research, the German Research Foundation, and the Volkswagen Foundation. Authors affiliated with University of Surrey, UK; University of Lübeck, Germany.)26059855
27 Arellanes-Licea E, Caldelas I, De Ita-Pérez D, Díaz-Muñoz M. 2014. The circadian timing system: A recent addition in the physiological mechanisms underlying pathological and aging processes. Aging Dis 5(6): 406–418. (Supported by CONACYT and DGAPA-PAPIIT. Authors affiliated with UNAM, Mexico.)25489492
28 Arendt J. 2010. Shift work: coping with the biological clock. Occup Med (Lond) 60(1): 10–20. (Support not reported. Authors affiliated with University of Surrey, UK.)20051441
29 Arnold M, Leitzmann M, Freisling H, Bray F, Romieu I, Renehan A, Soerjomataram I. 2016. Obesity and cancer: An update of the global impact. Cancer Epidemiol 41: 8–15. (Supported by the World Cancer Research Fund International. Authors affiliated with IARC, France; University of Regensburg, Germany; University of Manchester, UK.)26775081
30 Asher G, Gatfield D, Stratmann M, Reinke H, Dibner C, Kreppel F, Mostoslavsky R, Alt FW, Schibler U. 2008. SIRT1 regulates circadian clock gene expression through PER2 deacetylation. Cell 134(2): 317–328. (Supported by the Swiss National Foundation, the State of Geneva, the Louis Jeantet Foundation of Medicine, the Bonizzi-Theler Stiftuung, the 6th European Framework Project EUCLOCK, EMBO, the Human Frontier Science Program, and FEBS. Authors affiliated with University of Geneva, Switzerland; University of Ulm, Germany; Harvard Medical School, MA.)18662546
31 Asher G, Sassone-Corsi P. 2015. Time for food: the intimate interplay between nutrition, metabolism, and the circadian clock. Cell 161(1): 84–92. (Supported by the Israel Science Foundation, the Abish-Frenkel Foundation, the HFSP Career Development Award, the European Research Council, NIH, ABOCA SpA [Italy], Institut National de la Sante et Recherche Medicale [INSERM, France], and a Novo Nordisk Foundation Challenge Grant. Authors affiliated with Weizmann Institute of Science, Israel; University of California, CA.)25815987
32 Atoum M, Alzoughool F. 2017. Vitamin D and breast cancer: Latest evidence and future steps. Breast Cancer (Auckl) 11: 1178223417749816. (Supported by the Hashemite University. Authors affiliated with Hashemite University, Jordan.)29434472
33 Aubert C, Janiaud P, Lecalvez J. 1980. Effect of pinealectomy and melatonin on mammary tumor growth in Sprague-Dawley rats under different conditions of lighting. J Neural Transm 47(2): 121–130. (Supported by the Institut National de la Santé et de la Recherche Médicale. Authors affiliated with Institut Gustave-Roussy, France.)6768843
34 Aubrecht TG, Weil ZM, Nelson RJ. 2014. Dim light at night interferes with the development of the short-day phenotype and impairs cell-mediated immunity in Siberian hamsters (Phodopus sungorus). J Exp Zool A Ecol Genet Physiol 321(8): 450–456. (Supported by NSF and NIDCR. Authors affiliated with Ohio State University Wexner Medical Center, OH.)24962267
35 Aulitzky W, Keen F, Daxenbichler G. 1984. The circadian rhythms of serum prolactin in nurses working on a night shift. Arch Gynecol 236(2): 73–75. (Support not reported. Authors affiliated with Universitätsklinik für Frauenheilkunde, Austria.)6524967
36 Balachandran D. 2011. Sleep and the immune system: Implications for health and mortality. In Sleep & Safety S Surani, S Subramanian, eds. Bentham Science Publishers Ltd. p. 52–59. (Support not reported. Author affiliated with University of Texas MD Anderson Cancer Center, TX.)
37 Ballesta A, Innominato PF, Dallmann R, Rand DA, Lévi FA. 2017. Systems chronotherapeutics. Pharmacol Rev 69(2): 161–199. (Supported by the 7th Framework Programme of the European Union through the Coordinating Action on Systems Medicine and by Cancer Research UK. Authors affiliated with University of Warwick, UK; Senate House, UK; INSERM, France; University Hospitals Birmingham National Health Service Foundation Trust, UK.)28351863
38 Balsalobre A, Brown SA, Marcacci L, Tronche F, Kellendonk C, Reichardt HM, Schütz G, Schibler U. 2000. Resetting of circadian time in peripheral tissues by glucocorticoid signaling. Science 289(5488): 2344–2347. (Supported by the Swiss National Science Foundation, the Louis-Jeantet Foundation for Medicine, and the State of Geneva [U.S.] and by the Deutsche Forschungsgemeinschaft and the European Union. Authors affiliated with Université de Genève, Switzerland; Deutsches Krebsforschungzentrum, Germany.)11009419
39 Baturin DA, Alimova IN, Anisimov VN, Popovich IG, Zabezhinski MA, Provinciali M, Mancini R, Franceschi C. 2001. The effect of light regimen and melatonin on the development of spontaneous mammary tumors in HER-2/neu transgenic mice is related to a downregulation of HER-2/neu gene expression. Neuro Endocrinol Lett 22(6): 441–447. (Supported by the Russian Foundation for Basic Research and Duke University. Authors affiliated with N.N. Petrov Research Institute of Oncology, Russia; INRCA, Italy; University of Bologna, Italy.)11781542
40 Bauer SE, Wagner SE, Burch J, Bayakly R, Vena JE. 2013. A case-referent study: light at night and breast cancer risk in Georgia. Int J Health Geogr 12: 23. (Supported by the Georgia Cancer Coalition. Authors affiliated with University of Georgia, GA; University of South Carolina, SC; Georgia Comprehensive Cancer Registry, GA.)23594790
41 Bedrosian TA, Fonken LK, Walton JC, Nelson RJ. 2011. Chronic exposure to dim light at night suppresses immune responses in Siberian hamsters. Biol Lett 7(3): 468–471. (Supported by the U.S. National Science Foundation and the U. S. Department of Defense through the National Defense Science and Engineering Graduate Fellowship [NDSEG] program. Authors affiliated with Ohio State University Medical Center, OH.)21270021
42 Bedrosian TA, Galan A, Vaughn CA, Weil ZM, Nelson RJ. 2013. Light at night alters daily patterns of cortisol and clock proteins in female Siberian hamsters. J Neuroendocrinol 25(6): 590–596. (Supported by a National Defense Science and Engineering Graduate [NDSEG] fellowship and NSF. Authors affiliated with Ohio State University Wexner Medical Center, OH.)23489976
43 Bedrosian TA, Nelson RJ. 2013. Influence of the modern light environment on mood. Mol Psychiatry 18(7): 751–757. (Support not reported. Authors affiliated with Ohio State University Wexner Medical Center, OH.)23711982
44 Behrens T, Rabstein S, Wichert K, Erbel R, Eisele L, Arendt M, Dragano N, Brüning T, Jöckel KH. 2017. Shift work and the incidence of prostate cancer: a 10-year follow-up of a German population-based cohort study. Scand J Work Environ Health 43(6): 560–568. (Supported by the German Social Accident Insurance, the Heinz Nixdorf Foundation, the German Ministry of Education and Science, the Kulturstiftung Essen, and the German Research Foundation. Authors affiliated with Institute of the Ruhr-Universität Bochum, Germany; University Hospital of Essen, Germany; Heinrich Heine University, Germany.)28879368
45 Belancio VP. 2015. LINE-1 activity as molecular basis for genomic instability associated with light exposure at night. Mob Genet Elements 5(3): 1–5. (Support not reported. Authors affiliated with Tulane University, LA.)
46 Ben-Shlomo R. 2014. Chronodisruption, cell cycle checkpoints and DNA repair. Indian J Exp Biol 52(5): 399–403. (Support not reported. Author affiliated with University of Haifa, Israel.)24851401
47 Beniashvili DS, Benjamin S, Baturin DA, Anisimov VN. 2001. Effect of light/dark regimen on N-nitrosoethylurea-induced transplacental carcinogenesis in rats. Cancer Lett 163(1): 51–57. (Support not reported. Authors affiliated with G. Wolfson Medical Center, Israel; N.N. Petrov Research Institute of Oncology, Russia.)11163108
48 Benna C, Helfrich-Förster C, Rajendran S, Monticelli H, Pilati P, Nitti D, Mocellin S. 2017. Genetic variation of clock genes and cancer risk: a field synopsis and meta-analysis. Oncotarget 8(14): 23978–23995. (Supported by the University of Padova. Authors affiliated with University of Padova, Italy; University of Würzburg, Germany; Azienda Ospedaliera Padova, Italy; Sant’Antonio Hospital, Italy; IOV-IRCSS, Italy.)28177907
49 Benot S, Molinero P, Soutto M, Goberna R, Guerrero JM. 1998. Circadian variations in the rat serum total antioxidant status: correlation with melatonin levels. J Pineal Res 25(1): 1–4. (Supported by the Dirección General de Investigación Científica y Técnica. Authors affiliated with University of Seville School of Medicine, Spain; Virgen Macarena Hospital, Spain.)9694397
50 Berson DM, Dunn FA, Takao M. 2002. Phototransduction by retinal ganglion cells that set the circadian clock. Science 295(5557): 1070–1073. (Supported by NIH. Authors affiliated with Brown University, RI.)11834835
51 Bhatti P, Cushing-Haugen KL, Wicklund KG, Doherty JA, Rossing MA. 2013a. Nightshift work and risk of ovarian cancer. Occup Environ Med 70(4): 231–237. (Supported by the US National Cancer Institute. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; Geisel School of Medicine at Dartmouth, NH.)23343856
52 Bhatti P, Mirick DK, Davis S. 2013b. Racial differences in the association between night shift work and melatonin levels among women. Am J Epidemiol 177(5): 388–393. (Supported by NIH. Authors affiliated with Fred Hutchinson Cancer Research Center, WA.)23380044
53 Bhatti P, Mirick DK, Davis S. 2014. The impact of chronotype on melatonin levels among shift workers. Occup Environ Med 71(3): 195–200. (Supported by the US National Cancer Institute. Authors affiliated with Fred Hutchinson Cancer Research Center, WA.)24399070
54 Bhatti P, Mirick DK, Randolph TW, Gong J, Buchanan DT, Zhang JJ, Davis S. 2016. Oxidative DNA damage during sleep periods among nightshift workers. Occup Environ Med 73(8): 537–544. (Supported by the V Foundation for Cancer Research and the US National Cancer Institute. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; Duke University, NC; University of Washington, WA.)27307003
55 Bhatti P, Mirick DK, Randolph TW, Gong J, Buchanan DT, Zhang JJ, Davis S. 2017. Oxidative DNA damage during night shift work. Occup Environ Med 74: 680–683. (Supported by the Fred Hutchinson Cancer Research Center, V Foundation for Cancer Research and the US National Cancer Institute. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; Duke University, NC; Peking University, China; University of Washington, WA.)28652381
56 Bhatti P, Zhang Y, Song X, Makar KW, Sather CL, Kelsey KT, Houseman EA, Wang P. 2015. Nightshift work and genome-wide DNA methylation. Chronobiol Int 32(1): 103–112. (Supported by the Fred Hutchinson Cancer Research Center and the Safeway Foundation. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; Brown University, RI; Oregon State University, OR; Mount Sinai Hospital, NY.)25187986
57 Bierman A, Klein TR, Rea MS. 2005. The daysimeter: A device for measuring optical radiation as a stimulus for the human circadian system. Measure Sci Technol 16: 2292–2299. (Supported by the California Energy Commission, Connecticut Light and Power, Iowa Energy Center, New York State Energy Research and Development Authority, North Carolina Daylighting Consortium, Northwest Energy Efficiency Alliance, and the United States Department of Energy. Authors affiliated with Rensselaer Polytechnic Institute, NY.)
58 Bjarnason GA, Jordan RC, Sothern RB. 1999. Circadian variation in the expression of cell-cycle proteins in human oral epithelium. Am J Pathol 154(2): 613–622. (Supported by the PMAC Health Research Foundation/Medical Research Council of Canada, The Sunnybrook Research Foundation, and a donation from Kathy and Paul Potvin. Authors affiliated with University of Toronto, Canada; Sunnybrook Health Science Centre, Canada; University of Minnesota, MN.)10027418
59 Bjarnason GA, Jordan RC, Wood PA, Li Q, Lincoln DW, Sothern RB, Hrushesky WJ, Ben-David Y. 2001. Circadian expression of clock genes in human oral mucosa and skin: association with specific cell-cycle phases. Am J Pathol 158(5): 1793–1801. (Supported by the Pharmaceutical Manufacturers Association of Canada Health Research Foundation/Medical Research Council of Canada, The Medical Research Council of Canada, the National Cancer Institute of Canada, the Office of Research and Development, Medical Research Service, Department of Veterans Affairs, the Robison Family Foundation, and the National Institutes of Health. Authors affiliated with Toronto-Sunnybrook Regional Cancer Centre, Canada; University of Toronto, Canada; Sunnybrook and Women’s College Health Sciences Centre, Canada; WJB Dorn VA Medical Center, SC; Stratton Veterans Affairs Medical Center, NY; University of Minnesota, MN.)11337377
60 Blask DE, Brainard GC, Dauchy RT, Hanifin JP, Davidson LK, Krause JA, Sauer LA, Rivera-Bermudez MA, Dubocovich ML, Jasser SA, Lynch DT, Rollag MD, Zalatan F. 2005. Melatonin-depleted blood from premenopausal women exposed to light at night stimulates growth of human breast cancer xenografts in nude rats. Cancer Res 65(23): 11174–11184. (Supported by NIH, the Laura Evans Memorial Breast Cancer Research Award of the Edwin W. Pauley Foundation, the Louis Busch Hager Cancer Center and the Stephen C. Clark Foundation. Authors affiliated with Bassett Research Institute, NY; Thomas Jefferson University, PA; Northwestern University Feinberg School of Medicine, IL; Uniformed Services University of the Health Sciences, MD.)16322268
61 Blask DE, Dauchy RT, Brainard GC, Hanifin JP. 2009. Circadian stage-dependent inhibition of human breast cancer metabolism and growth by the nocturnal melatonin signal: consequences of its disruption by light at night in rats and women. Integr Cancer Ther 8(4): 347–353. (Supported by NIH and the Laura Evans Memorial Breast Cancer Research Award of the Edwin W. Pauley Foundation. Authors affiliated with Tulane University School of Medicine, LA; Jefferson Medical College, PA.)20042410
62 Blask DE, Dauchy RT, Dauchy EM, Mao L, Hill SM, Greene MW, Belancio VP, Sauer LA, Davidson L. 2014. Light exposure at night disrupts host/cancer circadian regulatory dynamics: impact on the Warburg effect, lipid signaling and tumor growth prevention. PLoS One 9(8): e102776. (Supported by the American Association for Laboratory Animal Science, the National Institutes of Health, Tulane University School of Medicine and Louisiana Cancer Research Consortium. Authors affiliated with Tulane University School of Medicine, LA; Tulane Cancer Center and Louisiana Cancer Research Consortium, LA; Bassett Research Institute, NY.)25099274
63 Blask DE, Dauchy RT, Sauer LA, Krause JA. 2004. Melatonin uptake and growth prevention in rat hepatoma 7288CTC in response to dietary melatonin: melatonin receptormediated inhibition of tumor linoleic acid metabolism to the growth signaling molecule 13-hydroxyoctadecadienoic acid and the potential role of phytomelatonin. Carcinogenesis 25(6): 951–960. (Supported by NCI. Authors affiliated with Bassett Research Institute, NY.)14754876
64 Blask DE, Dauchy RT, Sauer LA, Krause JA, Brainard GC. 2002a. Light during darkness, melatonin suppression and cancer progression. Neuro Endocrinol Lett 23 Suppl 2: 52–56. (Supported by NCI, the Laura Evans Memorial Breast Cancer Research Fund of the E.W Pauley Foundation and the Louis Busch-Hager Cancer Center Research Fund. Authors affiliated with Bassett Research Institute, NY; Thomas Jefferson Medical College, PA.)12163849
65 Blask DE, Dauchy RT, Sauer LA, Krause JA, Brainard GC. 2003. Growth and fatty acid metabolism of human breast cancer (MCF-7) xenografts in nude rats: impact of constant light-induced nocturnal melatonin suppression. Breast Cancer Res Treat 79(3): 313–320. (Supported by NCI, the Laura Evans Memorial Breast Cancer Award of the Edwin W. Pauley Foundation and the Stephen C. Clark Research Fund. Authors affiliated with Bassett Research Institute, NY; Thomas Jefferson University, PA.)12846415
66 Blask DE, Hill SM, Dauchy RT, Xiang S, Yuan L, Duplessis T, Mao L, Dauchy E, Sauer LA. 2011. Circadian regulation of metabolic signaling mechanisms of human breast cancer growth by the nocturnal melatonin signal and the consequences of its disruption by light at night. J Pineal Res 51(3): 259–269. (Supported by NIH, the Army Department Of Defense, NIEHS, the Edwin W. Pauley Foundation, and Grants for Laboratory Animal Science. Authors affiliated with Laboratory of Chrono-Neuroendocrine Oncology, LA; Tulane University School of Medicine, LA; Tulane Cancer Center, LA; Louisiana Cancer Research Consortium, LA.)21605163
67 Blask DE, Sauer LA, Dauchy R, Holowachuk EW, Ruhoff MS. 1999. New actions of melatonin on tumor metabolism and growth. Biol Signals Recept 8(1–2): 49–55. (Support not reported. Authors affiliated with Bassett Research Institute, NY.)10085462
68 Blask DE, Sauer LA, Dauchy RT. 2002b. Melatonin as a chronobiotic/anticancer agent: cellular, biochemical, and molecular mechanisms of action and their implications for circadian-based cancer therapy. Curr Top Med Chem 2(2): 113–132. (Supported by NCI and the Stephen C. Clark Research Fund. Authors affiliated with Bassett Research Institute, NY.)11899096
69 BLS. 2004. Current Population Survey, May 2004: Work Schedules and Work at Home Supplement File. Technical Documentation CPS—04. Washington, D.C.: Bureau of Labor Statistics, US Department of Labor. 221 pp.
70 BLS. 2005. Workers on Flexible and Shift Schedules in May 2004. USDL 05-1198. U.S. Department of Labor, Bureau of Labor Statistics. 14 pp. https://www.bls.gov/news.release/flex.nr0.htm.
71 BLS. 2017a. Occupational Outlook Handbook: Airline and Commercial Pilots. Bureau of Labor Statistics. Accessed on 11/7/17. https://www.bls.gov/ooh/transportation-and-material-moving/airline-and-commercial-pilots.htm
72 BLS. 2017b. Occupational Outlook Handbook: Flight Attendants. Bureau of Labor Statistics. Accessed on 11/7/17. https://www.bls.gov/ooh/transportation-and-material-moving/flight-attendants.htm
73 Boivin DB, Boudreau P. 2014. Impacts of shift work on sleep and circadian rhythms. Pathol Biol (Paris) 62(5): 292–301. (Support not reported. Authors affiliated with McGill University, Canada.)25246026
74 Bollati V, Baccarelli A, Sartori S, Tarantini L, Motta V, Rota F, Costa G. 2010. Epigenetic effects of shiftwork on blood DNA methylation. Chronobiol Int 27(5): 1093–1104. (Support not reported. Authors affiliated with Università degli Studi di Milano, Italy; Foundation IRCCS Ca’ Granda–Ospedale Maggiore Policlinico, Italy.)20636218
75 Bonde JP, Hansen J, Kolstad HA, Mikkelsen S, Olsen JH, Blask DE, Harma M, Kjuus H, de Koning HJ, Olsen J, Moller M, Schernhammer ES, Stevens RG, Akerstedt T. 2012. Work at night and breast cancer--report on evidence-based options for preventive actions. Scand J Work Environ Health 38(4): 380–390. (Supported by the Danish Society of Cancer, Danish regions, and the Danish Nurses’ Organization. Authors affiliated with University of Copenhagen, Denmark; Danish Cancer Society, Denmark; Aarhus University Hospital, Denmark; Tulane University, LA; Finnish Institute of Occupational Health, Finland; National Institute of Occupational Health, Norway; University Medical Center Rotterdam, Netherlands; University of California, CA; University of Aarhus, Denmark; Brigham and Women’s Hospital and Harvard Medical School, MA; Harvard School of Public Health, MA: University of Connecticut Health Center, CT; Stockholm University, Sweden; Karolinska Institutet, Sweden.)22349009
76 Bonkhoff H. 2018. Estrogen receptor signaling in prostate cancer: Implications for carcinogenesis and tumor progression. Prostate 78(1): 2–10. (Support not reported. Authors affiliated with Pathology Laboratory, Germany.)29094395
77 Boquet A, Cruz C, Nesthus T, Detwiler C, Knecht W, Holcomb K. 2004. Clockwise and counterclockwise rotating shifts: effects on temperature and neuroendocrine measures. Aviat Space Environ Med 75(10): 898–904. (Support not reported. Authors affiliated with Federal Aviation Administration Civil Aerospace Medical Institute, OK.)15497371
78 Borisenkov MF. 2011. Latitude of residence and position in time zone are predictors of cancer incidence, cancer mortality, and life expectancy at birth. Chronobiol Int 28(2): 155–162. (Support not reported. Authors affiliated with Russian Academy of Science, Russia.)21231877
79 Borugian MJ, Gallagher RP, Friesen MC, Switzer TF, Aronson KJ. 2005. Twenty-four-hour light exposure and melatonin levels among shift workers. J Occup Environ Med 47(12): 1268–1275. (Supported by the Workers’ Compensation Board of British Columbia and the National Cancer Institute of Canada. Authors affiliated with British Columbia Cancer Research Centre, Canada; Queen’s University, Canada.)16340708
80 Bracci M, Ciarapica V, Copertaro A, Barbaresi M, Manzella N, Tomasetti M, Gaetani S, Monaco F, Amati M, Valentino M, Rapisarda V, Santarelli L. 2016. Peripheral skin temperature and circadian biological clock in shift nurses after a day off. Int J Mol Sci 17(5). (Support not reported. Authors affiliated with Polytechnic University of Marche, Italy; Loreto Hospital, Italy; University of Catania, Italy.)
81 Bracci M, Copertaro A, Manzella N, Staffolani S, Strafella E, Nocchi L, Barbaresi M, Copertaro B, Rapisarda V, Valentino M, Santarelli L. 2013. Influence of night-shift and napping at work on urinary melatonin, 17-beta-estradiol and clock gene expression in pre-menopausal nurses. J Biol Regul Homeost Agents 27(1): 267–274. (Supported by the Italian Institute of Insurance against Professional Illness and Injuries [INAIL]. Authors affiliated with Polytechnic University of Marche, Italy; Loreto Hospital, Italy; University of Catania, Italy.)23489707
82 Bracci M, Manzella N, Copertaro A, Staffolani S, Strafella E, Barbaresi M, Copertaro B, Rapisarda V, Valentino M, Santarelli L. 2014. Rotating-shift nurses after a day off: peripheral clock gene expression, urinary melatonin, and serum 17-beta-estradiol levels. Scand J Work Environ Health 40(3): 295–304. (Supported by the Italian Institute of Insurance against Professional Illness and Injuries [INAIL]. Authors affiliated with Polytechnic University of Marche, Italy; Loreto Hospital, Italy; University of Catania, Italy.)24402410
83 Brainard GC, Hanifin JP, Greeson JM, Byrne B, Glickman G, Gerner E, Rollag MD. 2001. Action spectrum for melatonin regulation in humans: evidence for a novel circadian photoreceptor. J Neurosci 21(16): 6405–6412. (Supported by the National Institutes of Health, the NASA Cooperative Agreement with the National Space Biomedical Research Institute, a National Science Foundation Grant and a Department of Defense Grant. Authors affiliated with Thomas Jefferson University, PA; Uniformed Services University of Health Sciences, MD.)11487664
84 Brown GM. 1994. Light, melatonin and the sleep-wake cycle. J Psychiatry Neurosci 19(5): 345–353. (Support not reported. Authors affiliated with Clarke Institute of Psychiatry, Canada.)7803368
85 Brown SA, Azzi A. 2013. Peripheral circadian oscillators in mammals. In Circadian Clocks 2013/04/23. A Kramer, M Merrow, eds. Berlin: Springer. pp. 45–66. (Supported by the Swiss National Science Foundation, the Swiss Cancer League, the Velux Foundation, the Zurich Neurozentrum [ZNZ] and Molecular Life Sciences Program. Authors affiliated with Institute of Pharmacology and Toxicology, Switzerland.)
86 Brown SB, Hankinson SE, Eliassen AH, Reeves KW, Qian J, Arcaro KF, Wegrzyn LR, Willett WC, Schernhammer ES. 2015. Urinary melatonin concentration and the risk of breast cancer in Nurses’ Health Study II. Am J Epidemiol 181(3): 155–162. (Supported by NIH. Authors affiliated with University of Massachusetts, MA; Harvard School of Public Health, MA; Brigham and Women’s Hospital, MA; Harvard Medical School, MA.)25587174
87 Buhr ED, Takahashi JS. 2013. Molecular components of the mammalian circadian clock. Handb Exp Pharmacol(217): 3–27. (Support not reported. Authors affiliated with University of Texas Southwestern Medical Center, TX.)
88 Buhr ED, Yoo SH, Takahashi JS. 2010. Temperature as a universal resetting cue for mammalian circadian oscillators. Science 330(6002): 379–385. (Supported by NIH and the Howard Hughes Medical Institute. Authors affiliated with Northwestern University, IL; University of Texas Southwestern Medical Center, TX.)20947768
89 Buijs RM, Kalsbeek A. 2001. Hypothalamic integration of central and peripheral clocks. Nat Rev Neurosci 2(7): 521–526. (Support not reported. Authors affiliated with Netherlands Institute for Brain Research, Netherlands.)11433377
90 Bukowska A, Sobala W, Peplonska B. 2015. Rotating night shift work, sleep quality, selected lifestyle factors and prolactin concentration in nurses and midwives. Chronobiol Int 32(3): 318–326. (Supported by the Polish-Norwegian Research Programme and the Nofer Institute of Occupational Medicine. Authors affiliated with Nofer Institute of Occupational Medicine, Poland.)25364814
91 Bullough JD, Rea MS, Figueiro MG. 2006. Of mice and women: light as a circadian stimulus in breast cancer research. Cancer Causes Control 17(4): 375–383. (Supported by the Lighting Research Center and by the National Institute of Environmental Health Sciences. Authors affiliated with Rensselaer Polytechnic Institute, NY.)16596289
92 Burch JB, Yost MG, Johnson W, Allen E. 2005. Melatonin, sleep, and shift work adaptation. J Occup Environ Med 47(9): 893–901. (Supported by the National Institute for Occupational Safety and Health, National Institutes of Health. Authors affiliated with Colorado State University, CO; University of Washington, WA.)16155474
93 Burgueño A, Gemma C, Gianotti TF, Sookoian S, Pirola CJ. 2010. Increased levels of resistin in rotating shift workers: a potential mediator of cardiovascular risk associated with circadian misalignment. Atherosclerosis 210(2): 625–629. (Supported by the Universidad de Buenos Aires, the Agencia Nacional de Promoción Científica y Tecnológica and the Consejo Nacional de Investigaciones Científicas. Authors affiliated with University of Buenos Aires-National Council of Scientific and Technological Research [CONICET], Argentina.)20106477
94 Business Management Systems. 2017. Metropolitan Rotating Shift Schedule: 24/7 Shift Coverage. Business Management Systems. Accessed on 2/6/18. http://www.bmscentral.com/learn-employee-scheduling/metropolitan-shift-schedule/
95 Buss MR, Wirth MD, Burch JB. 2018. Association of shiftwork and leukocytes among national health and nutrition examination survey respondents. Chronobiol Int 35(3): 435–439. (Support not reported. Authors affiliated with University of South Carolina, SC; Connecting Healthy Innovations, SC; WJB Dorn VA Medical Center, SC.)29211507
96 Buyukhatipoglu H, Kirhan I, Vural M, Taskin A, Sezen Y, Dag OF, Turan MN, Aksoy N. 2010. Oxidative stress increased in healthcare workers working 24-hour on-call shifts. Am J Med Sci 340(6): 462–467. (Support not reported. Authors affiliated with Harran University School of Medicine, Turkey.)20811270
97 Cadenas C, van de Sandt L, Edlund K, Lohr M, Hellwig B, Marchan R, Schmidt M, Rahnenführer J, Oster H, Hengstler JG. 2014. Loss of circadian clock gene expression is associated with tumor progression in breast cancer. Cell Cycle 13(20): 3282–3291. (Supported by BMBF. Authors affiliated with TU Dortmund University, Germany; Johannes Gutenberg University, Germany; University of Lübeck, Germany.)25485508
98 Cajochen C, Frey S, Anders D, Späti J, Bues M, Pross A, Mager R, Wirz-Justice A, Stefani O. 2011. Evening exposure to a light-emitting diodes (LED)-backlit computer screen affects circadian physiology and cognitive performance. J Appl Physiol 110(5): 1432–1438. (Supported by the Daimler-Benz-Foundation and by the EU 6th Framework Project EUCLOCK. Authors affiliated with University of Basel, Switzerland; Fraunhofer IAO/University Stuttgart IAT, Germany.)21415172
99 Cajochen C, Jud C, Münch M, Kobialka S, Wirz-Justice A, Albrecht U. 2006. Evening exposure to blue light stimulates the expression of the clock gene PER2 in humans. Eur J Neurosci 23(4): 1082–1086. (Supported by the Velux Foundation, Switzerland, and in part by the Swiss National Foundation Grants START, the State of Fribourg, the EC grant ‘Braintime,’ the Federal Office for Science and Education, and by the EU 6th Framework Project EUCLOCK. Authors affiliated with University of Basel, Switzerland; University of Fribourg, Switzerland.)16519674
100 Carreón T, Hein MJ, Hanley KW, Viet SM, Ruder AM. 2014. Coronary artery disease and cancer mortality in a cohort of workers exposed to vinyl chloride, carbon disulfide, rotating shift work, and o-toluidine at a chemical manufacturing plant. Am J Ind Med 57(4): 398–411. (Supported by NIOSH. Authors affiliated with National Institute for Occupational Safety and Health, OH; Westat, MD.)24464642
101 Carter BD, Diver WR, Hildebrand JS, Patel AV, Gapstur SM. 2014. Circadian disruption and fatal ovarian cancer. Am J Prev Med 46(3 Suppl 1): S34–41. (Supported by the American Cancer Society. Authors affiliated with American Cancer Society, GA.)24512929
102 Carter N, Henderson R, Lal S, Hart M, Booth S, Hunyor S. 2002. Cardiovascular and autonomic response to environmental noise during sleep in night shift workers. Sleep 25(4): 457–464. (Supported by ARRB Transport Research Ltd., Vermont South, Victoria, Australia, and the Roads and Traffic Authority of New South Wales, Sydney, Australia. Authors affiliated with University of Sydney, Australia; University of Technology, Australia; Royal Prince Alfred Hospital, Australia; Royal North Shore Hospital. Australia.)12071548
103 Casado A, Castellanos A, López-Fernández ME, Ruíz R, Aroca CG, Noriega F. 2008. Relationship between oxidative and occupational stress and aging in nurses of an intensive care unit. Age (Dordr) 30(4): 229–236. (Supported by the Foundation Yebenes Velo. Authors affiliated with CSIC, Spain; Hospital General Universitario Gregorio Marañón, Spain.)19424846
104 Casado A, Castellanos A, López-Fernández ME, Ruiz R, López Imedio E, Castillo C, Fernández-Nieto AM. 2011. Determination of oxidative and occupational stress in palliative care workers. Clin Chem Lab Med 49(3): 471–477. (Supported by the Yebenes Velo Foundation. Authors affiliated with CSIC, Spain; Hospital General Universitario Gregorio Marañón, Spain.)21143019
105 Castanon-Cervantes O, Wu MW, Ehlen JC, Paul K, Gamble KL, Johnson RL, Besing RC, Menaker M, Gewirtz AT, Davidson AJ. 2010. Dysregulation of inflammatory responses by chronic circadian disruption. J Immunol 185(10): 5796–5805. (Supported by NIH, NCRR, RCMI, NCMHHD, the Georgia Research Alliance, and the NSF Center for Behavioral Neuroscience. Authors affiliated with Morehouse School of Medicine, GA; University of Alabama at Birmingham, AL; University of Virginia, VA; Emory University, GA.)20944004
106 CDC. 2015. CDC-NIOSH Worker Health Charts. Work Organization. Centers for Disease Control and Prevention. Accessed on 3/21/18. https://wwwn.cdc.gov/Niosh-whc/chart/ohs-workorg/work and select “All Work Organization” from drop-down menu for work organization and “adjusted prevalence” from drop-down menu for value to chart to find adjusted prevalence of frequent night work and shift work (with estimates of numbers of workers exposed). See PDF cover page for other query instructions
107 Cermakian N, Westfall S, Kiessling S. 2014. Circadian clocks and inflammation: reciprocal regulation and shared mediators. Arch Immunol Ther Exp (Warsz) 62(4): 303–318. (Supported by the Canadian Institutes for Health Research, and FRQS. Authors affiliated with McGill University, Canada.)24687370
108 Chan MM, Lu X, Merchant FM, Iglehart JD, Miron PL. 2005. Gene expression profiling of NMU-induced rat mammary tumors: cross species comparison with human breast cancer. Carcinogenesis 26(8): 1343–1353. (Supported by the Womens’ Cancers Program, Dana Farber Cancer Institute, the Breast Cancer Research Foundation, the Dana Farber/Harvard SPORE in Breast Cancer from the NCI, and the Ruth L. Kirschstein National Research Service Award. Authors affiliated with Beth Israel Deaconess Medical Center, MA; Harvard School of Public Health, MA; Massachusetts General Hospital, MA; Brigham and Women’s Hospital, MA; Dana-Farber Cancer Institute, MA.)15845649
109 Chang AM, Aeschbach D, Duffy JF, Czeisler CA. 2015. Evening use of light-emitting eReaders negatively affects sleep, circadian timing, and next-morning alertness. Proc Natl Acad Sci U S A 112(4): 1232–1237. (Supported by the Harvard Catalyst CTSC, National Center for Research Resources [NCRR], the National Center for Advancing Translational Sciences, National Institutes of Health, the Brigham and Women’s Hospital [BWH], Harvard University, the German Aerospace Center, NASA, and the National Space Biomedical Research Institute. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; German Aerospace Center, Germany; Pennsylvania State University, PA.)25535358
110 Chen-Goodspeed M, Lee CC. 2007. Tumor suppression and circadian function. J Biol Rhythms 22(4): 291–298. (Support not reported. Authors affiliated with University of Texas Health Science Center, TX.)17660446
111 Chen A, Du L, Xu Y, Chen L, Wu Y. 2005. The effect of blue light exposure on the expression of circadian genes: bmal1 and cryptochrome 1 in peripheral blood mononuclear cells of jaundiced neonates. Pediatr Res 58(6): 1180–1184. (Support not reported. Authors affiliated with Children’s Hospital of Zhejiang University School of Medicine, China.)16306190
112 Chen P, Hu P, Xie D, Qin Y, Wang F, Wang H. 2010. Meta-analysis of vitamin D, calcium and the prevention of breast cancer. Breast Cancer Res Treat 121(2): 469–477. (Supported by the One Hundred Talents Program of the Chinese Academy of Sciences, the National Nature Science Foundation, the Ministry of Science and Technology of China, the Science and Technology Commission of Shanghai Municipality, the Food Safety Research Center and Key Laboratory of Nutrition and Metabolism. Authors affiliated with Chinese Academy of Sciences, China.)19851861
113 Chi P, Allis CD, Wang GG. 2010. Covalent histone modifications--miswritten, misinterpreted and mis-erased in human cancers. Nat Rev Cancer 10(7): 457–469. (Supported by NIH and the Starr Cancer Consortium. Authors affiliated with Rockefeller University, NY; Memorial Sloan-Kettering Cancer Center, NY.)20574448
114 Chinoy ED, Duffy JF, Czeisler CA. 2018. Unrestricted evening use of light-emitting tablet computers delays self-selected bedtime and disrupts circadian timing and alertness. Physiol Rep 6(10): e13692. (Supported by NIH, Brigham and Women’s Hospital, and Harvard University and its affiliated academic health care centers. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA.)29845764
115 Chollet-Hinton L, Olshan AF, Nichols HB, Anders CK, Lund JL, Allott EH, Bethea TN, Hong CC, Cohen SM, Khoury T, Zirpoli GR, Borges VF, Rosenberg LA, Bandera EV, Ambrosone CB, Palmer JR, Troester MA. 2017. Biology and etiology of young-onset breast cancers among premenopausal African American women: Results from the AMBER Consortium. Cancer Epidemiol Biomarkers Prev 26(12): 1722–1729. (Supported by NCI, NIH, the University of North Carolina LCCC Cancer Control and Education Program, the Department of Defense Breast Cancer Research Program, the University Cancer Research Fund of North Carolina, the Susan G. Komen for the Cure Foundation, and the Breast Cancer Research Foundation. Authors affiliated with University of North Carolina at Chapel Hill, NC; Boston University, MA; Roswell Park Cancer Institute, NY; University of Colorado School of Medicine, CO; Rutgers Cancer Institute of New Jersey, NJ.)28903991
116 Chowdhury I, Sengupta A, Maitra SK. 2008. Melatonin: Fifty years of scientific journey from the discovery in bovine pineal gland to delineation of functions in human. Indian J Biochem Biophys 45(5): 289–304. (Supported by DAAD, DBT, DST, and CSIR. Authors affiliated with Morehouse School of Medicine, GA; Visva-Bharati University, India.)19069840
117 Clausen OP, Iversen OH, Thorud E. 1984. Circadian variation in the susceptibility of mouse epidermis to tumour induction by methylnitrosourea. Virchows Arch B Cell Pathol Incl Mol Pathol 45(3): 325–329. (Support not reported. Authors affiliated with University of Oslo, Norway.)6146223
118 Cole RJ, Kripke DF, Wisbey J, Mason WJ, Gruen W, Hauri PJ, Juarez S. 1995. Seasonal variation in human illumination exposure at two different latitudes. J Biol Rhythms 10(4): 324–334. (Supported by NIMH and the Department of Veteran’s Affairs. Authors affiliated with University of California - San Diego, CA; Synchrony Applied Health Sciences, CA; Mayo Clinic Sleep Disorders Center, MN; Ambulatory Monitoring, Inc., NY.)8639941
119 Cole SW, Nagaraja AS, Lutgendorf SK, Green PA, Sood AK. 2015. Sympathetic nervous system regulation of the tumour microenvironment. Nat Rev Cancer 15(9): 563–572. (Supported by the United States National Institutes of Health, the Department of Defense, the Betty Ann Asche Murray Distinguished Professorship, the Cancer Prevention and Research Institute of Texas, and the Breast Cancer Research Foundation. Authors affiliated with University of California - Los Angeles, CA; University of Texas M. D. Anderson Comprehensive Cancer Center, TX; University of Iowa, IA; United States National Cancer Institute, MD.)26299593
120 Colín-González AL, Aguilera G, Serratos IN, Escribano BM, Santamaría A, Túnez I. 2015. On the relationship between the light/dark cycle, melatonin and oxidative stress. Curr Pharm Des 21(24): 3477–3488. (Support not reported Authors affiliated with Instituto Nacional de Neurologia y Neurocirugia, Mexico; Universidad Autonoma Metropolitana-Iztapalapa, Mexico; Universidad de Cordoba, Spain; IMIBIC, Spain; RETICEF.)26144936
121 Conlon M, Lightfoot N, Kreiger N. 2007. Rotating shift work and risk of prostate cancer. Epidemiology 18(1): 182–183. (Support not reported. Authors affiliated with Sudbury Regional Hospital, Canada; Ontario School of Medicine, Canada; University of Toronto, Canada.)17179764
122 Copertaro A, Bracci M, Gesuita R, Carle F, Amati M, Baldassari M, Mocchegiani E, Santarelli L. 2011. Influence of shift-work on selected immune variables in nurses. Ind Health 49(5): 597–604. (Support not reported. Authors affiliated with Loreto Hospital, Italy; Polytechnic University of Marche, Italy; Biostatistics and Medical Information Technology, Italy; United Hospitals of Ancona, Italy; Istituto Nazionale Riposo e Cura Anziani (INRCA), Italy.)21804267
123 Copertaro A, Bracci M, Monica A, Mocchegiani E, Barbaresi M, Copertaro B, Santarelli L. 2010. [Biological risk and health care workers: Analysis of the effects of work chronobiology on the immune system]. Med Lav 101(6): 427–436. (Support unknown due to foreign language. Authors affiliated with Medicina Del Lavoro-Servizio Del Medico Competente, Italy; Università Politecnica Delle Marche, Italy; INCRA, Italy.)21141454
124 Cordina-Duverger E, Koudou Y, Truong T, Arveux P, Kerbrat P, Menegaux F, Guénel P. 2016. Night work and breast cancer risk defined by human epidermal growth factor receptor-2 (HER2) and hormone receptor status: A population-based case-control study in France. Chronobiol Int 33(6): 783–787. (Supported by the Agence nationale de sécurité sanitaire de l’alimentation, de l’environnement et du travail [ANSES], the Agence Nationale de la Recherche [ANR]; Fondation de France, the Institut National du Cancer [INCA], and the Ligue contre le Cancer. Authors affiliated with INSERM, France; Centre Georges-François Leclerc, France; Centre Eugène Marquis, France.)27078711
125 Cordina-Duverger E, Menegaux F, Popa A, Rabstein S, Harth V, Pesch B, Brüning T, Fritschi L, Glass DC, Heyworth JS, Erren TC, Castaño-Vinyals G, Papantoniou K, Espinosa A, Kogevinas M, Grundy A, Spinelli JJ, Aronson KJ, Guénel P. 2018. Night shift work and breast cancer: a pooled analysis of population-based case-control studies with complete work history. Eur J Epidemiol. (Support not reported. Authors affiliated with INSERM, France; Institute of the Ruhr-Universität Bochum, Germany; University Medical Center Hamburg-Eppendorf, Germany; Curtin University, Australia; Monash University, Australia; University of Western Australia, Australia; University of Cologne, Germany; CREAL, Spain; IMIM, Spain; Universitat Pompeu Fabra, Spain; CIBERESP, Spain; Medical University of Vienna, Austria; CRCHUM, Canada; Universite´ de Montréal, Canada; BC Cancer, Canada; University of British Columbia, Canada; Queen’s University, Canada.)
126 Cos S, Fernández R, Güézmes A, Sánchez-Barceló EJ. 1998. Influence of melatonin on invasive and metastatic properties of MCF-7 human breast cancer cells. Cancer Res 58(19): 4383–4390. (Supported by the Spanish General Direction of Scientific and Technological Investigation [DGICYT] and the Marqués de Valdecilla Foundation. Authors affiliated with University of Cantabria, Spain; “Sierrallana” Hospital, Spain.)9766668
127 Cos S, Mediavilla D, Martínez-Campa C, González A, Alonso-González C, Sanchez-Barceló EJ. 2006. Exposure to light-at-night increases the growth of DMBA-induced mammary adenocarcinomas in rats. Cancer Lett 235(2): 266–271. (Supported by the Spanish MCYT and Institute of Health ‘Carlos III.’ Authors affiliated with University of Cantabria, Spain.)15950374
128 Costa G, Bertoldi A, Kovacic M, Ghirlanda G, Minors DS, Waterhouse JM. 1997. Hormonal secretion of nurses engaged in fast-rotating shift systems. Int J Occup Environ Health 3(Suppl 2): S35–S39. (Support not reported. Authors affiliated with University of Verona, Italy; Policlinic Hospital, Italy; Universiiy of Manchester, UK; John Moores University of Liverpool, UK.)9891136
129 Costa G, Ghirlanda G, Tarondi G, Minors D, Waterhouse J. 1994. Evaluation of a rapidly rotating shift system for tolerance of nurses to nightwork. Int Arch Occup Environ Health 65(5): 305–311. (Support not reported. Authors affiliated with University of Verona, Italy; Policlinic and General Hospital Staff Management, Italy; University of Manchester, UK.)8175185
130 Costa G, Haus E, Stevens R. 2010. Shift work and cancer - considerations on rationale, mechanisms, and epidemiology. Scand J Work Environ Health 36(2): 163–179. (Support not reported. Authors affiliated with University of Milano/Fondazione IRCCS “Cà Granda – Ospedale Maggiore Policlinico," Italy; University of Minnesota/HealthPartners Medical Group/Regions Hospital, MO; University of Connecticut Health Center, CT.)20126969
131 Costas L, Benavente Y, Olmedo-Requena R, Casabonne D, Robles C, Gonzalez-Barca EM, de la Banda E, Alonso E, Aymerich M, Tardón A, Marcos-Gragera R, Gimeno-Vázquez E, Gómez-Acebo I, Papantoniou K, Castaño-Vinyals G, Aragonés N, Pollán M, Kogevinas M, de Sanjosé S. 2016. Night shift work and chronic lymphocytic leukemia in the MCC-Spain case-control study. Int J Cancer. (Supported by the Spanish Ministry of Economy and Competitiveness, Carlos III Institute of Health, and the Catalan Government. Authors affiliated with Catalan Institute of Oncology, Spain; University of Barcelona, Spain; Consortium for Biomedical Research in Epidemiology and Public Health, Spain; University of Granada, Spain; IARC, France; Hospital Universitari de Bellvitge, Spain; University of Oviedo, Spain; Universitat de Girona, Spain; Hospital del Mar, Spain; Grup de Recerca Aplicada en Neoplasies Hematològiques-PSMAR, Spain; Universidad de Cantabria, Spain; Centre for Research in Environmental Epidemiology, Spain; Medical University of Vienna, Austria; Hospital del Mar Medical Research Institute, Spain; Universitat Pompeu Fabra, Spain; Carlos III Institute of Health, Spain; IIS Puerta de Hierro, Spain; National School of Public Health, Greece.)
132 Crowley SJ, Cain SW, Burns AC, Acebo C, Carskadon MA. 2015. Increased sensitivity of the circadian system to light in early/mid-puberty. J Clin Endocrinol Metab 100(11): 4067–4073. (Supported by the National Institute of Mental Health and the National Heart Lung and Blood Institute. Authors affiliated with Rush University Medical Center, IL; Monash University, Australia; Bradley Hospital Sleep and Chronobiology Research Laboratory, RI; Brown University, RI; University of S Australia, Australia.)26301944
133 Cuesta M, Boudreau P, Dubeau-Laramée G, Cermakian N, Boivin DB. 2016. Simulated night shift disrupts circadian rhythms of immune functions in humans. J. Immunol. 196(196): 2466–2475. (Supported by the Canadian Institutes of Health Research, the McGill–Neuroscience Center Zurich partnership in Neurosciences, the Institut de recherche Robert-Sauvé en santé et en sécurité du travail du Québec, and the Fonds de Recherche du Québec–Sante. Authors affiliated with McGill University, Canada.)26873990
134 Curtis AM, Seo SB, Westgate EJ, Rudic RD, Smyth EM, Chakravarti D, FitzGerald GA, McNamara P. 2004. Histone acetyltransferase-dependent chromatin remodeling and the vascular clock. J Biol Chem 279(8): 7091–7097. (Supported by NIH. Authors affiliated with University of Pennsylvania, PA; Seoul National University, Korea; Phenomix Corporation, CA.)14645221
135 Dall GV, Britt KL. 2017. Estrogen effects on the mammary gland in early and late life and breast cancer risk. Front Oncol 7: 110. (Supported by the National Breast Cancer Research Foundation of Australia, The National Health and Medical Research Council of Australia, and the Peter MacCallum Cancer Centre. Authors affiliated with Peter MacCallum Cancer Centre, Australia; University of Melbourne, Australia.)28603694
136 Damiola F, Le Minh N, Preitner N, Kornmann B, Fleury-Olela F, Schibler U. 2000. Restricted feeding uncouples circadian oscillators in peripheral tissues from the central pacemaker in the suprachiasmatic nucleus. Genes Dev 14(23): 2950–2961. (Supported by the Swiss National Science Foundation, the State of Geneva, the Bonizzi-Theler Stiftung, and the Louis-Jeantet Foundation for Medicine. Authors affiliated with Université de Genève, Switzerland.)11114885
137 Datta K, Roy A, Nanda D, Das I, Guha S, Ghosh D, Sikdar S, Biswas J. 2014. Association of breast cancer with sleep pattern--a pilot case control study in a regional cancer centre in South Asia. Asian Pac J Cancer Prev 15(20): 8641–8645. (Support not reported. Authors affiliated with Chittaranjan National Cancer Institute, India.)25374182
138 Dauchy R, Blask D, Dauchy E, Hill C, Davidson L, Tirrell P, Greene M, Wu JH, Tirrell R, Lynch D, Sauer L. 2009a. Expression and light at night induced disruption of circadian dynamics in fatty acid and glucose metabolism, signal transduction, proliferative activity and clock gene expression in tissue-isolated human breast cancer xenografts in nude rats. Cancer Res 69: 1. (Support not reported. Authors affiliated with Tulane University School of Medicine, LA; The Mary Imogene Bassett Hospital, NY.)19117978
139 Dauchy RT, Blask DE, Dauchy EM, Davidson LK, Tirrell PC, Greene MW, Tirrell RP, Hill CR, Sauer LA. 2009b. Antineoplastic effects of melatonin on a rare malignancy of mesenchymal origin: melatonin receptor-mediated inhibition of signal transduction, linoleic acid metabolism and growth in tissue-isolated human leiomyosarcoma xenografts. J Pineal Res 47(1): 32–42. (Supported by the National Leiomyosarcoma Foundation. Authors affiliated with Tulane University School of Medicine, LA; Bassett Research Institute, NY.)19486272
140 Dauchy RT, Blask DE, Sauer LA, Brainard GC, Krause JA. 1999. Dim light during darkness stimulates tumor progression by enhancing tumor fatty acid uptake and metabolism. Cancer Lett 144(2): 131–136. (Supported by the Stephen C. Clark Research Fund and NIH. Authors affiliated with Bassett Research Institute, NY; Thomas Jefferson University, PA.)10529012
141 Dauchy RT, Blask DE, Sauer LA, Davidson LK, Krause JA, Smith LC, Dauchy EM. 2003. Physiologic melatonin concentration, omega-3 fatty acids, and conjugated linoleic acid inhibit fatty acid transport in rodent hind limb skeletal muscle in vivo. Comp Med 53(2): 186–190. (Supported by NCI and the Stephen C. Clark Research Fund. Authors affiliated with Bassett Research Institute, NY.)12784853
142 Dauchy RT, Dauchy EM, Davidson LK, Krause JA, Lynch DT, Tirrell PC, Tirrell RP, Sauer LA, Van der Riet P, Blask DE. 2007. Inhibition of fatty acid transport and proliferative activity in tissue-isolated human squamous cell cancer xenografts perfused in situ with melatonin or eicosapentaenoic or conjugated linoleic acids. Comp Med 57(4): 377–382. (Supported by the National Cancer Institute and by the Stephen E Clark Research Fund. Authors affiliated with Bassett Research Institute, NY.)17803052
143 Dauchy RT, Dauchy EM, Hanifin JP, Gauthreaux SL, Mao L, Belancio VP, Ooms TG, Dupepe LM, Jablonski MR, Warfield B, Wren MA, Brainard GC, Hill SM, Blask DE. 2013. Effects of spectral transmittance through standard laboratory cages on circadian metabolism and physiology in nude rats. J Am Assoc Lab Anim Sci 52(2): 146–156. (Supported by the Tulane University School of Medicine, the Louisiana Cancer Research Consortium, NIH, AALAS, the Ellison Medical Foundation, and the Institute of Integrative Health. Authors affiliated with Tulane University School of Medicine, LA; Thomas Jefferson University, PA.)23562097
144 Dauchy RT, Dupepe LM, Ooms TG, Dauchy EM, Hill CR, Mao L, Belancio VP, Slakey LM, Hill SM, Blask DE. 2011. Eliminating animal facility light-at-night contamination and its effect on circadian regulation of rodent physiology, tumor growth, and metabolism: a challenge in the relocation of a cancer research laboratory. J Am Assoc Lab Anim Sci 50(3): 326–336. (Supported by the Tulane University School of Medicine, the Louisiana Cancer Research Consortium, NIH, the National Institute on Aging, the the Ellison Medical Foundation New Scholar in Aging Award, and the American Association for Laboratory Animal Science Grants for Laboratory Animal Science [GLAS] Award. Authors affiliated with Tulane University School of Medicine, LA.)21640027
145 Dauchy RT, Hoffman AE, Wren-Dail MA, Hanifin JP, Warfield B, Brainard GC, Xiang S, Yuan L, Hill SM, Belancio VP, Dauchy EM, Smith K, Blask DE. 2015. Daytime blue light enhances the nighttime circadian melatonin inhibition of human prostate cancer growth. Comp Med 65(6): 473–485. (Supported by the Tulane University School of Medicine, the Louisiana Cancer Research Consortium, the American Association for Laboratory Animal Science, the Institute for Integrative Health, and the National Science Foundation. Authors affiliated with Tulane University School of Medicine, LA; Thomas Jefferson University, PA.)26678364
146 Dauchy RT, Sauer LA, Blask DE, Vaughan GM. 1997. Light contamination during the dark phase in “photoperiodically controlled” animal rooms: effect on tumor growth and metabolism in rats. Lab Anim Sci 47(5): 511–518. (Supported by the Stephen C. Clark Research Fund. Authors affiliated with Bassett Healthcare, NY; U.S. Army Institute of Surgical Research, TX.)9355094
147 Dauchy RT, Wren-Dail MA, Dupepe LM, Hill SM, Xiang S, Anbalagan M, Belancio VP, Dauchy EM, Blask DE. 2018. Effect of daytime blue-enriched LED light on the nighttime circadian melatonin inhibition of hepatoma 7288CTC Warburg effect and progression. Comp Med 68(4): 1–11. (Supported by the Tulane University School of Medicine, the Louisiana Cancer Research Consortium, NIH, and the American Association for Laboratory Animal Science. Authors affiliated with Tulane University School of Medicine, LA.)
148 Dauchy RT, Wren-Dail MA, Hoffman AE, Hanifin JP, Warfield B, Brainard GC, Hill SM, Belancio VP, Dauchy EM, Blask DE. 2016. Effects of daytime exposure to light from blue-enriched light-emitting diodes on the nighttime melatonin amplitude and circadian regulation of rodent metabolism and physiology. Comp Med 66(5): 373–383. (Supported by the Tulane University School of Medicine and Louisiana Cancer Research Consortium Startup, NIH, the American Association for Laboratory Animal Science Grants for Laboratory Animal Science, The Institute for Integrative Health, and the National Science Foundation. Authors affiliated with Tulane University School of Medicine, LA; Thomas Jefferson University, PA.)27780004
149 Dauchy RT, Xiang S, Mao L, Brimer S, Wren MA, Yuan L, Anbalagan M, Hauch A, Frasch T, Rowan BG, Blask DE, Hill SM. 2014. Circadian and melatonin disruption by exposure to light at night drives intrinsic resistance to tamoxifen therapy in breast cancer. Cancer Res 74(15): 4099–4110. (Supported by NIH, the American Association for Laboratory Animal Science, and the the Edmond and Lily Safra Endowed Chair for Breast Cancer Research. Authors affiliated with Tulane University School of Medicine, LA; Tulane Cancer Center and Louisiana Cancer Research Consortium, LA; Tulane Circadian Cancer Biology Group, LA.)25062775
150 Daugaard S, Garde AH, Bonde JPE, Christoffersen J, Hansen AM, Markvart J, Schlünssen V, Skene DJ, Vistisen HT, Kolstad HA. 2017. Night work, light exposure and melatonin on work days and days off. Chronobiol Int: 1–14. (Supported by the Danish Working Environment Research Fund. Authors affiliated with Aarhus University Hospital, Denmark; National Research Centre for the Working Environment, Denmark; Bispebjerg Hospital, Denmark; University of Copenhagen, Denmark; Velux Danmark A/S, Denmark; Aalborg Universitet, Denmark; University of Surrey, UK.)
151 Davidson AJ, Castanon-Cervantes O, Leise TL, Molyneux PC, Harrington ME. 2009. Visualizing jet lag in the mouse suprachiasmatic nucleus and peripheral circadian timing system. Eur J Neurosci 29(1): 171–180. (Supported by the Keck Genomics Center at the Morehouse School of Medicine Neuroscience Institute, NIH, and NSF. Authors affiliated with Morehouse School of Medicine, GA; Amherst College, MA; Smith College, MA.)19032592
152 Davis S, Kaune WT, Mirick DK, Chen C, Stevens RG. 2001a. Residential magnetic fields, light-at-night, and nocturnal urinary 6-sulfatoxymelatonin concentration in women. Am J Epidemiol 154(7): 591–600. (Supported by the Electric Power Research Institute. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Washington, WA; EM Factors, WA; University of Connecticut Health Center, CT.)11581092
153 Davis S, Mirick DK. 2006. Circadian disruption, shift work and the risk of cancer: a summary of the evidence and studies in Seattle. Cancer Causes Control 17(4): 539–545. (Support not reported. Authors affiliated with Fred Hutchinson Cancer Research Center, WA.)16596308
154 Davis S, Mirick DK, Chen C, Stanczyk FZ. 2012. Night shift work and hormone levels in women. Cancer Epidemiol Biomarkers Prev 21(4): 609–618. (Support not reported. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Washington, WA; University of Southern California, CA.)22315366
155 Davis S, Mirick DK, Stevens RG. 2001b. Night shift work, light at night, and risk of breast cancer. J Natl Cancer Inst 93(20): 1557–1562. (Supported by the National Cancer Institute, National Institutes of Health, Department of Health and Human Services. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Connecticut Health Center, CT.)11604479
156 De Bacquer D, Van Risseghem M, Clays E, Kittel F, De Backer G, Braeckman L. 2009. Rotating shift work and the metabolic syndrome: a prospective study. Int J Epidemiol 38(3): 848–854. (Supported by the Belgian Federal Public Service Employment, Labor and Social Dialogue and by the European Social Fund. Authors affiliated with Ghent University, Belgium; Université Libre de Bruxelles, Belgium.)19129266
157 de Castro TB, Bordin-Junior NA, de Almeida EA, de Campos Zuccari DAP. 2018. Evaluation of melatonin and AFMK levels in women with breast cancer. Endocrine(Epub ahead of print). (Supported by FAPESP and FAPERP. Authors affiliated with São Paulo State University, Brazil; São José do Rio Preto Medical School, Brazil; Regional University of Blumenau Foundation, Brazil.)
158 deHaro D, Kines KJ, Sokolowski M, Dauchy RT, Streva VA, Hill SM, Hanifin JP, Brainard GC, Blask DE, Belancio VP. 2014. Regulation of L1 expression and retrotransposition by melatonin and its receptor: implications for cancer risk associated with light exposure at night. Nucleic Acids Res 42(12): 7694–7707. (Supported by the Ellison Medical Foundation New Scholar in Aging Research, the Life Extension Foundation, the National Institutes of Health, the American Association for Laboratory Animal Science Grants for Laboratory Animal Science, and The Institute for Integrative Health. Authors affiliated with Tulane School of Medicine, LA; Tulane Center for Aging, LA; Thomas Jefferson University, PA.)24914052
159 Depner CM, Melanson EL, McHill AW, Wright KP, Jr. 2018. Mistimed food intake and sleep alters 24-hour time-of-day patterns of the human plasma proteome. Proc Natl Acad Sci U S A. (Supported by NIH, the Sleep Research Society Foundation, and SomaLogic, Inc. Authors affiliated with University of Colorado Boulder, CO; University of Colorado Anschutz Medical Campus, CO; VA Eastern Colorado Health Care System, CO; Oregon Health and Science University, OR; Brigham and Women’s Hospital, MA; Harvard Medical School, MA.)
160 Devore EE, Warner ET, Eliassen AH, Brown SB, Beck AH, Hankinson SE, Schernhammer ES. 2017. Urinary melatonin in relation to postmenopausal breast cancer risk according to melatonin 1 receptor status. Cancer Epidemiol Biomarkers Prev 26(3): 413–419. (Supported by NCI, CDC, and NIOSH. Authors affiliated with Brigham and Women’s Hospital and Harvard Medical School, MA; Massachusetts General Hospital, MA; Harvard T.H. Chan School of Public Health, MA; University of Massachusetts Amherst, MA; Beth Israel Deaconess Medical Center and Harvard Medical School, MA; Medical University of Vienna, Austria.)28151704
161 Dibner C, Schibler U, Albrecht U. 2010. The mammalian circadian timing system: organization and coordination of central and peripheral clocks. Annu Rev Physiol 72: 517–549. (Support not reported. Authors affiliated with Geneva University Hospital, Switzerland; University of Geneva, Switzerland; University of Fribourg, Switzerland.)20148687
162 Dickerman BA, Markt SC, Koskenvuo M, Hublin C, Pukkala E, Mucci LA, Kaprio J. 2016. Sleep disruption, chronotype, shift work, and prostate cancer risk and mortality: a 30-year prospective cohort study of Finnish twins. Cancer Causes Control 27(11): 1361–1370. (Suppored by NCI, NIH, and the Academy of Finland. Authors affiliated with Harvard T.H. Chan School of Public Health, MA; University of Helsinki, Finland; Finnish Institute of Occupational Health, Finland; Finnish Cancer Registry, Finland; University of Tampere, Finland; National Institute for Health and Welfare, Finland.)27734240
163 Dijk DJ, Duffy JF, Silva EJ, Shanahan TL, Boivin DB, Czeisler CA. 2012. Amplitude reduction and phase shifts of melatonin, cortisol and other circadian rhythms after a gradual advance of sleep and light exposure in humans. PLoS One 7(2): e30037. (Supported by the National Aeronautics and Space Administration, the National Space Biomedical Research Institute, the National Institute of Mental Health, the National Institutes of Health and by the Brigham and Women’s Hospital. Authors affiliated with Harvard Medical School, MA: Brigham and Women’s Hospital, MA.)22363414
164 DOE. 2017. Street Lighting and Blue Light: Frequently Asked Questions. U.S. Department of Energy. 21 pp. https://www.energy.gov/eere/ssl/downloads/street-lighting-and-blue-light-faqs.
165 DOE. 2018. Fluorescent Lighting and LED Lighting. U.S. Department of Energy. Accessed on 5/31/18. https://www.energy.gov/energysaver/save-electricity-and-fuel/lighting-choices-save-you-money/fluorescent-lighting and https://www.energy.gov/energysaver/save-electricity-and-fuel/lighting-choices-save-you-money/led-lighting
166 Doi M, Hirayama J, Sassone-Corsi P. 2006. Circadian regulator CLOCK is a histone acetyltransferase. Cell 125(3): 497–508. (Supported by the Centre National de la Recherche Scientifique, Institut National de la Santé et de la Recherche Médicale, Université Louis Pasteur, Fondation de la Recherche Médicale, and Association pour la Recherche sur le Cancer. Authors affiliated with Institut de Génétique et de Biologie Moléculaire et Cellulaire, France; University of California, CA; Kobe University Graduate School of Medicine, Japan.)16678094
167 DOT. 2018. International Aviation Development Series: U.S. International Air Passenger and Freight Statistics: September 2017. U.S. Department of Transportation. 37 pp. https://www.transportation.gov/sites/dot.gov/files/docs/mission/office-policy/aviation-policy/306551/us-international-air-passenger-and-freight-statistics-september-2017.pdf.
168 Drake CL, Roehrs T, Richardson G, Walsh JK, Roth T. 2004. Shift work sleep disorder: prevalence and consequences beyond that of symptomatic day workers. Sleep 27(8): 1453–1462. (Supported by NIMH. Authors affiliated with Henry Ford Hospital Sleep Disorders and Research Center. MI; Wayne State College of Medicine, MI; St. Louis University, MO.)15683134
169 Dubocovich ML, Markowska M. 2005. Functional MT_1_ and MT_2_ melatonin receptors in mammals. Endocrine 27(2): 101–110. (Supported by the Foundation for Polish Science and the USPHS. Authors affiliated with Northwestern University, IL; Warsaw University, Poland.)16217123
170 Dubocovich ML, Rivera-Bermudez MA, Gerdin MJ, Masana MI. 2003. Molecular pharmacology, regulation and function of mammalian melatonin receptors. Front Biosci 8: d1093–1108. (Supported by the USPHS, and the American Heart Association. Authors affiliated with Northwestern University Feinberg School of Medicine, IL; Northwestern University Institute for Neuroscience, IL; Northwestern University, IL.)12957828
171 Dumont M, Lanctot V, Cadieux-Viau R, Paquet J. 2012. Melatonin production and light exposure of rotating night workers. Chronobiol Int 29(2): 203–210. (Supported by NSERC. Authors affiliated with Sacre-Coeur Hospital of Montreal, Canada; University of Montreal, Canada.)22324558
172 Dumont M, Paquet J. 2014. Progressive decrease of melatonin production over consecutive days of simulated night work. Chronobiol Int 31(10): 1231–1238. (Supported by the Natural Science and Engineering Research Canada. Authors affiliated with Sacre-Coeur Hospital of Montreal, Canada; University of Montreal, Canada.)25222345
173 Eastman CI, Tomaka VA, Crowley SJ. 2016. Circadian rhythms of European and African-Americans after a large delay of sleep as in jet lag and night work. Sci Rep 6: 36716. (Supported by NIH and NINR. Authors affiliated with Rush University Medical Center, IL.)27819313
174 EIA. 2017. Commercial Buildings Energy Consumption Survey (CBECS) Trends in Lighting in Commercial Buildings. U.S. Energy Information Administration. Updated on 5/17/17. Accessed on 5/31/18. https://www.eia.gov/consumption/commercial/reports/2012/lighting/
175 EIA. 2018. Commercial Buildings Energy Consumption Survey (CBECS) Building Type Definitions. U.S. Energy Information Administration. Accessed on 5/31/18. https://www.eia.gov/consumption/commercial/building-type-definitions.php
176 Elert G. 2018. Nature of Light. The Physic Hypertextbook. Accessed on 5/25/18. https://physics.info/light/
177 Erren TC. 2005. Could visible light contribute to the development of leukaemia and other cancers in children? Med Hypotheses 64(4): 864–871. (Supported by the Children with Leukaemia Charity. Authors affiliated with University of Cologne, Germany.)15694708
178 Escobar C, Martínez-Merlos MT, Angeles-Castellanos M, del Carmen Miñana M, Buijs RM. 2007. Unpredictable feeding schedules unmask a system for daily resetting of behavioural and metabolic food entrainment. Eur J Neurosci 26(10): 2804–2814. (Supported by CONACyT, DGAPA PAPIIT, and UNAM. Authors affiliated with Universidad Nacional Autónoma de México, Mexico; Moore House Medical School, GA; Netherlands Institute for Neuroscience, Netherlands.)18001277
179 Espiritu RC, Kripke DF, Ancoli-Israel S, Mowen MA, Mason WJ, Fell RL, Klauber MR, Kaplan OJ. 1994. Low illumination experienced by San Diego adults: association with atypical depressive symptoms. Biol Psychiatry 35(6): 403–407. (Supported by the Department of Veterans Affairs. Authors affiliated with Sam and Rose Stein Institute For Research on Aging, CA; UCSD, CA; San Diego Veterans Affairs Medical Center, CA; San Diego Stale University, CA.)8018787
180 Esquirol Y, Bongard V, Mabile L, Jonnier B, Soulat JM, Perret B. 2009. Shift work and metabolic syndrome: respective impacts of job strain, physical activity, and dietary rhythms. Chronobiol Int 26(3): 544–559. (Support not reported. Authors affiliated with INSERM, France; Service de Santé au Travail de Lacq, France.)19360495
181 Etchegaray JP, Lee C, Wade PA, Reppert SM. 2003. Rhythmic histone acetylation underlies transcription in the mammalian circadian clock. Nature 421(6919): 177–182. (Supported by the NIH and the Defense Advanced Research Projects Agency. Authors affiliated with University of Massachusetts Medical School, MA; Emory University, GA.)12483227
182 Evans JA, Davidson AJ. 2013. Health consequences of circadian disruption in humans and animal models. Prog Mol Biol Transl Sci 119: 283–323. (Support not reported. Authors affiliated with Morehouse School of Medicine, GA.)23899601
183 EWG. 2007. Chemical Exposures on the Job May Be Linked to Diseases in Nurses. Environmental Working Group. Updated on 12/11/07. Accessed on 1/5/18. https://www.ewg.org/news/news-releases/2007/12/11/chemical-exposures-job-may-be-linked-diseases-nurses#.WiBxsrQ-dqw
184 Falchi F, Cinzano P, Duriscoe D, Kyba CC, Elvidge CD, Baugh K, Portnov BA, Rybnikova NA, Furgoni R. 2016. The new world atlas of artificial night sky brightness. Sci Adv 2(6): e1600377. (Supported by the Italian Space Agency. Authors affiliated with Istituto di Scienza e Tecnologia dell’Inquinamento Luminoso, Italy; U.S. Department of Interior, CO; Deutsches GeoForschungsZentrum GFZ, Germany; Leibniz–Institute of Freshwater Ecology and Inland Fisheries, Germany; National Oceanic and Atmospheric Administration’s National Centers for Environmental Information, CO; University of Colorado, CO; University of Haifa, Israel; Association of Variable Star Observers, MA.)27386582
185 Fang L, Yang Z, Zhou J, Tung JY, Hsiao CD, Wang L, Deng Y, Wang P, Wang J, Lee MH. 2015a. Circadian clock gene CRY2 degradation is involved in chemoresistance of colorectal cancer. Mol Cancer Ther 14(6): 1476–1487. (Supported by NIH, the Fidelity Foundation, the Susan G. Komen Breast Cancer Foundation, the Program of Introducing Talents of Discipline to Universities, and the International S&T Cooperation Program of China. Authors affiliated with The Sixth Affiliated Hospital of Sun Yat-Sen University, China; University of Texas MD Anderson Cancer Center, TX; Academia Sinica, Taiwan.)25855785
186 Fang M, Ohman Strickland PA, Kang HG, Zarbl H. 2017. Uncoupling genotoxic stress responses from circadian control increases susceptibility to mammary carcinogenesis. Oncotarget 8(20): 32752–32768. (Supported by NIH, a V Foundation Grant for Cancer Research, and an International Collaboration Fund from the Animal and Plant Quarantine Agency, South Korea. Authors affiliated with State University of New Jersey, NJ; Veterinary Drugs & Biologics Division, Animal and Plant Quarantine Agency, Korea.)28427145
187 Fang MZ, Ohman-Strickland P, Kelly-McNeil K, Kipen H, Crabtree BF, Lew JP, Zarbl H. 2015b. Sleep interruption associated with house staff work schedules alters circadian gene expression. Sleep Med 16(11): 1388–1394. (Supported by the V Foundation for Cancer Research, the National Institute of Environmental Health Sciences and the State University of New Jersey. Authors affiliated with Robert Wood Johnson Medical School, NJ; NIEHS, NJ; State University of New Jersey, NJ; School of Public Health, NJ; Children’s National Medical Center, Washington, DC.)26498241
188 Faraut B, Bayon V, Léger D. 2013. Neuroendocrine, immune and oxidative stress in shift workers. Sleep Med Rev 17(6): 433–444. (Supported by the Direction Générale du Travail, Ministère du Travail, de l’Emploi et de la Santé auprès de la Société Française de Médecine du Travail. Authors affiliated with Université Paris Descartes, France; Consensus Group on Shift Work, France.)23618533
189 Faraut B, Boudjeltia KZ, Vanhamme L, Kerkhofs M. 2012. Immune, inflammatory and cardiovascular consequences of sleep restriction and recovery. Sleep Med Rev 16(2): 137–149. (Supported by the European Union, and the Scientific Research Fund of the ISPPC-CHU de Charleroi. Authors affiliated with Université Libre de Bruxelles, Belgium; Université Paris Descartes, France.)21835655
190 Fekedulegn D, Burchfiel CM, Violanti JM, Hartley TA, Charles LE, Andrew ME, Miller DB. 2012. Associations of long-term shift work with waking salivary cortisol concentration and patterns among police officers. Ind Health 50(6): 476–486. (Support not reported. Authors affiliated with National Institute for Occupational Safety and Health, GA; State University of New York, NY.)23047078
191 Fenton SE. 2006. Endocrine-disrupting compounds and mammary gland development: early exposure and later life consequences. Endocrinology 147(6 Suppl): S18–24. (Supported by the US EPA. Author affiliated with U.S. EPA, NC.)16690811
192 Feychting M, Österlund B, Ahlbom A. 1998. Reduced cancer incidence among the blind. Epidemiology 9(5): 490–494. (Supported by Martin Rind’s Foundation. Authors affiliated with Karolinska Institutet, Sweden.)9730026
193 Figueiro M. 2018. Personal communication from Dr. Mariana Figueiro of Renssalaer Polytechnic Institute, Troy, NY, on 1/4/2018.
194 Figueiro M, Overington D. 2016. Self-luminous devices and melatonin suppression in adolescents. Light Res Technol 48(8): 966–975. (Supported by the Lighting Research Center at Rensselaer Polytechnic Institute. Authors affiliated with Rensselaer Polytechnic Institute, NY.)
195 Figueiro M, Wood B, Plitnick B, Rea M. 2011. The impact of light from computer monitors on melatonin levels in college students. Biogenic Amines 25(2): 106–116. (Supported by the Office of Naval Research. Authors affiliated with Rensselaer Polytechnic Institute, NY.)
196 Figueiro MG. 2017. Disruption of circadian rhythms by light during day and night. Curr Sleep Med Rep 3(2): 76–84. (Supported by NIOSH. Authors affiliated with Rensselaer Polytechnic Institute, NY.)28845384
197 Figueiro MG, Plitnick B, Rea MS. 2012. Light modulates leptin and ghrelin in sleep-restricted adults. Int J Endocrinol 2012: 530726. (Supported by Seoul Semiconductors. Authors affiliated with Rensselaer Polytechnic Institute, NY.)22988459
198 Figueiro MG, Rea MS, Bullough JD. 2006. Does architectural lighting contribute to breast cancer? J Carcinog 5: 20. (Supported by the Lighting Research Center and NIEHS. Authors affiliated with Rensselaer Polytechnic Institute, NY.)16901343
199 Figueiro MG, Steverson B, Heerwagen J, Kampschroer K, Hunter CM, Gonzales K, Plitnick B, Rea MS. 2017. The impact of daytime light exposures on sleep and mood in office workers. Sleep Health 3(3): 204–215. (Supported by the US General Services Administration. Authors affiliated with Rensselaer Polytechnic Institute, NY; US General Services Administration.)28526259
200 Filipski E, Delaunay F, King VM, Wu MW, Claustrat B, Gréchez-Cassiau A, Guettier C, Hastings MH, Francis L. 2004. Effects of chronic jet lag on tumor progression in mice. Cancer Res 64(21): 7879–7885. (Supported by the Association pour la Recherche sur le Temps Biologique et la Chronothérapeutique [hôpital Paul Brousse], Action Thématique Concertée Nutrition from the Institut National de la Santé et de la Recherche Médicale (France), the Association pour la Recherche sur le Cancer, the Fondation pour la Recherche Médicale, Université de Nice-Sophia Antipolis, and a Research Training Fellowship from the Medical Research Council. Authors affiliated with INSERM, France; Université de Nice-Sophia Antipolis, France; University of Cambridge, UK; Hôpital Neurocardiologique, France; Hôpital Paul Brousse, France; MRC, UK.)15520194
201 Filipski E, Innominato PF, Wu M, Li XM, Iacobelli S, Xian LJ, Lévi F. 2005. Effects of light and food schedules on liver and tumor molecular clocks in mice. J Natl Cancer Inst 97(7): 507–517. (Supported by INSERM Action Thématique Concertée Nutrition, the Programme de Recherches Avancées de Coopération Franco-Chinoises, the Association pour la Recherche sur le Temps Biologique et la Chronothérapie and Association pour la Recherche sur le Cancer, Paul Brousse Hospital, France, and Clinical Important Program of Ministry of Public Health of P.R. China. Authors affiliated with INSERM, France; Università “G. D’Annunzio," Italy; Sun Yat-sen University, China.)15812076
202 Filipski E, King VM, Li X, Granda TG, Mormont MC, Liu X, Claustrat B, Hastings MH, Lévi F. 2002. Host circadian clock as a control point in tumor progression. J Natl Cancer Inst 94(9): 690–697. (Supported by the Association pour la Recherche sur le Cancer, the Association pour la Recherche sur le Temps Biologique et la Chronothérapeutique, Institut de Cancer et d’Immunogénétique and by a Research Training Fellowship from Medical Research Council. Authors affiliated with INSERM, France; University of Cambridge, UK; Hôpital Neurocardiologique, France; Medical Research Council, UK.)11983758
203 Filipski E, Levi F. 2009. Circadian disruption in experimental cancer processes. Integr Cancer Ther 8(4): 298–302. (Supported by the European Union through the Network of Excellence BioSim, STREP TEMPO, and Association Internationale pour la Recherche sur le Temps Biologique et la Chronothérapie (ARTBC International), Paul Brousse Hospital, France. Authors affiliated with Hôpital Paul Brousse, France; Université Paris-Sud, France.)20042408
204 Filipski E, Li XM, Levi F. 2006. Disruption of circadian coordination and malignant growth. Cancer Causes Control 17(4): 509–514. (Support not reported. Authors affiliated with INSERM, France.)16596304
205 Filipski E, Subramanian P, Carriere J, Guettier C, Barbason H, Lévi F. 2009. Circadian disruption accelerates liver carcinogenesis in mice. Mutat Res 680(1–2): 95–105. (Supported by the European Union trough the Network of Excellence BioSim, STREP TEMPO, the Association Internationale pour la Recherche sur le Temps Biologique et la Chronothérapie (ARTBC International), Paul Brousse Hospital, France and the University Paris Sud XI. Authors affiliated with INSERM, France; Université Paris-Sud, France; Hôpital Paul Brousse, France.)19833225
206 Flynn-Evans EE, Mucci L, Stevens RG, Lockley SW. 2013. Shiftwork and prostate-specific antigen in the National Health and Nutrition Examination Survey. J Natl Cancer Inst 105(17): 1292–1297. (Supported by the Harvard Medical School Division of Sleep Medicine Training Program in Sleep, Circadian and Respiratory Neurobiology. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard School of Public Health, MA; University of Connecticut Health Center, CT.)23943864
207 Flynn-Evans EE, Stevens RG, Tabandeh H, Schernhammer ES, Lockley SW. 2009. Total visual blindness is protective against breast cancer. Cancer Causes Control 20(9): 1753–1756. (Supported by a Department of Defense Breast Cancer Research Program Idea Award and the Harvard Medical School Division of Sleep Medicine Training Program in Sleep, Circadian, and Respiratory Neurobiology. Authors affiliated with Brigham and Women’s Hospital, MA; University of Surrey, UK; University of Connecticut, CT; Retina-Vitreous Associates, CA; Harvard Medical School, MA.)19649715
208 Folkard S. 2008. Do permanent night workers show circadian adjustment? A review based on the endogenous melatonin rhythm. Chronobiol Int 25(2): 215–224. (Supported by the UK’s Health and Safety Executive. Author affiliated with Université Paris Descartes, France; Swansea University, UK.)18533325
209 Fonken LK, Aubrecht TG, Meléndez-Fernández OH, Weil ZM, Nelson RJ. 2013a. Dim light at night disrupts molecular circadian rhythms and increases body weight. J Biol Rhythms 28(4): 262–271. (Supported by NSF and the American Heart Association. Authors affiliated with Ohio State University, OH.)23929553
210 Fonken LK, Lieberman RA, Weil ZM, Nelson RJ. 2013b. Dim light at night exaggerates weight gain and inflammation associated with a high-fat diet in male mice. Endocrinology 154(10): 3817–3825. (Supported by the National Science Foundation and the American Heart Association. Authors affiliated with Ohio State University, OH.)23861373
211 Fonken LK, Nelson RJ. 2014. The effects of light at night on circadian clocks and metabolism. Endocr Rev 35(4): 648–670. (Supported by the American Heart Association and the National Science Foundation. Authors affiliated with Ohio State University, OH.)24673196
212 Fonken LK, Workman JL, Walton JC, Weil ZM, Morris JS, Haim A, Nelson RJ. 2010. Light at night increases body mass by shifting the time of food intake. Proc Natl Acad Sci U S A 107(43): 18664–18669. (Supported by the National Science Foundation and by the United States–Israel Binational Science Foundation. Authors affiliated with Ohio State University, OH; University of Haifa, Israel.)20937863
213 Frajacomo FT, de Paula Garcia W, Fernandes CR, Garcia SB, Kannen V. 2015. Pineal gland function is required for colon antipreneoplastic effects of physical exercise in rats. Scand J Med Sci Sports 25(5): e451–458. (Supported by the National Council for Scientific and Technological Development [CNPq–Brazil] and University of São Paulo [Brazil]. Authors affiliated with University of São Paulo, Brazil.)25487536
214 Fritschi L, Erren TC, Glass DC, Girschik J, Thomson AK, Saunders C, Boyle T, El-Zaemey S, Rogers P, Peters S, Slevin T, D’Orsogna A, de Vocht F, Vermeulen R, Heyworth JS. 2013. The association between different night shiftwork factors and breast cancer: a case-control study. Br J Cancer 109(9): 2472–2480. (Supported by the National Health and Medical Research Council Australia, the Cancer Council Western Australia, the University of Western Australia, and the Lions Cancer Institute. Authors affiliated with University of Western Australia, Australia; University of Cologne, Germany; Monash University, Australia; Cancer Council Western Australia, Australia; Health Consumer Representative, Australia; University of Manchester, UK; Utrecht University, Netherlands.)24022188
215 Fritschi L, Valérie Groß J, Wild U, Heyworth JS, Glass DC, Erren TC. 2018. Shift work that involves circadian disruption and breast cancer: a first application of chronobiological theory and the consequent challenges. Occup Environ Med 75(3): 231–234. (Supported by the National Health and Medical Research Council Australia, and the Cancer Council Western Australia. Authors affiliated with Curtin University, Australia; University of Cologne, Germany; University of Western Australia, Australia; Monash University, Australia.)28775132
216 Fu L, Kettner NM. 2013. The circadian clock in cancer development and therapy. Prog Mol Biol Transl Sci 119: 221–282. (Supported by USDA/ARS, NIH/NCI and NIH/NIDDK. Authors affiliated with Baylor College of Medicine, TX.)23899600
217 Fu L, Lee CC. 2003. The circadian clock: pacemaker and tumour suppressor. Nat Rev Cancer 3(5): 350–361. (Support not reported. Authors affiliated with Baylor College of Medicine, TX.)12724733
218 Fu L, Patel MS, Bradley A, Wagner EF, Karsenty G. 2005. The molecular clock mediates leptin-regulated bone formation. Cell 122(5): 803–815. (Supported by NIH and the Canadian Institutes for Health Research. Authors affiliated with Baylor College of Medicine, TX; Wellcome Trust Sanger Institute, UK; Research Institute of Molecular Pathology, Austria)16143109
219 Fu L, Pelicano H, Liu J, Huang P, Lee C. 2002. The circadian gene Period2 plays an important role in tumor suppression and DNA damage response in vivo. Cell 111(1): 41–50. (Supported by the National Institute of Health and Clayton Foundation for Research. Authors affiliated with Baylor College of Medicine, TX; University of Texas, TX.)12372299
220 Fu XJ, Li HX, Yang K, Chen D, Tang H. 2016. The important tumor suppressor role of PER1 in regulating the cyclin-CDK-CKI network in SCC15 human oral squamous cell carcinoma cells. Onco Targets Ther 9: 2237–2245. (Support not reported. Authors affiliated with First Affiliated Hospital of Chongqing Medical University, China.)27143919
221 Fujino Y, Japan Collaborative Cohort Study for Evaluation of C. 2007. Occupational factors and mortality in the Japan Collaborative Cohort Study for Evaluation of Cancer (JACC). Asian Pac J Cancer Prev 8 Suppl: 97–104. (Support not reported. Author affiliated with University of Occupational and Environmental Health, Japan.)18260708
222 Furness JB. 2006. The organisation of the autonomic nervous system: peripheral connections. Auton Neurosci 130(1–2): 1–5. (Supported by the Australian Research Council and the National Health and Medical Research Council of Australia. Author affiliated with University of Melbourne, Australia.)16798102
223 Gaddameedhi S, Selby CP, Kaufmann WK, Smart RC, Sancar A. 2011. Control of skin cancer by the circadian rhythm. Proc Natl Acad Sci U S A 108(46): 18790–18795. (Supported by NIH and NIEHS. Authors affiliated with University of North Carolina School of Medicine, NC; North Carolina State University, NC.)22025708
224 Gall D, Bieske K. 2004. Definition and measurement of circadian radiometric quantities. In Light and Health - Non-Visual Effects: Proceedings of the CIE Symposium ’04 : 30 September - 2 October 2004 Vienna, Austria: Commission Internationale de L’éclairage. p. 129–132. (Supported by OSRAM GmbH. Authors affiliated with Technische Universität Ilmenau, Germany.)
225 Gamaldo CE, Shaikh AK, McArthur JC. 2012. The sleep-immunity relationship. Neurol Clin 30(4): 1313–1343. (Support not reported. Authors affiliated with Johns Hopkins Sleep Disorders Center, MD; Emory University Rollins School of Public Health, GA; Johns Hopkins University School of Medicine, MD.)23099140
226 Gamble KL, Motsinger-Reif AA, Hida A, Borsetti HM, Servick SV, Ciarleglio CM, Robbins S, Hicks J, Carver K, Hamilton N, Wells N, Summar ML, McMahon DG, Johnson CH. 2011. Shift work in nurses: contribution of phenotypes and genotypes to adaptation. PLoS One 6(4): e18395. (Supported by Vanderbilt University, the National Center for Research Resources of the National Institutes of Health, the Vanderbilt Joint Center for Nursing Research, and the National Institute of Mental Health. Authors affiliated with Vanderbilt University, TN; North Carolina State University, NC; Children’s National Medical Center, Washington, D.C.)21533241
227 Gan Y, Li L, Zhang L, Yan S, Gao C, Hu S, Qiao Y, Tang S, Wang C, Lu Z. 2018. Association between shift work and risk of prostate cancer: a systematic review and meta-analysis of observational studies. Carcinogenesis 39(2): 87–97. (No funding received. Authors affiliated with Huazhong University of Science and Technology, China; Jiangxi Science and Technology Normal University, China; Xiamen University, China; Chinese Center for Disease Control and Prevention, China; Changsha Medical University, China.)29126152
228 Gandini S, Boniol M, Haukka J, Byrnes G, Cox B, Sneyd MJ, Mullie P, Autier P. 2011. Meta-analysis of observational studies of serum 25-hydroxyvitamin D levels and colorectal, breast and prostate cancer and colorectal adenoma. Int J Cancer 128(6): 1414–1424. (Supported by the Director’s Cancer Research Trust, University of Otago, New Zealand. Authors affiliated with European Institute of Oncology, Italy; International Prevention Research Institute, France; University of Helsinki, Finland; IARC, France; University of Otago, New Zealand; Catholic University Leuven, Belgium.)20473927
229 Gangwisch JE, Feskanich D, Malaspina D, Shen S, Forman JP. 2013. Sleep duration and risk for hypertension in women: results from the nurses’ health study. Am J Hypertens 26(7): 903–911. (Supported by the National Institutes of Health, the National Heart, Lung, and Blood Institute, and the American Heart Association. Authors affiliated with Columbia University, NY; Brigham and Woman’s Hospital and Harvard Medical School, MA; New York University, NY.)23564028
230 Gapstur SM, Diver WR, Stevens VL, Carter BD, Teras LR, Jacobs EJ. 2014. Work schedule, sleep duration, insomnia, and risk of fatal prostate cancer. Am J Prev Med 46(3 Suppl 1): S26–33. (Supported by the American Cancer Society. Authors affiliated with American Cancer Society, GA.)24512928
231 Garcia-Saenz A, Sánchez de Miguel A, Espinosa A, Valentin A, Aragonés N, Llorca J, Amiano P, Martín Sánchez V, Guevara M, Capelo R, Tardón A, Peiró-Perez R, Jiménez-Moleón JJ, Roca-Barceló A, Pérez-Gómez B, Dierssen-Sotos T, Fernández-Villa T, Moreno-Iribas C, Moreno V, García-Pérez J, Castaño-Vinyals G, Pollán M, Aubé M, Kogevinas M. 2018. Evaluating the association between artificial light-at-night exposure and breast and prostate cancer risk in Spain (MCC-Spain Study). Environ Health Perspect 126(4): 047011. (Supported by the Accion Transversal del Cancer, Instituto de Salud Carlos III-FEDER, the Fundación Marqués de Valdecilla, the ICGC International Cancer Genome Consortium CLL, MINECO, RTICC, the Junta de Castillay León, Consejería de Salud of the Junta de Andalucía, the Conselleria de Sanitat of the Generalitat Valenciana, the Regional Government of the Basque Country, the Consejería de Sanidad de la Región de Murcia, the European Commission, AECC, the Catalan Government–Agency for Management of University and Research, the Fundación Caja de Ahorros de Asturias, the University of Oviedo, CERCA, the STARS4ALL project, the European Union, and the Cities at Night project. Authors affiliated with Barcelona Institute for Global Health, Spain; CIBER, Spain, CIBERESP, Spain; IAA, Spain; CSIC, Spain; Universidad Complutense de Madrid, Spain; Cégep de Sherbrooke, Canada; University Exeter, UK; IMIM, Spain; National Centre for Epidemiology, Spain; IDIVAL, Spain; Health Department of Basque Region, Spain; University of León, Spain; IdiSNA, Spain; CYSMA, Spain; IUOPA, Spain; FISABIO, Spain; University of Granada, Spain; ibs.GRANADA, Spain; Autonomous Government of Catalonia, Spain; REDISSEC, Spain; IDIBELL, Spain; University of Barcelona, Spain.)29687979
232 Garde AH, Hansen J, Kolstad HA, Larsen AD, Hansen AM. 2016. How do different definitions of night shift affect the exposure assessment of night work? Chronobiol Int 33(6): 595–598. (Support not reported. Authors affiliated with National Research Centre for the Working Environment, Denmark; University of Copenhagen, Denmark; Danish Cancer Society, Denmark; Aarhus University Hospital, Denmark.)27077244
233 Geiger SS, Fagundes CT, Siegel RM. 2015. Chrono-immunology: progress and challenges in understanding links between the circadian and immune systems. Immunology 146(3): 349–358. (Supported by the Wellcome Trust and the National Institute of Arthritis and Musculoskeletal and Skin Diseases of the U.S. National Institutes of Health. Authors affiliated with NIH, MD; Universidade Federal de Minas Gerais, Brazil.)26301993
234 Gérard C, Goldbeter A. 2012. Entrainment of the mammalian cell cycle by the circadian clock: modeling two coupled cellular rhythms. PLoS Comput Biol 8(5): e1002516. (Supported by the Fonds de la Recherche Scientifique Médicale, the Belgian Federal Science Policy Office, and the F.R.S.-FNRS in conjunction with the ErasysBio+ project C5Sys, ‘‘Circadian and Cell Cycle Clock Systems in Cancer.’’ Authors affiliated with Université Libre de Bruxelles, Belgium.)22693436
235 Gery S, Gombart AF, Yi WS, Koeffler C, Hofmann WK, Koeffler HP. 2005. Transcription profiling of C/EBP targets identifies Per2 as a gene implicated in myeloid leukemia. Blood 106(8): 2827–2836. (Supported by NIH, and the Ronald Havner, Parker Hughes, and the Cindy, Alan Horn, and Inger funds. Authors affiliated with UCLA, CA; University Hospital “Benjamin Franklin,” Germany.)15985538
236 Gery S, Komatsu N, Baldjyan L, Yu A, Koo D, Koeffler HP. 2006. The circadian gene per1 plays an important role in cell growth and DNA damage control in human cancer cells. Mol Cell 22(3): 375–382. (Supported by NIH, the Parker Hughes Trust, and the Inger Foundation. Authors affiliated with UCLA School of Medicine, CA.)16678109
237 Geyfman M, Kumar V, Liu Q, Ruiz R, Gordon W, Espitia F, Cam E, Millar SE, Smyth P, Ihler A, Takahashi JS, Andersen B. 2012. Brain and muscle Arnt-like protein-1 (BMAL1) controls circadian cell proliferation and susceptibility to UVB-induced DNA damage in the epidermis. Proc Natl Acad Sci U S A 109(29): 11758–11763. (Supported by the Irving Weinstein Foundation, the National Institutes of Health, and the National Institute on Drug Abuse. Authors affiliated with University of California - Irvine, CA; University of Texas Southwestern Medical Center, TX; University of Pennsylvania School of Medicine, PA.)22753467
238 Giannoulia-Karantana A, Vlachou A, Polychronopoulou S, Papassotiriou I, Chrousos GP. 2006. Melatonin and immunomodulation: connections and potential clinical applications. Neuroimmunomodulation 13(3): 133–144. (Support not reported. Authors affiliated with Athens University Medical School, Greece; ‘Aghia Sophia’ Children’s Hospital, Greece.)17119342
239 Girschik J, Heyworth J, Fritschi L. 2013. Self-reported sleep duration, sleep quality, and breast cancer risk in a population-based case-control study. Am J Epidemiol 177(4): 316–327. (Supported by the Australian National Health and Medical Research Council, the University of Western Australia, and the Cancer Council Western Australia. Authors affiliated with University of Western Australia, Australia.)23324334
240 Glickman G, Levin R, Brainard GC. 2002. Ocular input for human melatonin regulation: relevance to breast cancer. Neuro Endocrinol Lett 23 Suppl 2: 17–22. (Supported by NCI, NIH, and National Space Biomedical Research Institute under a NASA Cooperative Agreement. Authors affiliated with Jefferson Medical College, PA; Rensselaer Polytechnic Institute, NY.)
241 Goel N, Stunkard AJ, Rogers NL, Van Dongen HP, Allison KC, O’Reardon JP, Ahima RS, Cummings DE, Heo M, Dinges DF. 2009. Circadian rhythm profiles in women with night eating syndrome. J Biol Rhythms 24(1): 85–94. (Supported by NIH, the Institute for Experimental Psychiatry Research Foundation, the NHMRC Howard Florey Centenary Research Fellowship and a NSW BioFirst award. Authors affiliated with University of Pennsylvania School of Medicine, PA; University of Washington, WA; Albert Einstein College of Medicine, NY.)19150931
242 Gómez-Acebo I, Dierssen-Sotos T, Papantoniou K, García-Unzueta MT, Santos-Benito MF, Llorca J. 2015. Association between exposure to rotating night shift versus day shift using levels of 6-sulfatoxymelatonin and cortisol and other sex hormones in women. Chronobiol Int 32(1): 128–135. (Supported by the Instituto de Formación e Investigación Marqués de Valdecilla [IFIMAV]. Authors affiliated with University of Cantabria, Spain; IDIVAL, Spain; CIBER Epidemiología y Salud Pública [CIBERESP], Spain; Centre for Research in Environmental Epidemiology [CREAL], Spain; Hospital del Mar Medical Research Institute, Spain; Universitat Pompeu Fabra, Spain; Marques de Valdecilla University Hospital, Spain.)25216206
243 Gooley JJ, Chamberlain K, Smith KA, Khalsa SB, Rajaratnam SM, Van Reen E, Zeitzer JM, Czeisler CA, Lockley SW. 2011. Exposure to room light before bedtime suppresses melatonin onset and shortens melatonin duration in humans. J Clin Endocrinol Metab 96(3): E463–472. (Supported by Brigham and Women’s Hospital General Clinical Research Center, Harvard Clinical and Translational Science Center, the National Center for Research Resources, NIH, NIMH, NCCAM, NINDS, and the National Space Biomedical Research Institute through NASA. Authors affiliated with Brigham and Women’s Hospital and Harvard Medical School, MA; University of Surrey, UK.)21193540
244 Goto M, Oshima I, Tomita T, Ebihara S. 1989. Melatonin content of the pineal gland in different mouse strains. J Pineal Res 7(2): 195–204. (Supported by the Ministry of Education, Science and Culture of Japan. Authors affiliated with Nagoya University, Japan.)2769571
245 Gotoh T, Kim JK, Liu J, Vila-Caballer M, Stauffer PE, Tyson JJ, Finkielstein CV. 2016. Model-driven experimental approach reveals the complex regulatory distribution of p53 by the circadian factor Period 2. Proc Natl Acad Sci U S A 113(47): 13516–13521. (Supported by the National Science Foundation Molecular and Cellular Biosciences Division, the Fralin Life Science Institute, the Korea Advanced Institute of Science and Technology Research, the National Research Foundation of Korea, and a T. J. Park Science Fellowship of POSCO. Authors affiliated with Virginia Polytechnic Institute and State University, VA; Korea Advanced Institute of Science and Technology, Korea.)27834218
246 Goulet G, Mongrain V, Desrosiers C, Paquet J, Dumont M. 2007. Daily light exposure in morning-type and evening-type individuals. J Biol Rhythms 22(2): 151–158. (Supported by the Canadian Institute of Health Research, Fonds de la Recherche en Santé du Québec and the Natural Sciences and Engineering Research Council. Authors affiliated with Sacré-Coeur Hospital of Montréal, Canada; Université de Montréal, Canada.)17440216
247 Gradisar M, Wolfson AR, Harvey AG, Hale L, Rosenberg R, Czeisler CA. 2013. The sleep and technology use of Americans: findings from the National Sleep Foundation’s 2011 Sleep in America poll. J Clin Sleep Med 9(12): 1291–1299. (Supported by Merck, Pfizer, Astra Zeneca, Philips/Respironics, Vanda Pharmaceuticals, Cephalon, Inc., Koninklijke Philips Electronics, N.V., ResMed, the Brigham and Women’s Hospital. Authors affiliated with Flinders University, Australia; College of the Holy Cross, MA; University of California - Berkeley, CA; Stony Brook University, NY; Atlanta School of Sleep and Medicine Technology, GA; National Sleep Foundation, Washington, DC; Brigham and Women’s Hospital, MA; Harvard Medicine School, MA.)24340291
248 Grajewski B, Nguyen MM, Whelan EA, Cole RJ, Hein MJ. 2003. Measuring and identifying large-study metrics for circadian rhythm disruption in female flight attendants. Scand J Work Environ Health 29(5): 337–346. (Supported by the Federal Aviation Administration. Authors affiliated with NIOSH, OH; Synchrony Applied Health Sciences, CA.)14584514
249 Green A, Cohen-Zion M, Haim A, Dagan Y. 2017. Evening light exposure to computer screens disrupts human sleep, biological rhythms, and attention abilities. Chronobiol Int 34: 855–865. (Support not reported. Authors affiliated with University of Haifa, Israel; Assuta Medical Center, Israel; Academic College of Tel Aviv, Israel; Academic College of Tel-Hai, Israel.)28548897
250 Greene MW. 2012. Circadian rhythms and tumor growth. Cancer Lett 318(2): 115–123. (Supported by the Stephan C. Clark Foundation. Author affiliated with Bassett Research Institute, NY.)22252116
251 Griefahn B, Kuenemund C, Robens S. 2006. Shifts of the hormonal rhythms of melatonin and cortisol after a 4 h bright-light pulse in different diurnal types. Chronobiol Int 23(3): 659–673. (Supported by the Deutsche Forschungsgemeinschaft. Authors affiliated with Dortmund University, Germany.)16753948
252 Gritton HJ, Sutton BC, Martinez V, Sarter M, Lee TM. 2009. Interactions between cognition and circadian rhythms: attentional demands modify circadian entrainment. Behav Neurosci 123(5): 937–948. (Supported by PHS. Authors affiliated with University of Michigan, MI.)19824760
253 Gromadzinska J, Peplonska B, Sobala W, Reszka E, Wasowicz W, Bukowska A, Lie JA. 2013. Relationship between intensity of night shift work and antioxidant status in blood of nurses. Int Arch Occup Environ Health 86(8): 923–930. (Supported by the Polish-Norwegian Research Fund. Authors affiliated with Nofer Institute of Occupational Medicine, Poland; Institute of Occupational Health, Norway.)23179107
254 Grundy A, Richardson H, Burstyn I, Lohrisch C, SenGupta SK, Lai AS, Lee D, Spinelli JJ, Aronson KJ. 2013a. Increased risk of breast cancer associated with long-term shift work in Canada. Occup Environ Med 70(12): 831–838. (Supported by the Canadian Institutes of Health Research. Authors affiliated with Queen’s University, Canada; Drexel University, PA; British Columbia Cancer Agency, Canada; University of British Columbia, Canada.)23817841
255 Grundy A, Sanchez M, Richardson H, Tranmer J, Borugian M, Graham CH, Aronson KJ. 2009. Light intensity exposure, sleep duration, physical activity, and biomarkers of melatonin among rotating shift nurses. Chronobiol Int 26(7): 1443–1461. (Supported by Breast Cancer Action Kingston. Authors affiliated with Queen’s University, Canada; British Columbia Cancer Agency, Canada.)19916841
256 Grundy A, Schuetz JM, Lai AS, Janoo-Gilani R, Leach S, Burstyn I, Richardson H, Brooks-Wilson A, Spinelli JJ, Aronson KJ. 2013b. Shift work, circadian gene variants and risk of breast cancer. Cancer Epidemiol 37(5): 606–612. (Supported by the Canadian Institutes of Health Research. Authors affiliated with Queen’s University, Canada; British Columbia Cancer Agency, Canada; Drexel University, PA; Simon Fraser University, Canada; University of British Columbia, Canada.)23725643
257 Grundy A, Tranmer J, Richardson H, Graham CH, Aronson KJ. 2011. The influence of light at night exposure on melatonin levels among Canadian rotating shift nurses. Cancer Epidemiol Biomarkers Prev 20(11): 2404–2412. (Supported by the Workplace Safety and Insurance Board of Ontario and the Canadian Institutes of Health Research. Authors affiliated with Queen’s University, Canada; Queen’s Cancer Research Institute, Canada.)21953114
258 Gu F, Han J, Laden F, Pan A, Caporaso NE, Stampfer MJ, Kawachi I, Rexrode KM, Willett WC, Hankinson SE, Speizer FE, Schernhammer ES. 2015. Total and cause-specific mortality of U.S. nurses working rotating night shifts. Am J Prev Med 48(3): 241–252. (Supported by NCI, NIH Heart, Lung and Blood Institute, and the CDC/The National Institute for Occupational Safety and Health. Authors affiliated with NCI, MD; Brigham and Women’s Hospital, MA; Harvard Medical School, MA; University of Massachusetts, MA; Indiana University, IN; National University of Singapore, Singapore; National University Health System, Singapore; Applied Cancer Research–Institution for Translational Research Vienna, Austria.)25576495
259 Gu F, Xu S, Devesa SS, Zhang F, Klerman EB, Graubard BI, Caporaso NE. 2017. Longitude position in a time zone and cancer risk in the United States. Cancer Epidemiol Biomarkers Prev 26(8): 1306–1311. (Supported by NCI. Authors affiliated with National Cancer Institute, MD; Roswell Park Cancer Institute, NY; Harvard University, MA: Information Management Services, Inc., MD; Brigham and Women’s Hospital, MA.)28450580
260 Gubareva E, Maidin MA, Tyndyk ML, Vinogradova IA, Panchenko AV. 2016. [Role of clock proteins in skin carcinogenesis in 14-month-old SHR mice maintained under disrupted light regimen]. Vopr Oncol 62(5): 666–670. (Support unknown due to foreign language. Authors affiliated with N. N. Petrov Research Institute of Oncology, Russia; Petrozavodsk State University, Russia.)
261 Guerrero-Vargas NN, Guzmán-Ruiz M, Fuentes R, García J, Salgado-Delgado R, Basualdo Mdel C, Escobar C, Markus RP, Buijs RM. 2015. Shift work in rats results in increased inflammatory response after lipopolysaccharide administration: A role for food consumption. J Biol Rhythms 30(4): 318–330. (Supported by DGAPA, CONACYT, and PROLAB IBRO LARC. Authors affiliated with Universidad Nacional Autónoma de México, Mexico; Universidad Autónoma de San Luis Potosí, Mexico; University of São Paulo, Brazil.)26017928
262 Guerrero-Vargas NN, Navarro-Espíndola R, Guzmán-Ruíz MA, Basualdo MDC, Espitia-Bautista E, López-Bago A, Lascurain R, Córdoba-Manilla C, Buijs RM, Escobar C. 2017. Circadian disruption promotes tumor growth by anabolic host metabolism; experimental evidence in a rat model. BMC Cancer 17(1): 625. (Supported by DGAPA-UNAM, PAPIIT-UNAM, and CONACyT. Authors affiliated with Universidad Nacional Autónoma de México, Mexico.)28874144
263 Guo Y, Liu Y, Huang X, Rong Y, He M, Wang Y, Yuan J, Wu T, Chen W. 2013. The effects of shift work on sleeping quality, hypertension and diabetes in retired workers. PLoS One 8(8): e71107. (Supported by the National Basic Research Program. Authors affiliated with Huazhong University of Science and Technology, China.)23976988
264 Gurer-Orhan H, Suzen S. 2015. Melatonin, its metabolites and its synthetic analogs as multi-faceted compounds: antioxidant, prooxidant and inhibitor of bioactivation reactions. Curr Med Chem 22(4): 490–499. (Supported by The Scientific and Technological Research Council of Turkey. Authors affiliated with Ege University, Turkey; Ankara University, Turkey.)25515518
265 Gyarmati G, Turner MC, Castano-Vinyals G, Espinosa A, Papantoniou K, Alguacil J, Costas L, Perez-Gomez B, Martin Sanchez V, Ardanaz E, Moreno V, Gomez-Acebo I, Fernandez-Tardon G, Villanueva Ballester V, Capelo R, Chirlaque MD, Santibanez M, Pollan M, Aragones N, Kogevinas M. 2016. Night shift work and stomach cancer risk in the MCC-Spain study. Occup Environ Med 73(8): 520–527. (Supported by the ‘Accion Transversal del Cancer,’ approved by the Spanish Ministry Council on 11 October 2007, the Instituto de Salud Carlos III-FEDER, the Fundación Marqués de Valdecilla, the Junta de Castilla y León, the Consejería de Salud of the Junta de Andalucía, the Conselleria de Sanitat of the Generalitat Valenciana, the Recercaixa, the Regional Government of the Basque Country, the Consejería de Sanidad de la Región de Murcia, the European Commission, the Spanish Association Against Cancer [AECC] Scientific Foundation, the Catalan Government, the Fundación Caja de Ahorros de Asturias, the University of Oviedo, and the Canadian Institutes of Health. Authors affiliated with ISGlobal, Spain; Universitat Pompeu Fabra, Spain; CIBERESP, Spain; University of Ottawa, Canada; IMIM, Spain; Medical University of Vienna, Austria; Universidad de Huelva, Spain; Catalan Institute of Oncology, Spain; University of Barcelona, Spain; Carlos III Health Institute, Spain; Cancer Epidemiology Research Group, Spain; Universidad de León, Spain; Navarra Public Health Institute, Spain; Navarra Institute for Health Research, Spain; University of Cantabria, Spain; Universidad de Oviedo, Spain; FISABIO, Spain; Murcia Health Council, Spain.)27312400
266 Habbal OA, Al-Jabri AA. 2009. Circadian rhythm and the immune response: a review. Int Rev Immunol 28(1): 93–108. (Support not reported. Authors affiliated with Sultan Qaboos University, Oman.)19241255
267 Hadden H, Soldin SJ, Massaro D. 2012. Circadian disruption alters mouse lung clock gene expression and lung mechanics. J Appl Physiol 113(3): 385–392. (Supported by the National Heart, Lung, and Blood Institute. Authors affiliated with Georgetown University School of Medicine, Washington, D.C.; NIH, MD.)22678966
268 Hahn RA. 1991. Profound bilateral blindness and the incidence of breast cancer. Epidemiology 2(3): 208–210. (Support not reported. Author affiliated with Centers for Disease Control, GA.)2054403
269 Haim A, Yukler A, Harel O, Schwimmer H, Fares F. 2010. Effects of chronobiology on prostate cancer cells growth in vivo. Sleep Sci. 3(1): 32–35. (Supported by the Research authority of the University of Haifa. Authors affiliated with University of Haifa, Israel.)
270 Haim A, Zubidat AE. 2015. Artificial light at night: melatonin as a mediator between the environment and epigenome. Philos Trans R Soc Lond B Biol Sci 370(1667). (Support not reported. Authors affiliated with University of Haifa, Israel.)
271 Hamilton T. 1969. Influence of environmental light and melatonin upon mammary tumour induction. Br J Surg 56(10): 764–766. (Support not reported. Author affiliated with University of Edinburgh, UK.)5347580
272 Hammer GP, Emrich K, Nasterlack M, Blettner M, Yong M. 2015. Shift work and prostate cancer incidence in industrial workers: A historical cohort study in a German chemical company. Dtsch Arztebl Int 112(27–28): 463–470. (Supported by the German Social Accident Insurance. Authors affiliated with Johannes Gutenberg University, Germany; Laboratoire National de Santé, Luxembourg; Occupational Medicine and Health Protection, BASF SE, Germany.)26214232
273 Hansen AM, Helene Garde A, Hansen J. 2006. Diurnal urinary 6-sulfatoxymelatonin levels among healthy Danish nurses during work and leisure time. Chronobiol Int 23(6): 1203–1215. (Supported by the Danish Cancer Society and the National Institute of Occupational Health. Authors affiliated with National Institute of Occupational Health, Denmark; Danish Cancer Society, Denmark.)17190706
274 Hansen J. 2001. Increased breast cancer risk among women who work predominantly at night. Epidemiology 12(1): 74–77. (Support not reported. Author affiliated with Danish Cancer Society, Denmark.)11138824
275 Hansen J. 2006. Risk of breast cancer after night- and shift work: current evidence and ongoing studies in Denmark. Cancer Causes Control 17(4): 531–537. (Support not reported. Author affiliated with Danish Cancer Society, Denmark.)16596307
276 Hansen J, Lassen CF. 2012. Nested case-control study of night shift work and breast cancer risk among women in the Danish military. Occup Environ Med 69(8): 551–556. (Supported by the Danish Ministry of Defence. Authors affiliated with Danish Cancer Society, Denmark.)22645325
277 Hansen J, Stevens RG. 2012. Case-control study of shift-work and breast cancer risk in Danish nurses: impact of shift systems. Eur J Cancer 48(11): 1722–1729. (Supported by the Danish Cancer Society and from the National Programme of Environmental Health Research. Authors affiliated with Danish Cancer Society, Denmark; University of Connecticut Health Center, CT.)21852111
278 Hardeland R. 2013. Chronobiology of melatonin beyond the feedback to the suprachiasmatic nucleus-consequences to melatonin dysfunction. Int J Mol Sci 14(3): 5817–5841. (Support not reported. Author affiliated with University of Göttingen, Germany.)23481642
279 Hardeland R. 2014. Melatonin, noncoding RNAs, messenger RNA stability and epigenetics--evidence, hints, gaps and perspectives. Int J Mol Sci 15(10): 18221–18252. (Support not reported. Author affiliated with University of Göttingen, Germany.)25310649
280 Härmä M, Koskinen A, Ropponen A, Puttonen S, Karhula K, Vahtera J, Kivimäki M. 2017. Validity of self-reported exposure to shift work. Occup Environ Med 74(3): 228–230. (Supported by the Finnish Work Environment Fund and NordForsk. Authors affiliated with Finnish Institute of Occupational Health, Finland; University of Turku, Finland; Turku University Hospital, Finland; University of Helsinki, Finland; University College London Medical School, UK.)27679673
281 Hattar S, Liao HW, Takao M, Berson DM, Yau KW. 2002. Melanopsin-containing retinal ganglion cells: architecture, projections, and intrinsic photosensitivity. Science 295(5557): 1065–1070. (Supported by the U.S. National Eye Institute. Authors affiliated with Johns Hopkins University School of Medicine, MD; Brown University, RI.)11834834
282 Haus E, Smolensky MH. 1999. Biologic rhythms in the immune system. Chronobiol Int 16(5): 581–622. (Support not reported. Authors affiliated with Healthpartners Research Foundation, MN; University of Minnesota, MN; University of Texas, TX; Health Science Center, TX.)10513884
283 Haus EL, Smolensky MH. 2013. Shift work and cancer risk: potential mechanistic roles of circadian disruption, light at night, and sleep deprivation. Sleep Med Rev 17(4): 273–284. (Supported by the HealthPartners Research Foundation and the and Department of Pathology, Regions Hospital, Departmental Funds. Authors affiliated with University of Minnesota and HealthPartners Medical Group, MN; University of Texas, TX.)23137527
284 He C, Anand ST, Ebell MH, Vena JE, Robb SW. 2015. Circadian disrupting exposures and breast cancer risk: a meta-analysis. Int Arch Occup Environ Health 88(5): 533–547. (Supported by the Georgia Cancer Coalition. Authors affiliated with University of Georgia, GA; Medical University of South Carolina, SC.)25261318
285 Heckman CJ, Kloss JD, Feskanich D, Culnan E, Schernhammer ES. 2017. Associations among rotating night shift work, sleep and skin cancer in Nurses’ Health Study II participants. Occup Environ Med 74(3): 169–175. (Supported by NCI, NIH, CDC. NIOSH, and Drexel University. Authors affiliated with Fox Chase Cancer Center, PA; Drexel University, PA; Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Medical University of Vienna, Austria.)27663986
286 Hemiö K, Puttonen S, Viitasalo K, Härmä M, Peltonen M, Lindström J. 2015. Food and nutrient intake among workers with different shift systems. Occup Environ Med 72(7): 513–520. (Supported by the Finnish Funding Agency for Technology and Innovation, the Yrjö Jahnsson Foundation, the Academy of Finland, the Juho Vainio Foundation, and the Finnish Work Environment Fund. Authors affiliated with National Institute for Health and Welfare, Finland; Finnish Institute of Occupational Health, Finland; University of Helsinki, Finland; Finnair Health Services, Finland.)25896332
287 Heo JY, Kim K, Fava M, Mischoulon D, Papakostas GI, Kim MJ, Kim DJ, Chang KJ, Oh Y, Yu BH, Jeon HJ. 2017. Effects of smartphone use with and without blue light at night in healthy adults: A randomized, double-blind, cross-over, placebo-controlled comparison. J Psychiatr Res 87: 61–70. (Supported by Samsung Display, Original Technology Research Program for Brain Science through the National Research Foundation of Korea [NRF] funded by the Ministry of Education, Science and Technology, and the Korean Mental Health Technology R&D Project, Ministry of Health & Welfare, Republic of Korea. Authors affiliated with Sungkyunkwan University School of Medicine, South Korea; Harvard Medical School, MA: Samsung Medical Center, South Korea.)28017916
288 Hersh C, Sisti J, Richiutti V, Schernhammer E. 2015. The effects of sleep and light at night on melatonin in adolescents. Hormones (Athens) 14(3): 399–409. (Supported by NIH and NCI. Authors affiliated with Brown University, RI; Harvard T.H. Chan School of Public Health, MA; University of Cincinnati College of Medicine, OH; Brigham and Women’s Hospital, MA; Harvard Medical School, MA; ACR-ITR VIEnna, Austria.)26233931
289 Higuchi S, Motohashi Y, Ishibashi K, Maeda T. 2007. Influence of eye colors of Caucasians and Asians on suppression of melatonin secretion by light. Am J Physiol Regul Integr Comp Physiol 292(6): R2352–2356. (Supported by the Japanese Ministry of Education, Culture, Sports, Science, and Technology. Authors affiliated with Akita University School of Medicine, Japan; Kyushu University, Japan; National Institute of Occupational Safety and Health, Japan; Hokkaido University, Japan.)17332164
290 Higuchi S, Nagafuchi Y, Lee SI, Harada T. 2014. Influence of light at night on melatonin suppression in children. J Clin Endocrinol Metab 99(9): 3298–3303. (Supported by the Japan Society for the Promotion of Science and the Ministry of Education, Culture, Sports, Science and Technology of Japan. Authors affiliated with Kyushu University, Japan; Kochi University, Japan.)24840814
291 Hill SM, Belancio VP, Dauchy RT, Xiang S, Brimer S, Mao L, Hauch A, Lundberg PW, Summers W, Yuan L, Frasch T, Blask DE. 2015. Melatonin: an inhibitor of breast cancer. Endocr Relat Cancer 22(3): R183–204. (Supported by NIH, the American Association for Laboratory Animal Science, the Life Extension Foundation, and the Edmond and Lily Safra Endowed Chair for Breast Cancer Research at Tulane Cancer Center. Authors affiliated with Tulane University School of Medicine, LA.)25876649
292 Hill SM, Cheng C, Yuan L, Mao L, Jockers R, Dauchy B, Blask DE. 2013. Age-related decline in melatonin and Its MT1 receptor are associated with decreased sensitivity to melatonin and enhanced mammary tumor growth. Curr. Aging Sci. 6(6): 125–133. (Supported by NIH and the Army DOD. Authors affiliated with Tulane University School of Medicine, LA; Institute Cochin, France.)23895529
293 Hill SM, Spriggs LL, Simon MA, Muraoka H, Blask DE. 1992. The growth inhibitory action of melatonin on human breast cancer cells is linked to the estrogen response system. Cancer Lett 64(3): 249–256. (Supported by NCI and the American Cancer Society. Authors affiliated with Tulane University, LA; Abilene Christian University, TX; Mary Imogene Bassett Hospital, NY.)1638517
294 Hirano A, Fu YH, Ptáček LJ. 2016. The intricate dance of post-translational modifications in the rhythm of life. Nat Struct Mol Biol 23(12): 1053–1060. (Supported by NIH, the the William Bowes Neurogenetics Fund, the Howard Hughes Medical Institute, and the Uehara memorial foundation. Authors affiliated with University of California - San Francisco, CA; Kavli Institute for Fundamental Neuroscience, CA; Weill Institute of Neurosciences, CA; Howard Hughes Medical Institute, CA.)27922612
295 Holick MF. 2016. Biological effects of sunlight, ultraviolet radiation, visible light, infrared radiation and vitamin D for health. Anticancer Res 36(3): 1345–1356. (Support not reported. Authors affiliated with Boston University Medical Center, MA.)26977036
296 Honda K, Kondo M, Hiramoto D, Saneyasu T, Kamisoyama H. 2017. Effects of continuous white light and 12h white-12h blue light-cycles on the expression of clock genes in diencephalon, liver, and skeletal muscle in chicks. Comp Biochem Physiol A Mol Integr Physiol 207: 73–78. (Supported by the Project of the NARO Bio-oriented Technology Research Advancement Institution [The Special Scheme to Create Dynamism in Agriculture, Forestry and Fisheries through Deploying Highly Advanced Technology]. Authors affiliated with Kobe University, Japan.)28238833
297 Honma S. 2018. The mammalian circadian system: a hierarchical multi-oscillator structure for generating circadian rhythm. J Physiol Sci 68(3): 207–219. (Support not reported. Authors affiliated with Hokkaido University, Japan.)29460036
298 Hoogerwerf WA, Hellmich HL, Cornelissen G, Halberg F, Shahinian VB, Bostwick J, Savidge TC, Cassone VM. 2007. Clock gene expression in the murine gastrointestinal tract: Endogenous rhythmicity and effects of a feeding regimen. Gastroenterology 133(4): 1250–1260. (Supported by R21 DK074477-01A1. Authors affiliated with University of Michigan, MI; University of Texas Medical Branch, TX; University of Minnesota, MN; Texas A&M University, TX.)17919497
299 Howlader N, Noone AM, Krapcho M, Miller D, Bishop K, Kosary CL, Yu M, Ruhl J, Tatalovich Z, Mariotto A, Lewis DR, Chen HS, Feuer EJ, Cronin KA. 2017. SEER Cancer Statistics Review, 1975-2014. National Cancer Institute. https://seer.cancer.gov/csr/1975_2014/, based on November 2016 SEER data submission, posted to the SEER web site, April 2017
300 Huisman SA, Ahmadi AR, IJzermans JNM, Verhoef C, van der Horst GTJ, de Bruin RWF. 2016. Disruption of clock gene expression in human colorectal liver metastases. Tumour Biol 37(10): 13973–13981. (Supported by the Dutch Cancer Society. Authors affiliated with Erasmus University Medical Center, Netherlands.)27492458
301 Hung EW, Aronson KJ, Leung M, Day A, Tranmer J. 2016. Shift work parameters and disruption of diurnal cortisol production in female hospital employees. Chronobiol Int 33(8): 1045–1055. (Support not reported. Authors affiliated with Queen’s University, Canada; Hospital for Sick Children, Canada; Kingston General Hospital, Canada.)27384964
302 Hurley S, Goldberg D, Nelson D, Hertz A, Horn-Ross PL, Bernstein L, Reynolds P. 2014. Light at night and breast cancer risk among California teachers. Epidemiology 25(5): 697–706. (Supported by the Regents of the University of California, California Breast Cancer Research Program and the National Cancer Institute. Authors affiliated with Cancer Prevention Institute of California, CA; Beckman Research Institute, CA; Stanford University School of Medicine, CA.)25061924
303 Hurley S, Nelson DO, Garcia E, Gunier R, Hertz A, Reynolds P. 2013. A cross-sectional analysis of light at night, neighborhood sociodemographics and urinary 6-sulfatoxymelatonin concentrations: implications for the conduct of health studies. Int J Health Geogr 12: 39. (Supported by the California Breast Cancer Research Program and National Cancer Institute. Authors affiliated with Cancer Prevention Institute of California, CA; Stanford University School of Medicine, CA.)24127816
304 Husse J, Eichele G, Oster H. 2015. Synchronization of the mammalian circadian timing system: Light can control peripheral clocks independently of the SCN clock: alternate routes of entrainment optimize the alignment of the body’s circadian clock network with external time. Bioessays 37(10): 1119–1128. (Supported by the Max Planck Society and the Volkswagen Foundation. Authors affiliated with Max Planck Institute for Biophysical Chemistry, Germany; University of Lübeck, Germany.)26252253
305 IARC. 2010. Shift work. In Painting, Firefighting, and Shiftwork. IARC Working Group on the Evaluation of Carcinogenic Risks to Humans. vol. 98. Lyon, France: International Agency for Research on Cancer. p. 563–764.
306 IARC. 2012. EUCAN: Breast Cancer. International Agency for Research on Cancer. Last accessed: 1/8/18. http://eco.iarc.fr/EUCAN/CancerOne.aspx?Cancer=46&Gender=2
307 Ibáñez-Costa A, Córdoba-Chacón J, Gahete MD, Kineman RD, Castaño JP, Luque RM. 2015. Melatonin regulates somatotrope and lactotrope function through common and distinct signaling pathways in cultured primary pituitary cells from female primates. Endocrinology 156(3): 1100–1110. (Supported by Junta de Andalucía, the Ministerio de Economía y Competitividad, Gobierno de España, the Instituto de Salud Carlos III, the Centro de Investigación Biomédica en Red de la Fisiopatología de la Obesidad y Nutrición, Ayuda Merck Serono 2013, the Department of Veterans Affairs, and NIH. Authors affiliated with University of Cordoba, Spain; University of Illinois at Chicago, IL.)25545385
308 Ijaz S, Verbeek J, Seidler A, Lindbohm ML, Ojajärvi A, Orsini N, Costa G, Neuvonen K. 2013. Night-shift work and breast cancer – a systematic review and meta-analysis. Scand J Work Environ Health 39(5): 431–447. (Supported by the Danish Work and Environment Fund. Authors affiliated with Finnish Institute of Occupational Health, Finland; Technical University of Dresden, Germany; Karolinska Institute, Sweden; University of Milan, Italy; IRCCS Ca’ Granda Foundation, Italy.)23804277
309 Ika K, Suzuki E, Mitsuhashi T, Takao S, Doi H. 2013. Shift work and diabetes mellitus among male workers in Japan: does the intensity of shift work matter? Acta Med Okayama 67(1): 25–33. (Support not reported. Authors affiliated with Okayama University Graduate School of Medicine, Dentistry and Pharmaceutical Sciences, Japan.)23439506
310 Illnerová H, Vanecek J, Hoffmann K. 1989. Different mechanisms of phase delays and phase advances of the circadian rhythm in rat pineal N-acetyltransferase activity. J Biol Rhythms 4(2): 187–200. (Support not reported. Authors affiliated with Czechoslovak Academy of Sciences, Czechoslovakia; Max-Planck-Gesellschaft Clinical Research Unit for Reproductive Medicine, Germany.)2519588
311 ILO. 2004. Shift Work. Information Sheet No. WT-8. Geneva, Switzerland: International Labour Office. 4 pp.
312 Institute of Medicine. 2012. Examining mechanisms of breast cancer over the lifecourse: Implications for risk. In Breast Cancer and the Environment: A Life Course Approach Washington, DC: The National Academies Press. p. 239–281. https://www.nap.edu/read/13263/chapter/7.
313 Ishihara I, Nakano M, Ikushima M, Hara Y, Yoshimine T, Haraga M, Nakatani J, Kawamoto R, Kasai H. 2008. Effect of work conditions and work environments on the formation of 8-OH-dG in nurses and non-nurse female workers. J UOEH 30(3): 293–308. (Supported by the Ministry of Education, Culture, Sports, Science and Technology of Japan. Authors affiliated with University of Occupational and Environmental Health, Japan; Kyushu University, Japan.)18783011
314 Ishii N, Iwata T, Dakeishi M, Murata K. 2004. Effects of shift work on autonomic and neuromotor functions in female nurses. J Occup Health 46(5): 352–358. (Supported by the Ministry of Education, Culture, Science and Technology, Japan. Authors affiliated with Akita University School of Medicine, Japan.)15492451
315 Isobe Y, Fukamachi K, Hida H, Tsuda H, Nishino H. 2008. Diethylnitrosamine-induced hepatic lesions are greater in rats maintained under a light-dark cycle than under constant light, related to the locomotor activity rhythm. Asian Pac J Cancer Prev 9(4): 619–624. (Supported by the Ministry of Education, Sports, Science and Culture of Japan and the Ministry of Health, Labor and Welfare, Japan.)19256749
316 Itoh H, Weng Z, Saito H, Ogawa Y, Nakayama K, Hasegawa-Ohira M, Morimoto K, Maki S, Takahashi M. 2011. Association between night-shift work and serum 25-hydroxyvitamin D levels in Japanese male indoor workers: a cross-sectional study. Ind Health 49(5): 658–662. (Supported by the National Institute of Occupational Safety and Health, Japan. Authors affiliated with National Institute of Occupational Safety and Health, Japan; Osaka University Graduate School of Medicine, Japan; Osaka University of Health and Sport Sciences, Japan.)21804263
317 Iversen OH, Iversen UM. 1995. A diurnal variation in the tumorigenic response of mouse epidermis to a single application of the strong short-acting chemical carcinogen methylnitrosourea. A dose-response study of 1, 2 and 10 mg. In Vivo 9(2): 117–132. (Supported by the Norwegian Cancer Society and the University of Oslo. Authors affiliated with University of Oslo, Norway; Rikshospitalet, Norway.)7548787
318 Iwamoto A, Kawai M, Furuse M, Yasuo S. 2014. Effects of chronic jet lag on the central and peripheral circadian clocks in CBA/N mice. Chronobiol. Int. 31(2): 189–198. (Supported by the Japanese Society for the Promotion of Science, the Uehara Memorial Foundation, the Nisshin Seifun Foundation, and the Research Grant for Young Investigators of Faculty of Agriculture, Kyushu University. Authors affiliated with Kyushu University, Japan.)24147659
319 Jacobs DI, Hansen J, Fu A, Stevens RG, Tjonneland A, Vogel UB, Zheng T, Zhu Y. 2013. Methylation alterations at imprinted genes detected among long-term shiftworkers. Environ Mol Mutagen 54(2): 141–146. (Supported by NIEHS, Yale University, and the Danish Cancer Society. Authors affiliated with Yale School of Public Health, CT; Danish Cancer Society, Denmark; University of Connecticut Health Center, CT; National Research Centre for the Working Environment, Denmark.)23193016
320 James FO, Cermakian N, Boivin DB. 2007. Circadian rhythms of melatonin, cortisol, and clock gene expression during simulated night shift work. Sleep 30(11): 1427–1436. (Supported by the Fonds de Recherche en Santé du Québec and the Canadian Institutes of Health Research. Authors affiliated with Douglas Mental Health University Institute, Canada; McGill University, Canada.)18041477
321 James P, Bertrand KA, Hart JE, Schernhammer ES, Tamimi RM, Laden F. 2017. Outdoor light at night and breast cancer incidence in the Nurses’ Health Study II. Environ Health Perspect 125(8): 087010. (Supported by the Harvard National Heart, Lung, and Blood Institute, NIH, NCI, and the Susan G. Komen for the Cure® organization. Authors affiliated with Harvard T. H. Chan School of Public Health, MA; Brigham and Women’s Hospital and Harvard Medical School, MA; Boston University, MA; Medical University of Vienna, Austria; University of California Los Angeles, CA.)28886600
322 Jensen MA, Garde AH, Kristiansen J, Nabe-Nielsen K, Hansen AM. 2016. The effect of the number of consecutive night shifts on diurnal rhythms in cortisol, melatonin and heart rate variability (HRV): a systematic review of field studies. Int Arch Occup Environ Health 89(4): 531–545. (Supported by the Danish Working Environment Research Fund and the University of Copenhagen. Authors affiliated with University of Copenhagen, Denmark; National Research Centre for the Working Environment, Denmark.)26464315
323 Ji BT, Gao YT, Shu XO, Yang G, Yu K, Xue SZ, Li HL, Liao LM, Blair A, Rothman N, Zheng W, Chow WH. 2012. Nightshift work job exposure matrices and urinary 6-sulfatoxymelatonin levels among healthy Chinese women. Scand J Work Environ Health 38(6): 553–559. (Supported by NIH and the National Center for Research Resources. Authors affiliated with National Cancer Institute, MD; Vanderbilt University School of Medicine, TN; Shanghai Cancer Institute, China.)22975884
324 Jia Y, Lu Y, Wu K, Lin Q, Shen W, Zhu M, Huang S, Chen J. 2013. Does night work increase the risk of breast cancer? A systematic review and meta-analysis of epidemiological studies. Cancer Epidemiol 37(3): 197–206. (Support not reported. Authors affiliated with Shanghai Jiaotong University School of Medicine, China.)23403128
325 Jilge B, Kunz E. 2004. Chapter 20: Circadian rhythms of the mouse. In The Laboratory Mouse H Hedrich, G Bullock, eds. San Diego, CA: Elsevier. p. 311–325. (Support not reported. Authors affiliated with University of Ulm, Germany.)
326 Johns LE, Jones ME, Schoemaker MJ, McFadden E, Ashworth A, Swerdlow AJ. 2018. Domestic light at night and breast cancer risk: a prospective analysis of 105 000 UK women in the Generations Study. Br J Cancer 118(4): 600–606. (Supported by Breast Cancer Now, The Institute of Cancer Research, and NHS. Authors affiliated with Institute of Cancer Research, UK; Breast Cancer Now Research Centre, UK.)29360812
327 Jørgensen JT, Karlsen S, Stayner L, Andersen J, Andersen ZJ. 2017. Shift work and overall and cause-specific mortality in the Danish nurse cohort. Scand J Work Environ Health 43(2): 117–126. (Support not reported. Authors affiliated with University of Copenhagen, Denmark; University of Illinois at Chicago School of Public Health, IL; Danish Cancer Society, Denmark.)28245504
328 Joska TM, Zaman R, Belden WJ. 2014. Regulated DNA methylation and the circadian clock: implications in cancer. Biology (Basel) 3(3): 560–577. (Supported by the Nation Institute of General Medical Sciences and the New Jersey Agriculture Experiment Station. Authors affiliated with State University of New Jersey, NJ.)25198253
329 Kamdar BB, Tergas AI, Mateen FJ, Bhayani NH, Oh J. 2013. Night-shift work and risk of breast cancer: a systematic review and meta-analysis. Breast Cancer Res Treat 138(1): 291–301. (Support not reported. Authors affiliated with Johns Hopkins University, MD; Johns Hopkins Bloomberg School of Public Health, MD; Howard University Hospital, Washington, D.C.)23400581
330 Kane S. 2016. These incredible maps show the most lightpolluted places in the world. Business Insider. Updated on: 6/14/16. http://www.businessinsider.com/worst-light-pollution-skyglow-map-2016-6
331 Kannen V, Marini T, Zanette DL, Frajacomo FT, Silva GE, Silva WA, Jr., Garcia SB. 2011. The melatonin action on stromal stem cells within pericryptal area in colon cancer model under constant light. Biochem Biophys Res Commun 405(4): 593–598. (Supported by CAPES, CNPq and FAPESP. Authors affiliated with University of São Paulo, Brazil; Center for Cell Therapy and Regional Blood Center, Brazil.)21266165
332 Kantermann T, Duboutay F, Haubruge D, Hampton S, Darling AL, Berry JL, Kerkhofs M, Boudjeltia KZ, Skene DJ. 2014. The direction of shift-work rotation impacts metabolic risk independent of chronotype and social jetlag – an exploratory pilot study. Chronobiol Int 31(10): 1139–1145. (Supported by the German Research Foundation, the Technology foundation STW, the 6th Framework Project EUCLOCK, a Royal Society Wolfson Research Merit Award, and the ISPPC Research Fund. Authors affiliated with University of Groningen, Netherlands; Clinical Centre Ludwig-Maximilians University, Germany; CMBT, Belgium; ArcelorMittal Industeel Belgium, Belgium; University of Surrey, UK; Manchester Royal Infirmary, UK; Université Libre de Bruxelles, Belgium.)25187988
333 Karantanos T, Theodoropoulos G, Pektasides D, Gazouli M. 2014. Clock genes: their role in colorectal cancer. World J Gastroenterol 20(8): 1986–1992. (Support not reported. Authors affiliated with University of Athens, Greece.)24587674
334 Kelleher FC, Rao A, Maguire A. 2014. Circadian molecular clocks and cancer. Cancer Lett 342(1): 9–18. (Support not reported. Authors affiliated with Peter MacCallum Cancer Centre, Australia; St. Vincent’s University Hospital, Ireland.)24099911
335 Kervezee L, Cuesta M, Cermakian N, Boivin DB. 2018. Simulated night shift work induces circadian misalignment of the human peripheral blood mononuclear cell transcriptome. Proc Natl Acad Sci U S A 115(21): 5540–5545. (Supported by the Canadian Institutes of Health Research, and the Fonds de Recherche du Québec–Santé. Authors affiliated with McGill University, Canada.)29735673
336 Keshet-Sitton A, Or-Chen K, Huber E, Haim A. 2017. Illuminating a risk for breast cancer: A preliminary ecological study on the association between streetlight and breast cancer. Integr Cancer Ther 16(4): 451–463. (No financial support recieved. Authors affiliated with University of Haifa, Israel.)27899698
337 Keshet-Sitton A, Or-Chen K, Yitzhak S, Tzabary I, Haim A. 2016. Can avoiding light at night reduce the risk of breast cancer? Integr Cancer Ther 15(2): 145–152. (No financial support received. Authors affiliated with University of Haifa, Israel; Poria Medical Center, Israel; Soroka University Medical Center, Israel.)26631258
338 Kettner NM, Katchy CA, Fu L. 2014. Circadian gene variants in cancer. Ann Med 46(4): 208–220. (Supported by the USDA/ARS and the NIH/NCI. Authors affiliated with Baylor College of Medicine, TX.)24901356
339 Kettner NM, Mayo SA, Hua J, Lee C, Moore DD, Fu L. 2015. Circadian dysfunction induces leptin resistance in mice. Cell Metab 22(3): 448–459. (Supported by USDA/ARS, NIH/NCI, NIH/NIDDK, and NIH/NICHD. Authors affiliated with Baylor College of Medicine, TX; Florida State University, FL.)26166747
340 Kettner NM, Voicu H, Finegold MJ, Coarfa C, Sreekumar A, Putluri N, Katchy CA, Lee C, Moore DD, Fu L. 2016. Circadian homeostasis of liver metabolism suppresses hepatocarcinogenesis. Cancer Cell 30(6): 909–924. (Supported by NIH, NCI, USDA, CRPIT, NIDDK, the BCM Dan L. Duncan Cancer Center, the Alkek Center for Molecular Discovery, and the BCM Agilent Technologies Center of Excellence. Authors affiliated with Baylor College of Medicine, TX; Florida State University, FL.)27889186
341 Khosro S, Alireza S, Omid A, Forough S. 2011. Night work and inflammatory markers. Indian J Occup Environ Med 15(1): 38–41. (Supported by the Tehran University of Medical Sciences. Authors affiliated with Tehran University of Medical Sciences, Iran; Dr. Sharifi Medical Lab, Iran.)21808500
342 Kiefer T, Ram PT, Yuan L, Hill SM. 2002. Melatonin inhibits estrogen receptor transactivation and cAMP levels in breast cancer cells. Breast Cancer Res Treat 71(1): 37–45. (Supported by NIH. Authors affiliated with Tulane University School of Medicine, LA.)11859872
343 Kim SW, Jang EC, Kwon SC, Han W, Kang MS, Nam YH, Lee YJ. 2016. Night shift work and inflammatory markers in male workers aged 20-39 in a display manufacturing company. Ann Occup Environ Med 28: 48. (Support not reported. Authors affiliated with Soonchunhyang University Cheonan Hospital, Korea.)27660715
344 Kim YJ, Lee E, Lee HS, Kim M, Park MS. 2015. High prevalence of breast cancer in light polluted areas in urban and rural regions of South Korea: An ecologic study on the treatment prevalence of female cancers based on National Health Insurance data. Chronobiol Int 32(5): 657–667. (Supported by the Korean Environmental Industry and Technology Institute. Authors affiliated with Korea University, South Korea; Sungshin Women’s University College of Natural Sciences, South Korea.)25955405
345 Kishi T, Sunagawa K. 2011. Experimental ‘jet lag’ causes sympathoexcitation via oxidative stress through AT1 receptor in the brainstem. Conf Proc IEEE Eng Med Biol Soc 2011: 1969–1972. (Supported by the Japan Society for the Promotion of Science. Authors affiliated with Kyushu University Graduate School of Medical Sciences, Japan.)
346 Kiss Z, Ghosh PM. 2016. Circadian rhythmicity and the influence of ‘clock’ genes on prostate cancer. Endocr Relat Cancer 23(11): T123–T134. (Supported by the Department of Veterans Affairs and NIH. Authors affiliated with VA Northern California Health Care System, CA; University of California at Davis, CA.)27660402
347 Kliukiene J, Tynes T, Andersen A. 2001. Risk of breast cancer among Norwegian women with visual impairment. Br J Cancer 84(3): 397–399. (Supported by Telenor AS. Authors affiliated with Cancer Registry of Norway, Norway; Norwegian Radiation Protection Authority, Norway.)11161406
348 Kloog I, Haim A, Stevens RG, Barchana M, Portnov BA. 2008. Light at night co-distributes with incident breast but not lung cancer in the female population of Israel. Chronobiol Int 25(1): 65–81. (Supported by NIH. Authors affiliated with University of Haifa, Israel; University of Connecticut Health Center, CT; Ministry of Health, Israel.)18293150
349 Kloog I, Haim A, Stevens RG, Portnov BA. 2009. Global co-distribution of light at night (LAN) and cancers of prostate, colon, and lung in men. Chronobiol Int 26(1): 108–125. (Support not reported. Authors affiliated with University of Haifa, Israel; University of Connecticut Health Center, CT.)19142761
350 Kloog I, Portnov BA, Rennert HS, Haim A. 2011. Does the modern urbanized sleeping habitat pose a breast cancer risk? Chronobiol Int 28(1): 76–80. (Support not reported. Authors affiliated with University of Haifa, Israel; Technion–Israel Institute of Technology and Clalit Health Services National Cancer Control Center, Israel; Harvard School of Public Health, MA.)21182407
351 Kloog I, Stevens RG, Haim A, Portnov BA. 2010. Nighttime light level co-distributes with breast cancer incidence worldwide. Cancer Causes Control 21(12): 2059–2068. (Support not reported. Authors affiliated with University of Haifa, Israel; University of Connecticut Health Center, CT.)20680434
352 Knutsson A, Alfredsson L, Karlsson B, Åkerstedt T, Fransson EI, Westerholm P, Westerlund H. 2013. Breast cancer among shift workers: results of the WOLF longitudinal cohort study. Scand J Work Environ Health 39(2): 170–177. (Support not reported. Authors affiliated with Mid Sweden University, Sweden; Karolinska Institutet, Sweden; Norrlands University Hospital, Sweden; Stockholm University, Sweden; Jönköping University, Sweden; Uppsala University, Sweden.)23007867
353 Ko CH, Takahashi JS. 2006. Molecular components of the mammalian circadian clock. Hum Mol Genet 15(Spec No 2): R271–277. (Supported by NIH. Authors affiliated with Northwestern University, IL; University of Toronto, Canada.)16987893
354 Kochan DZ, Ilnytskyy Y, Golubov A, Deibel SH, McDonald RJ, Kovalchuk O. 2015. Circadian disruption-induced microRNAome deregulation in rat mammary gland tissues. Oncoscience 2(4): 428–442. (Supported by the Canadian Breast Cancer Foundation. Authors affiliated with University of Lethbridge, Canada.)26097876
355 Kochan DZ, Ilnytskyy Y, Golubov A, Deibel SH, McDonald RJ, Kovalchuk O. 2016. Circadian-disruption-induced gene expression changes in rodent mammary tissues. Oncoscience 3(2): 58–70. (Supported by the Canadian Breast Cancer Foundation. Authors affiliated with University of Lethbridge, Canada.)27014724
356 Kolstad HA, Garde AH, Hansen AM, Frydenberg M, Christiansen P, Vistisen HT, Bonde JP. 2017. Response to Dr Stevens’ letter ref. Visitisen et al: “Short-term effects of night shift work on breast cancer risk: a cohort study of payroll data”. Scand J Work Environ Health 43(1): 95. (Support not reported. Authors affiliated with Aarhus University Hospital, Denmark; National Research Centre for the Working Environment, Denmark; University of Copenhagen, Denmark; Danish Breast Cancer Corporative Group, Denmark; Bispebjerg University Hospital, Denmark.)27935621
357 Koopman A, Rauh S, van’t Riet E, Groeneveld L, van der Heijden A, Elders PJ, Dekker JM, Nijpels G, Beulens J, Rutters F. 2017. The association between social jetlag, the metabolic syndrome, and type 2 diabetes mellitus in the general population. J Biol Rhythms 32(4): 359–368. (Support not reported. Authors affiliated with VU Medical Centre, Netherlands; University Medical Centre Utrecht, Netherlands.)28631524
358 Koppes LL, Geuskens GA, Pronk A, Vermeulen RC, de Vroome EM. 2014. Night work and breast cancer risk in a general population prospective cohort study in The Netherlands. Eur J Epidemiol 29(8): 577–584. (Supported by the Dutch Ministry of Social Affairs and Employment. Authors affiliated with Netherlands Organization for Applied Scientific Research, Netherlands; Utrecht University, Netherlands.)25012051
359 Korkmaz A, Reiter RJ. 2008. Epigenetic regulation: a new research area for melatonin? J Pineal Res 44(1): 41–44. (Support not reported. Authors affiliated with Gulhane Military Medical Academy, Turkey; University of Texas Health Science Center at San Antonio, TX.)18078446
360 Korkmaz A, Sanchez-Barcelo EJ, Tan DX, Reiter RJ. 2009. Role of melatonin in the epigenetic regulation of breast cancer. Breast Cancer Res Treat 115(1): 13–27. (Supported by the Spanish Ministry of Education and Science. Authors affiliated with Gulhane Military Medical Academy, Turkey; University of Texas Health Science Center at San Antonio, TX; University of Cantabria, Spain.)18592373
361 Korompeli A, Sourtzi P, Tzavara C, Velonakis E. 2009. Rotating shift-related changes in hormone levels in intensive care unit nurses. J Adv Nurs 65(6): 1274–1282. (No funding received. Authors affiliated with University of Athens, Greece.)19374673
362 Korsiak J, Tranmer J, Leung M, Borghese MM, Aronson KJ. 2017. Actigraph measures of sleep among female hospital employees working day or alternating day and night shifts. J Sleep Res. (Supported by the Canadian Institutes for Health Research and the Workplace Safety and Insurance Board. Authors affiliated with Queen’s University, Canada.)
363 Kothari LS. 1987. Influence of chronic melatonin on 9,10-dimethyl-1,2-benzanthracene-induced mammary tumors in female Holtzman rats exposed to continuous light. Oncology 44(1): 64–66. (Support not reported. Authors affiliated with Tata Memorial Center, India.)3104848
364 Kothari LS, Shah PN, Mhatre MC. 1982. Effect of continuous light on the incidence of 9,10-dimethyl-1,2-benzanthracene induced mammary tumors in female Holtzman rats. Cancer Lett 16(3): 313–317. (Support not reported. Authors affiliated with Cancer Research Institute, India.)6817910
365 Kozaki T, Kubokawa A, Taketomi R, Hatae K. 2015. Effects of day-time exposure to different light intensities on light-induced melatonin suppression at night. J Physiol Anthropol 34: 27. (Support not reported. Authors affiliated with Kyushu University, Japan.)26141542
366 Kozaki T, Kubokawa A, Taketomi R, Hatae K. 2016. Light-induced melatonin suppression at night after exposure to different wavelength composition of morning light. Neurosci Lett 616: 1–4. (Supported by the Department of Design, Kyushu University. Authors affiliated with Kyushu University, Japan.)26777427
367 Kräuchi K, Cajochen C, Pache M, Flammer J, Wirz-Justice A. 2006. Thermoregulatory effects of melatonin in relation to sleepiness. Chronobiol Int 23(1–2): 475–484. (Support not reported. Authors affiliated with University Psychiatric Clinics, Switzerland; University Eye Clinic, Switzerland.)16687320
368 Kubo T, Oyama I, Nakamura T, Kunimoto M, Kadowaki K, Otomo H, Fujino Y, Fujimoto N, Matsumoto T, Matsuda S. 2011. Industry-based retrospective cohort study of the risk of prostate cancer among rotating-shift workers. Int J Urol 18(3): 206–211. (Supported by KAKENHI from the Ministry of Education, Culture, Sports, Science and Technology, Japan, and the Occupational Health Promotion Foundation, Japan. Authors affiliated with University of Occupational and Environmental Health, Japan; Asahi Kasei Nobeoka Office Health Care Center, Japan; Asahi Kasei Chemicals Mizushima Works Health Care Center, Japan.)21332815
369 Kubo T, Ozasa K, Mikami K, Wakai K, Fujino Y, Watanabe Y, Miki T, Nakao M, Hayashi K, Suzuki K, Mori M, Washio M, Sakauchi F, Ito Y, Yoshimura T, Tamakoshi A. 2006. Prospective cohort study of the risk of prostate cancer among rotating-shift workers: findings from the Japan collaborative cohort study. Am J Epidemiol 164(6): 549–555. (Supported by the Ministry of Education, Science, Sports and Culture of Japan. Authors affiliated with University of Occupational and Environmental Health, Japan; Kyoto Prefectural University of Medicine, Japan; Aichi Cancer Center Research Institute, Japan; Fukuoka Institute of Occupational Health, Japan; Meiji University of Oriental Medicine, Japan; Fujita Health University School of Health Sciences, Japan; Sapporo Medical University School of Medicine, Japan; Nagoya University Graduate School of Medicine, Japan; Fukuoka Institute of Health and Environmental Sciences, Japan.)16829554
370 Kulikov VY, Fridman YM, Fomin AN. 2007. Role of oxidative stress in mechanisms of premature aging in shift labor workers. Alaska Med 49(2 Suppl): 81–84. (Support not reported. Authors affiliated with Scientific Center of Clinical and Experimental Medicine SB RAMS, Russia.)17929612
371 Kwon P, Lundin J, Li W, Ray R, Littell C, Gao D, Thomas DB, Checkoway H. 2015. Night shift work and lung cancer risk among female textile workers in Shanghai, China. J Occup Environ Hyg 12(5): 334–341. (Supported by NIH. Authors affiliated with Bassett Army Community Hospital, Alaska; University of Washington, WA; Fred Hutchinson Cancer Research Center, WA; Walter Reed Army Institute of Research, MD; Fudan University, China; University of California San Diego, CA.)25616851
372 Lahti TA, Partonen T, Kyyrönen P, Kauppinen T, Pukkala E. 2008. Night-time work predisposes to non-Hodgkin lymphoma. Int J Cancer 123(9): 2148–2151. (Supported by the Academy of Finland. Authors affiliated with National Public Health Institute, Finland; Finnish Institute of Occupational Health, Finland; Institute of Statistical and Epidemiological Cancer Research, Finland.)18697199
373 Lang R, Hintner H, Hermann A, Brandstaetter R. 2003. Photoperiod modulates melanoma growth in C57BL/6 mice. Exp Dermatol 12(4): 510–513. (Supported by the Medical Research Centre of the University of Salzburg, the Austrian Academy of Sciences, and the Austrian National Bank. Authors affiliated with University of Salzburg, Austria; General Hospital Salzburg, Austria; Max-Planck Research Centre for Ornithology, Germany.)12930310
374 Langley AR, Graham CH, Grundy AL, Tranmer JE, Richardson H, Aronson KJ. 2012. A cross-sectional study of breast cancer biomarkers among shift working nurses. BMJ Open 2(1): e000532. (Supported by the Workplace Safety and Insurance Board of Ontario and Breast Cancer Action Kingston. Authors affiliated with Queen’s University, Canada.)
375 Lee S, Donehower LA, Herron AJ, Moore DD, Fu L. 2010. Disrupting circadian homeostasis of sympathetic signaling promotes tumor development in mice. PLoS ONE 5(6). (Supported by NIH and the USDA. Authors affiliated with Baylor College of Medicine, TX.)
376 LeGates TA, Fernandez DC, Hattar S. 2014. Light as a central modulator of circadian rhythms, sleep and affect. Nat Rev Neurosci 15(7): 443–454. (Support not reported. Authors affiliated with Johns Hopkins University, MD.)24917305
377 Lenoir V, de Jonage-Canonico MB, Perrin MH, Martin A, Scholler R, Kerdelhué B. 2005. Preventive and curative effect of melatonin on mammary carcinogenesis induced by dimethylbenz[a]anthracene in the female Sprague-Dawley rat. Breast Cancer Res 7(4): R470–476. (Support not reported. Authors affiliated with Université René Descartes, France; Hôpital Avicenne, France.)15987452
378 Leung M, Tranmer J, Hung E, Korsiak J, Day AG, Aronson KJ. 2016. Shift work, chronotype, and melatonin patterns among female hospital employees on day and night shifts. Cancer Epidemiol Biomarkers Prev 25(5): 830–838. (Supported by the Workplace Safety and Insurance Board of Ontario and the Canadian Institutes of Health Research Canada. Authors affiliated with Queen’s University, Canada; Kingston General Hospital, Canada.)26941366
379 Levallois P, Dumont M, Touitou Y, Gingras S, Mâsse B, Gauvin D, Kröger E, Bourdages M, Douville P. 2001. Effects of electric and magnetic fields from high-power lines on female urinary excretion of 6-sulfatoxymelatonin. Am J Epidemiol 154(7): 601–609. (Supported by Hydro-Québec and Électricité de France. Authors affiliated with Centre hospitalier universitaire de Québec, Canada; Institut national de santé publique du Québec and Université Laval, Canada; Hôpital du Sacré-Coeur and Université de Montréal, Canada; Faculté de médecine Pitié-Salpétrière, France; Institut de recherche d’Hydro-Québec, Varennes, Canada; Hôpital de l’Hôtel-Dieu de Québec, Canada.)11581093
380 Lévi F, Dugué P-A, Innominato P, Karaboué A, Dispersyn G, Parganiha A, Giacchetti S, Moreau T, Focan C, Waterhouse J, Spiegel D. 2014. Wrist actimetry circadian rhythm as a robust predictor of colorectal cancer patients survival. Chronobiol Int 31(8): 891–900. (Supported by the Association Internationale pour la Recherche sur le Temps Biologique et la Chronothérapie [ARTBC International], Paul Brousse Hospital, France, the European Union through the 7th Framework Programme project In-CASA, and Paris Sud University. Authors affiliated with INSERM, France; Université Paris Sud, France; Paul Brousse Hospital, France; Pt. Ravishankar Shukla University, India; Hospitalier Chrétien, Belgium; John Moores University, UK; Stanford University School of Medicine, CA.)24927369
381 Lewy AJ. 1999. The dim light melatonin onset, melatonin assays and biological rhythm research in humans. Biol Signals Recept 8(1–2): 79–83. (Supported by the Public Health Service. Authors affiliated with Oregon Health Sciences University, OR.)10085467
382 Lewy AJ, Emens JS, Bernert RA, Lefler BJ. 2004. Eventual entrainment of the human circadian pacemaker by melatonin is independent of the circadian phase of treatment initiation: clinical implications. J Biol Rhythms 19(1): 68–75. (Supported by the Public Health Service, and the National Alliance for Research on Schizophrenia and Depression. Authors affiliated with Oregon Health & Science University, OR.)14964705
383 Li JC, Xu F. 1997. Influences of light-dark shifting on the immune system, tumor growth and life span of rats, mice and fruit flies as well as on the counteraction of melatonin. Biol Signals 6(2): 77–89. (Support not reported. Authors affiliated with Shenyang Pharmaceutical University, China.)9266095
384 Li M, Tse LA, Chan WC, Kwok CH, Leung SL, Wu C, Yu WC, Lee PM, Tsang KH, Law SH, Vermeulen R, Gu F, Caporaso NE, Yu IT, Wang F, Yang XR. 2017. Nighttime eating and breast cancer among Chinese women in Hong Kong. Breast Cancer Res 19(1): 31. (Supported by the Research Grants Council of Hong Kong. Authors affiliated with Chinese University of Hong Kong, China; North District Hospital, China; Princess Margaret Hospital, China; Pamela Youde Nethersole Eastern Hospital, China; Yan Chai Hospital, China; Utrecht University, Netherlands; NIH, MD.)28302140
385 Li Q, Zheng T, Holford TR, Boyle P, Zhang Y, Dai M. 2010. Light at night and breast cancer risk: results from a population-based case-control study in Connecticut, USA. Cancer Causes Control 21(12): 2281–2285. (Supported by the National Cancer Institute/National Institute of Environmental Health Science. Authors affiliated with Huazhong University of Science and Technology, China; Yale School of Public Health, CT; International Prevention Research Institute, France; Chinese Academy of Medical Sciences, China.)20927578
386 Li W, Ray RM, Thomas DB, Davis S, Yost M, Breslow N, Gao DL, Fitzgibbons ED, Camp JE, Wong E, Wernli KJ, Checkoway H. 2015. Shift work and breast cancer among women textile workers in Shanghai, China. Cancer Causes Control 26(1): 143–150. (Supported by NIOSH, NCI, and NIH. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Washington, WA; Zhong Shan Hospital Branch, China; Group Health Research Institute, WA; University of California - San Diego, CA.)25421377
387 Li X-M, Liu X-H, Filipski E, Metzger G, Delagrange P, Jeanniot JP, Lévi F. 2000. Relationship of atypical melatonin rhythm with two circadian clock outputs in B6D2F_1_ mice. Am J Physiol Reg Integr Comp Physiol 278: R924–R930. (Supported by the ‘‘Association pour la Recherche sur le Temps Biologique et la Chronothérapeutique,’’ Hôpital Paul Brousse, Villejuif, and the Institut de Recherches Internationales Servier, Courbevoie, France. Authors affiliated with Hôpital Paul Brousse, France; Institut de Recherches Internationales Servier, France; Technologie Servier, France.)
388 Liang G, Schernhammer E, Qi L, Gao X, De Vivo I, Han J. 2011. Associations between rotating night shifts, sleep duration, and telomere length in women. PLoS One 6(8): e23462. (Supported by NIH. Authors affiliated with Harvard Medical School, MA; Southeast University, China; Brigham and Women’s Hospital, MA; Harvard School of Public Health, MA; LBI-ACR, ACR-ITR, VIEnna/CEADDP, Austria.)21853136
389 Lie JA, Kjuus H, Zienolddiny S, Haugen A, Kjærheim K. 2013. Breast cancer among nurses: is the intensity of night work related to hormone receptor status? Am J Epidemiol 178(1): 110–117. (Supported by the Research Council of Norway, the South-Eastern Norway Regional Health Authority, the Norwegian Cancer Society, and the “Raagholtstiftelsen” foundation. Authors affiliated with National Institute of Occupational Health, Norway; Cancer Registry of Norway, Norway.)23788666
390 Lie JA, Kjuus H, Zienolddiny S, Haugen A, Stevens RG, Kjærheim K. 2011. Night work and breast cancer risk among Norwegian nurses: assessment by different exposure metrics. Am J Epidemiol 173(11): 1272–1279. (Supported by the Research Council of Norway, the South-Eastern Norway Regional Health Authority, and the Norwegian Cancer Society. Authors affiliated with National Institute of Occupational Health, Norway; University of Connecticut Health Center, CT; Cancer Registry of Norway, Norway.)21454824
391 Lighting Research Center (2018). Estimated corneal illuminance data provided by the Lighting Research Center, Rensselaer Polytechnic Institute (Troy, NY) (personal correspondence, 1/4/18, Mariana Figuiero).
392 Lin X, Chen W, Wei F, Ying M, Wei W, Xie X. 2015. Night-shift work increases morbidity of breast cancer and all-cause mortality: a meta-analysis of 16 prospective cohort studies. Sleep Med 16(11): 1381–1387. (Support not reported. Authors affiliated with Sun Yat-sen University, China; Teaching Hospital of Fujian Medical University, China; Fujian University of Traditional Chinese Medicine, China.)26498240
393 Lin Y, Ueda J, Yagyu K, Kurosawa M, Tamakoshi A, Kikuchi S. 2013. A prospective cohort study of shift work and the risk of death from pancreatic cancer in Japanese men. Cancer Causes Control 24(7): 1357–1361. (Supported by the Ministry of Education, Science, Sports and Culture of Japan, and the Japanese Ministry of Education, Culture, Sports, Science and Technology of Japan. Authors affiliated with Aichi Medical University School of Medicine, Japan; Juntendo University School of Medicine, Japan; Hokkaido University Graduate School of Medicine, Japan.)23619608
394 Linnersjö A, Hammar N, Dammström BG, Johansson M, Eliasch H. 2003. Cancer incidence in airline cabin crew: experience from Sweden. Occup Environ Med 60(11): 810–814. (Supported by the Swedish Council for Work Life Research. Authors affiliated with Stockholm Center of Public Health, Sweden; Swedish SAS, Sweden; Swedish Air Force, Sweden.)14573710
395 Liu R, Jacobs DI, Hansen J, Fu A, Stevens RG, Zhu Y. 2015. Aberrant methylation of miR-34b is associated with long-term shiftwork: a potential mechanism for increased breast cancer susceptibility. Cancer Causes Control 26(2): 171–178. (Supported by NIH, the China Scholarship Council and the Danish Cancer Society. Authors affiliated with Yale School of Public Health, CT; Southeast University, China; Danish Cancer Society, Denmark.)25398683
396 Lizama N, Heyworth J, Thomson A, Slevin T, Fritschi L. 2017. Self-reported shift work, recall bias, and belief about disease causation in a case-control study of breast cancer. Cancer Epidemiol 50(Pt A): 9–15. (Supported by the National Health and Medical Research Council Australia and the Cancer Council Western Australia. Authors affiliated with University of Western Australia, Australia; Curtin University, Australia; Cancer Council Western Australia, Australia.)28756308
397 Lockley SW, Brainard GC, Czeisler CA. 2003. High sensitivity of the human circadian melatonin rhythm to resetting by short wavelength light. J Clin Endocrinol Metab 88(9): 4502–4505. (Supported by NINDS, NIMH, NCRR, and the Wellcome Trust, UK. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Thomas Jefferson University, PA.)12970330
398 Lockley SW, Skene DJ, Arendt J, Tabandeh H, Bird AC, Defrance R. 1997. Relationship between melatonin rhythms and visual loss in the blind. J Clin Endocrinol Metab 82(11): 3763–3770. (Supported by the South Thames Regional Health Authority, United Kingdom, Stockgrand Ltd., University of Surrey, United Kingdom, and Servier Research and Development, France. Authors affiliated with University of Surrey, UK; Moorfields Eye Hospital, UK; Institut de Recherches Internationales Servier, France.)9360538
399 Logan RW, Zhang C, Murugan S, O’Connell S, Levitt D, Rosenwasser AM, Sarkar DK. 2012. Chronic shift-lag alters the circadian clock of NK cells and promotes lung cancer growth in rats. J Immunol 188(6): 2583–2591. (Supported by NIH. Authors affiliated with State University of New Jersey, NJ; University of Maine, ME.)22308312
400 Lowrey PL, Takahashi JS. 2004. Mammalian circadian biology: elucidating genome-wide levels of temporal organization. Annu Rev Genomics Hum Genet 5: 407–441. (Support not reported. Authors affiliated with Northwestern University, IL.)15485355
401 Lowrey PL, Takahashi JS. 2011. Genetics of circadian rhythms in mammalian model organisms. Adv Genet 74: 175–230. (Supported by NIH. Authors affiliated with Rider University, NJ; University of Texas Southwestern Medical Center, TX.)21924978
402 Lu C, Sun H, Huang J, Yin S, Hou W, Zhang J, Wang Y, Xu Y, Xu H. 2017. Long-term sleep duration as a risk factor for breast cancer: Evidence from a systematic review and dose-response meta-analysis. Biomed Res Int 2017: 4845059. (Supported by the National Natural Science Foundation of China and Key Laboratory Programme of Education Department of Liaoning Province. Authors affiliated with First Hospital of China Medical University, China.)29130041
403 Lu LF, Wang CP, Tsai IT, Hung WC, Yu TH, Wu CC, Hsu CC, Lu YC, Chung FM, Jean MC. 2016. Relationship between shift work and peripheral total and differential leukocyte counts in Chinese steel workers. J Occup Health 58(1): 81–88. (Supported by the E-Da Hospital, Kaohsiung City, Taiwan. Authors affiliated with I-Shou University, Taiwan.)26549833
404 Lucas RJ, Peirson SN, Berson DM, Brown TM, Cooper HM, Czeisler CA, Figueiro MG, Gamlin PD, Lockley SW, O’Hagan JB, Price LL, Provencio I, Skene DJ, Brainard GC. 2014. Measuring and using light in the melanopsin age. Trends Neurosci 37(1): 1–9. (Supported by ZVEI [German Electrical and Electronic Manufacturer’s Association]. Authors affiliated with University of Manchester, UK; University of Oxford, UK; Brown University, RI; INSERM, France; Harvard Medical School, MA; Rensselaer Polytechnic Institute, NY; University of Alabama at Birmingham, AL; Public Health England, UK; University of Virginia, VA; University of Surrey, UK; Thomas Jefferson University, PA.)24287308
405 Luckhaupt SE, Sestito JP. 2013. Examining national trends in worker health with the National Health Interview Survey. J Occup Environ Med 55(12 Suppl): S58–62. (Supported by the US government. Authors affiliated with NIOSH, OH.)24284753
406 Lunn RM, Blask DE, Coogan AN, Figueiro MG, Gorman MR, Hall JE, Hansen J, Nelson RJ, Panda S, Smolensky MH, Stevens RG, Turek FW, Vermeulen R, Carreón T, Caruso CC, Lawson CC, Thayer KA, Twery MJ, Ewens AD, Garner SC, Schwingl PJ, Boyd WA. 2017. Health consequences of electric lighting practices in the modern world: A report on the National Toxicology Program’s workshop on shift work at night, artificial light at night, and circadian disruption. Sci Total Environ 607–608: 1073–1084. (No financial support recieved. Authors affiliated with NIEHS, NC; Tulane University School of Medicine, LA; National University of Ireland, Ireland; Rensselaer Polytechnic Institute, NY; University of California San Diego, CA; Danish Cancer Society, Denmark; Ohio State University Wexner Medical Center, OH; Salk Institute for Biological Studies, CA; University of Texas at Austin, TX; University of Texas-Houston McGovern School of Medicine, TX; University of Connecticut, CT; Northwestern University, IL; Utrecht University, Netherlands; NIOSH, OH; NHLBI, MD; Integrated Laboratory Systems, NC.)
407 Maeda SS, Kunii IS, Hayashi L, Lazaretti-Castro M. 2007. The effect of sun exposure on 25-hydroxyvitamin D concentrations in young healthy subjects living in the city of São Paulo, Brazil. Braz J Med Biol Res 40(12): 1653–1659. (Supported by FAPESP. Authors affiliated with Universidade Federal de São Paulo, Brazil.)17713647
408 Malone SK, Zemel B, Compher C, Souders M, Chittams J, Thompson AL, Lipman TH. 2016. Characteristics associated with sleep duration, chronotype, and social jet lag in adolescents. J Sch Nurs 32(2): 120–131. (Supported by the National Association of School Nurses, National Institute of Nursing Research Ruth L. Kirschstein National Research Service Award, The Rockefeller University Heilbrunn Nurse Scholar Award, University of Pennsylvania School of Nursing Biobehavioral Research Center, and University of Pennsylvania Office of Nursing Research. Authors affiliated with University of Pennsylvania School of Nursing, PA: University of Pennsylvania, PA; Children’s Hospital of Philadelphia, PA.)26376832
409 Mancio J, Leal C, Ferreira M, Norton P, Lunet N. 2018. Does the association of prostate cancer with night-shift work differ according to rotating vs. fixed schedule? A systematic review and meta-analysis. Prostate Cancer Prostatic Dis(21): 337–344. (Supported by the Fundação Portuguesa para a Ciência e Tecnologia and by the Sociedade Portuguesa de Cardiologia [“Bolsa de investigação João Porto”]. Authors affiliated with University of Porto, Portugal; Centro Hospitalar de Vila Nova de Gaia, Portugal.)
410 Manenschijn L, van Kruysbergen RG, de Jong FH, Koper JW, van Rossum EF. 2011. Shift work at young age is associated with elevated long-term cortisol levels and body mass index. J Clin Endocrinol Metab 96(11): E1862–1865. (Supported by the Netherlands Organization for Scientific Research. Authors affiliated with Erasmus Medical Center, Netherlands; Arbo Unie Nijverdal, Netherlands.)21880805
411 Manzella N, Bracci M, Strafella E, Staffolani S, Ciarapica V, Copertaro A, Rapisarda V, Ledda C, Amati M, Valentino M, Tomasetti M, Stevens RG, Santarelli L. 2015. Circadian modulation of 8-oxoguanine DNA damage repair. Scientific Rep 5: 12. (Supported by the Italian Institute of Insurance against Professional Illness and Injuries. Authors affiliated with Polytechnic University of Marche, Italy; Loreto Hospital, Italy; University of Catania, Italy; University of Connecticut Health Center, CT.)
412 Mao L, Dauchy RT, Blask DE, Dauchy EM, Slakey LM, Brimer S, Yuan L, Xiang S, Hauch A, Smith K, Frasch T, Belancio VP, Wren MA, Hill SM. 2016a. Melatonin suppression of aerobic glycolysis (Warburg effect), survival signalling and metastasis in human leiomyosarcoma. J Pineal Res 60(2): 167–177. (Support not reported. Authors affiliated with Tulane University School of Medicine, LA; Tulane Cancer Center, LA; Louisiana Cancer Research Consortium, LA.)26607298
413 Mao L, Dauchy RT, Blask DE, Slakey LM, Xiang S, Yuan L, Dauchy EM, Shan B, Brainard GC, Hanifin JP, Frasch T, Duplessis TT, Hill SM. 2012. Circadian gating of epithelial-to-mesenchymal transition in breast cancer cells via melatonin-regulation of GSK3beta. Mol Endocrinol 26(11): 1808–1820. (Supported by NIH, the Army Department of Defense, the American Association for Laboratory Animal Science, and the Institute for Integrative Health. Authors affiliated with Tulane University School of Medicine, LA; Thomas Jefferson University, PA.)23002080
414 Mao L, Summers W, Xiang S, Yuan L, Dauchy RT, Reynolds A, Wren-Dail MA, Pointer D, Frasch T, Blask DE, Hill SM. 2016b. Melatonin represses metastasis in her2-postive human breast cancer cells by suppressing RSK2 expression. Mol Cancer Res 14(11): 1159–1169. (Supported by NIH, NCI, the Edmond and Lily Safra Chair for Breast Cancer Research, and the Tulane Center for Circadian Biology. Authors affiliated with Tulane University School of Medicine, LA: Tulane Cancer Center and Louisiana Cancer Research Consortium, LA.)27535706
415 Marinac CR, Natarajan L, Sears DD, Gallo LC, Hartman SJ, Arredondo E, Patterson RE. 2015a. Prolonged nightly fasting and breast cancer risk: Findings from NHANES (2009-2010). Cancer Epidemiol Biomarkers Prev 24(5): 783–789. (Supported by NCI and Ms. Carol Vassiliadis and her family. Authors affiliated with University of California - San Diego, CA; San Diego State University, CA.)25896523
416 Marinac CR, Nelson SH, Breen CI, Hartman SJ, Natarajan L, Pierce JP, Flatt SW, Sears DD, Patterson RE. 2016. Prolonged nightly fasting and breast cancer prognosis. JAMA Oncol 2(8): 1049–1055. (Supported by NCI and NIH. Authors affiliated with University of California - San Diego, CA; San Diego State University, CA.)27032109
417 Marinac CR, Sears DD, Natarajan L, Gallo LC, Breen CI, Patterson RE. 2015b. Frequency and circadian timing of eating may influence biomarkers of inflammation and insulin resistance associated with breast cancer risk. PLoS One 10(8): e0136240. (Supported by NCI. Authors affiliated with University of California San Diego, CA; San Diego State University, CA.)26305095
418 Markt SC, Valdimarsdottir UA, Shui IM, Sigurdardottir LG, Rider JR, Tamimi RM, Batista JL, Haneuse S, Flynn-Evans E, Lockley SW, Czeisler CA, Stampfer MJ, Launer L, Harris T, Smith AV, Gudnason V, Lindstrom S, Kraft P, Mucci LA. 2015. Circadian clock genes and risk of fatal prostate cancer. Cancer Causes Control 26(1): 25–33. (Supported by the National Institutes on Aging Intramural Research Program, the Hjartavernd [the Icelandic Heart Association], the Althingi [the Icelandic Parliament], the Harvard Catalyst Award, the Icelandic Cancer Society, the National Cancer Institute at the National Institutes of Health, the National Heart, Lung, and Blood Institute at the National Institutes of Health, the Prostate Cancer Foundation, and the US Army Department of Defense Prostate Cancer Research Program Fellowship. Authors affiliated with Harvard School of Public Health, MA: University of Iceland, Iceland; Icelandic Cancer Society, Iceland; Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Icelandic Heart Association, Iceland; National Institute on Aging, MD.)25388799
419 Masri S, Kinouchi K, Sassone-Corsi P. 2015. Circadian clocks, epigenetics, and cancer. Curr Opin Oncol 27(1): 50–56. (Supported by NIH, INSERM, KAUST, Merieux Pharmaceuticals, the UC Irvine Chao Family Cancer Center, and JSPS. Authors affiliated with University of California - Irvine, CA.)25405464
420 Matulka R, Wood D. 2013. The History of the Light Bulb. Energy.gov. Updated on: 11/22/13. https://energy.gov/articles/history-light-bulb
421 Mavroudis PD, Scheff JD, Calvano SE, Lowry SF, Androulakis IP. 2012. Entrainment of peripheral clock genes by cortisol. Physiol Genomics 44(11): 607–621. (Supported by the NIGMS. Authors affiliated with Rutgers University, NJ; UMDNJ-Robert Wood Johnson Medical School, NJ.)22510707
422 Mazzoccoli G, Vinciguerra M, Papa G, Piepoli A. 2014. Circadian clock circuitry in colorectal cancer. World J Gastroenterol 20(15): 4197–4207. (Supported by the “5x1000” voluntary contribution, the Italian Ministry of Health through Department of Medical Sciences, Division of Internal Medicine and Chronobiology Unit, IRCCS Scientific Institute and Regional General Hospital “Casa Sollievo della Sofferenza”, Opera di Padre Pio da Pietrelcina, San Giovanni Rotondo [FG], Italy, and AIRC. Authors affiliated with IRCCS Scientific Institute and Regional General Hospital “Casa Sollievo della Sofferenza”, Italy; IEMEST, Italy; University of Chieti, Italy.)24764658
423 McBean AL, Montgomery-Downs HE. 2015. What are postpartum women doing while the rest of the world is asleep? J Sleep Res 24(3): 270–278. (Support not reported. Authors affiliated with West Virginia University, WV.)25431167
424 McCorry LK. 2007. Physiology of the autonomic nervous system. Am J Pharm Educ 71(4): 78. (Support not reported. Authors affiliated with Bay State College, MA.)17786266
425 McElroy JA, Newcomb PA, Titus-Ernstoff L, Trentham-Dietz A, Hampton JM, Egan KM. 2006. Duration of sleep and breast cancer risk in a large population-based case-control study. J Sleep Res 15(3): 241–249. (Supported by NIH. Authors affiliated with University of Wisconsin, WI; Fred Hutchinson Cancer Research Center, WA; Dartmouth Medical School, NH; Vanderbilt University, TN; Vanderbilt-Ingram Cancer Center, TN.)16911025
426 McMahon DM, Burch JB, Wirth MD, Youngstedt SD, Hardin JW, Hurley TG, Blair SN, Hand GA, Shook RP, Drenowatz C, Burgess S, Hebert JR. 2018. Persistence of social jetlag and sleep disruption in healthy young adults. Chronobiol Int 35(3): 312–328. (Supported by the Dept. of Veterans Affairs Office of Research and Development, NCI, the National Institute of Diabetes and Digestive and Kidney Diseases, BodyMedia, Technogym, the U.S. Department of Defense, and the Coca-Cola Company. Authors affiliated with University of South Carolina, SC; WJB Dorn Department of Veterans Affairs Medical Center, SC; Arizona State University, AZ; Phoenix VA Health Care System, AZ; West Virginia University, WV; Children’s Mercy Hospital, MO; University of Education Upper Austria, Austria.)29231745
427 McMenamin T. 2007. A time to work: recent trends in shift work and flexible schedules. Mon Labor Rev December: 3–15. (Support not reported. Author affiliated with Bureau of Labor Statistics.)
428 Mediavilla MD, Sanchez-Barcelo EJ, Tan DX, Manchester L, Reiter RJ. 2010. Basic mechanisms involved in the anti-cancer effects of melatonin. Curr Med Chem 17(36): 4462–4481. (Supported by the Spanish Ministry of Science and Education. Authors affiliated with University of Cantabria, Spain; University of Texas Health Science Centre, TX.)21062257
429 Mehra A, Baker CL, Loros JJ, Dunlap JC. 2009. Post-translational modifications in circadian rhythms. Trends Biochem Sci 34(10): 483–490. (Supported by NIH and a CIHR Postdoc Fellowship. Authors affiliated with Dartmouth Medical School, NH.)19740663
430 Mendoza J, Pévet P, Challet E. 2008. High-fat feeding alters the clock synchronization to light. J Physiol 586(24): 5901–5910. (Supported by CNRS, University Louis Pasteur, Fondation pour la Recherche Médicale, and the Institut Servier. Authors affiliated with Université Louis Pasteur, France.)18936083
431 Menegaux F, Truong T, Anger A, Cordina-Duverger E, Lamkarkach F, Arveux P, Kerbrat P, Févotte J, Guénel P. 2013. Night work and breast cancer: a population-based case-control study in France (the CECILE study). Int J Cancer 132(4): 924–931. (Supported by the Agence Nationale de sécurité sanitaire de l’alimentation, de l’environnement et du travail [ANSES], the Agence Nationale de la Recherche [ANR], the Fondation de France, the Institut National du Cancer [INCA]; Ligue contre le Cancer Grand Ouest, and the Association pour le recherche contre le cancer [ARC]. Authors affiliated with INSERM, France; Univ Paris-Sud, France; Center Georges-François Leclerc, France; Center Eugène Marquis, France; Institut de Veille Sanitaire [InVS], France.)22689255
432 Mhatre MC, Shah PN, Juneja HS. 1984. Effect of varying photoperiods on mammary morphology, DNA synthesis, and hormone profile in female rats. J Natl Cancer Inst 72(6): 1411–1416. (Support not reported. Authors affiliated with Cancer Research Institute, India; Institute for Research in Reproduction, India.)6427503
433 Miller D, Bierman A, Figueiro M, Schernhammer E, Rea M. 2010. Ecological measurements of light exposure, activity, and circadian disruption. Light Res Technol 42(3): 271–284. (Supported by the CDC and the Trans-NIH Genes, Environment and Health Initiative. Authors affiliated with Rensselaer Polytechnic Institute, NY; Brigham and Women’s Hospital, MA; Harvard Medical School, MA.)23504497
434 Miller NJ, Kinzey BR. 2018. Home Nighttime Light Exposures: How Much Are We Really Getting? International Association of Lighting Designers. Last accessed: 6/11/18. https://www.iald.org/News/In-the-News/Home-Nighttime-Light-Exposures-How-Much-Are-We-Re
435 Mirick DK, Bhatti P, Chen C, Nordt F, Stanczyk FZ, Davis S. 2013. Night shift work and levels of 6-sulfatoxymelatonin and cortisol in men. Cancer Epidemiol Biomarkers Prev 22(6): 1079–1087. (Support not reported. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Washington, WA; Rhein Consulting Laboratories, OR; University of Southern California, CA.)23563887
436 Mirick DK, Davis S. 2008. Melatonin as a biomarker of circadian dysregulation. Cancer Epidemiol Biomarkers Prev 17(12): 3306–3313. (Support not reported. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Washington, WA.)19064543
437 Mohawk JA, Green CB, Takahashi JS. 2012. Central and peripheral circadian clocks in mammals. Annu Rev Neurosci 35: 445–462. (Support not reported. Authors affiliated with University of Texas Southwestern Medical Center, TX.)22483041
438 Monk TH, Buysse DJ, Billy BD, Fletcher ME, Kennedy KS, Begley AE, Schlarb JE, Beach SR. 2013. Shiftworkers report worse sleep than day workers, even in retirement. J Sleep Res 22(2): 201–208. (Supported by the National Institute on Aging. Authors affiliated with University of Pittsburgh Medical Center, PA; University of Pittsburgh, PA.)23136831
439 Monsees GM, Kraft P, Hankinson SE, Hunter DJ, Schernhammer ES. 2012. Circadian genes and breast cancer susceptibility in rotating shift workers. Int J Cancer 131(11): 2547–2552. (Supported by NIH, the Broad Institute Center for Genotyping and Analysis, the National Center for Research Resources, the Public Health Service, and NCI. Authors affiliated with Harvard School of Public Health, MA; Brigham and Women’s Hospital, MA; Fred Hutchinson Cancer Research Center, WA; University of Washington, WA; LBI-ACR and ACR-ITR VIEnna/CEADDP, Austria.)22473669
440 Mormont MC, Waterhouse J, Bleuzen P, Giacchetti S, Jami A, Bogdan A, Lellouch J, Misset JL, Touitou Y, Lévi F. 2000. Marked 24-h rest/activity rhythms are associated with better quality of life, better response, and longer survival in patients with metastatic colorectal cancer and good performance status. Clin Cancer Res 6(8): 3038–3045. (Supported by CNAMTS INSERM, ARTBC Internationale, Compagnie de Développement Aguettant, and Université Paris XI-Debiopharm. Authors affiliated with Université Paris XI and I.C.I.G., France; Hopital Paul Brousse, France; Liverpool John Moores University, UK; Hopital de la Pitié-Salpêtrière, France.)10955782
441 Mteyrek A, Filipski E, Guettier C, Oklejewicz M, van der Horst GT, Okyar A, Lévi F. 2017. Critical cholangiocarcinogenesis control by cryptochrome clock genes. Int J Cancer 140(11): 2473–2483. (Supported by ERASySBio+ and FP7, and the Association pour la Recherche sur le Temps Biologique et la Chronotherapie [ARTBC International, Hospital Paul Brousse, Villejuif, France]. Authors affiliated with INSERM, France; Paris Sud University, France; Hôpital Paul Brousse, France; Erasmus University Medical Center, Netherlands; Istanbul University Faculty of Pharmacy, Turkey; Warwick Medical School, UK.)28224616
442 Mteyrek A, Filipski E, Guettier C, Okyar A, Lévi F. 2016. Clock gene Per2 as a controller of liver carcinogenesis. Oncotarget 7(52): 85832–85847. (Supported by ERASySBio+ and FP7 to the C5Sys project, the Association pour la Recherche sur le Temps Biologique et la Chronothérapie [ARTBC International, Paul Brousse hospital, Villejuif, France] and Cancer Research UK. Authors affiliated with INSERM, France; Paris Sud University, France; Hôpital Paul Brousse, France; Istanbul University Faculty of Pharmacy, Turkey; Warwick Medical School, UK.)27494874
443 Muhammad DH, Qadir FA. 2017. Effects of night shift working on some immunological, prostate specific antigen, cortisol level and malondialdehyde in male nurses at Hawler City. AIP Conf Proc 1888(020035). (Support not reported. Authors affiliated with Ministry of Education, Iraq; Salahaddin University-Erbil, Iraq.)
444 Mullenders J, Fabius AW, Madiredjo M, Bernards R, Beijersbergen RL. 2009. A large scale shRNA barcode screen identifies the circadian clock component ARNTL as putative regulator of the p53 tumor suppressor pathway. PLoS One 4(3): e4798. (Supported by the Dutch Cancer Society and the EU 6th framework program TRANSFOG. Authors affiliated with Netherlands Cancer Institute, Netherlands.)19277210
445 Mure LS, Le HD, Benegiamo G, Chang MW, Rios L, Jillani N, Ngotho M, Kariuki T, Dkhissi-Benyahya O, Cooper HM, Panda S. 2018. Diurnal transcriptome atlas of a primate across major neural and peripheral tissues. Science 359(6381). (Supported by the Salk Institute Innovation, U.S. Department of Defense, NIH, NCI, the Chapman Foundation, the Helmsley Charitable Trust, the Glenn Center for Aging Research, and the Fyssen and Catharina Foundations. Authors affiliated with Salk Institute for Biological Studies, CA; University of California - San Diego, CA; National Museums of Kenya, Kenya; Université Lyon, France.)
446 Nagai M, Morikawa Y, Kitaoka K, Nakamura K, Sakurai M, Nishijo M, Hamazaki Y, Maruzeni S, Nakagawa H. 2011. Effects of fatigue on immune function in nurses performing shift work. J Occup Health 53(5): 312–319. (Supported by the Ministry of Education, Culture, Sports, Science, and Technology of Japan. Authors affiliated with Kanazawa Medical University, Japan.)21778660
447 Nagare R, Plitnick B, Figueiro M. 2018. Effect of exposure duration and light spectra on nighttime melatonin suppression in adolescents and adults. Lighting Res Technol. (Supported by the Lighting Research Center’s Light and Health Alliance [Acuity Brands, CREE, Current by GE, Ketra, OSRAM, Philips and USAI Lighting]. Authors affiliated with Rensselaer Polytechnic Institute, NY.)
448 Nagashima S, Osawa M, Matsuyama H, Ohoka W, Ahn A, Wakamura T. 2018. Bright-light exposure during daytime sleeping affects nocturnal melatonin secretion after simulated night work. Chronobiol Int 35(2): 229–239. (Supported by JSPS KAKENHI. Authors affiliated with Kyoto University, Japan; Japan Society for the Promotion of Science, Japan.)29144169
449 Nagata C, Nagao Y, Yamamoto S, Shibuya C, Kashiki Y, Shimizu H. 2008. Light exposure at night, urinary 6-sulfatoxymelatonin, and serum estrogens and androgens in postmenopausal Japanese women. Cancer Epidemiol Biomarkers Prev 17(6): 1418–1423. (Supported by the Ministry of Education, Culture, Sports, Science, and Technology, Japan. Authors affiliated with Gifu University Graduate School of Medicine, Japan; Gihoku General Hospital, Japan.)18559557
450 Nagata C, Tamura T, Wada K, Konishi K, Goto Y, Nagao Y, Ishihara K, Yamamoto S. 2017. Sleep duration, nightshift work, and the timing of meals and urinary levels of 8-isoprostane and 6-sulfatoxymelatonin in Japanese women. Chronobiol Int 34(9): 1187–1196. (Supported by the Ministry of Education, Science, Sports, Culture and Technology of Japan. Authors affiliated with Gifu University Graduate School of Medicine, Japan; Gihoku Kousei Hospital, Japan.)28933565
451 Nakahata Y, Kaluzova M, Grimaldi B, Sahar S, Hirayama J, Chen D, Guarente LP, Sassone-Corsi P. 2008. The NAD^+^-dependent deacetylase SIRT1 modulates CLOCK-mediated chromatin remodeling and circadian control. Cell 134(2): 329–340. (Supported by the Cancer Research Coordinating Committee of the University of California and NIH. Authors affiliated with University of California - Irvine, CA; Massachusetts Institute of Technology, MA.)18662547
452 Nakajima H, Narama I, Matsuura T, Nomura T. 1994. Enhancement of tumor growth under short light/dark cycle in mouse lung. Cancer Lett 78(1–3): 127–131. (Supported by the Osaka Cancer Research Fund. Authors affiliated with Osaka University, Japan; Setsunan University, Japan.)8068089
453 Nakano Y, Miura T, Hara I, Aono H, Miyano N, Miyajima K, Tabuchi T, Kosaka H. 1982. The effect of shift work on cellular immune function. J Hum Ergol (Tokyo) 11 Suppl: 131–137. (Support not reported. Authors affiliated with Osaka Prefectural Institute of Public Health, Japan.)6985367
454 NASA. 2018. Gateway to Astronaut Photography of Earth. National Aeronautics and Space Administration. Last accessed: 8/14/18. https://eol.jsc.nasa.gov/
455 Navara KJ, Nelson RJ. 2007. The dark side of light at night: physiological, epidemiological, and ecological consequences. J Pineal Res 43(3): 215–224. (Supported by NIH, NSF, and NRSA. Authors affiliated with Ohio State University, OH.)17803517
456 Neil-Sztramko SE, Gotay CC, Demers PA, Campbell KL. 2016. Physical activity, physical fitness, and body composition of Canadian shift workers: Data from the Canadian Health Measures Survey cycles 1 and 2. J Occup Environ Med 58(1): 94–100. (Supported by the Canadian Institutes of Health Research and the Canadian Cancer Research Institute. Authors affiliated with University of British Columbia, Canada; British Columbia Cancer Research Centre, Canada; Cancer Care Ontario, Canada; University of Toronto, Canada.)26716853
457 Neil-Sztramko SE, Pahwa M, Demers PA, Gotay CC. 2014. Health-related interventions among night shift workers: a critical review of the literature. Scand J Work Environ Health 40(6): 543–556. (Supported by the Canadian Cancer Society Research Institute, the Canadian Institute for Health Research, the Canadian Cancer Society British Columbia-Yukon, and the Workplace Safety and Insurance Board of Ontario. Authors affiliated with University of British Columbia, Canada; Cancer Care Ontario, Canada; University of Toronto, Canada; BC Cancer Research Centre, Canada.)24980289
458 Nelson RJ, Blom JM. 1994. Photoperiodic effects on tumor development and immune function. J Biol Rhythms 9(3–4): 233–249. (Supported by the National Institute of Child and Human Development, NCI, and Mr. Ted C. Hanf. Authors affiliated with Johns Hopkins University, MD.)7772792
459 Nesbitt AD, Leschziner GD, Peatfield RC. 2014. Headache, drugs and sleep. Cephalalgia 34(10): 756–766. (Supported by the Patrick Berthoud Charitable Trust. Authors affiliated with King’s College London, UK; University of Surrey, UK; Guy’s and St Thomas’ NHS Foundation Trust, UK; Imperial College Healthcare NHS Foundation Trust, UK.)25053748
460 Nesthus T, Cruz C, Boquet A, Detwiler C, Holcomb K, Della Rocco P. 2001. Circadian temperature rhythms in clockwise and counter-clockwise rapidly rotating shift schedules. J Hum Ergol (Tokyo) 30(1–2): 245–249. (Support not reported. Authors affiliated with Federal Aviation Administration Civil Aerospace Medical Institute, OK.)14564890
461 Nishitani N, Sakakibara H. 2007. Subjective poor sleep and white blood cell count in male Japanese workers. Ind Health 45(2): 296–300. (Support not reported. Authors affiliated with Nagoya University Graduate School of Medicine, Japan.)17485874
462 Niu SF, Chung MH, Chu H, Tsai JC, Lin CC, Liao YM, Ou KL, O’Brien AP, Chou KR. 2015. Differences in cortisol profiles and circadian adjustment time between nurses working night shifts and regular day shifts: A prospective longitudinal study. Int J Nurs Stud 52(7): 1193–1201. (No funding received. Authors affiliated with Shin Kong Wu Ho-Su Memorial Hospital, Taiwan; Taipei Medical University, Taiwan; Taipei Medical University-Shuang Ho Hospital, Taiwan; Tri-Service General Hospital, Taiwan; National Defense Medical Center, Taiwan; Centre for Practice Opportunity and Development, Australia; Fu Jen Catholic University, Taiwan; University of Newcastle, Australia.)25900684
463 NOAA. 2015. Defense Meteorological Satellite Program (DMSP). NOAA, National Centers for Environmental Information. Last accessed: 1/8/18. https://ngdc.noaa.gov/eog/dmsp.html
464 NOAO. 2015. Recommended Light Levels (Illuminance) for Outdoor and Indoor Venues. National Optical Astronomy Observatory. Last accessed: 5/31/18. https://www.noao.edu/education/QLTkit/ACTIVITY_Documents/Safety/LightLevels_outdoor+indoor.pdf
465 NOAO. 2018. Types of Light. National Optical Astronomy Observatory. 6 pp. https://www.noao.edu/education/QLTkit/ACTIVITY_Documents/Energy/Types_of_Lights.pdf.
466 Nobel Prize. 2017. Press Release on The Nobel Prize in Physiology or Medicine 2017. Last updated: 10/2/17. https://www.nobelprize.org/nobel_prizes/medicine/laureates/2017/press.html
467 Nogueira LM, Sampson JN, Chu LW, Yu K, Andriole G, Church T, Stanczyk FZ, Koshiol J, Hsing AW. 2013. Individual variations in serum melatonin levels through time: Implications for epidemiologic studies. Plos One 8(12): e83208. (Supported by NCI, NIH. Authors affiliated with NCI, MD; Cancer Prevention Institute of California, CA; Washington University School of Medicine, MO; University of Minnesota School of Public Health, MN; University of Southern California Los Angeles, CA.)24376664
468 NTP. 2015. Handbook for Preparing Report on Carcinogens Monographs. Research Triangle Park, NC: National Toxicology Program. 89 pp. https://ntp.niehs.nih.gov/ntp/roc/handbook/roc_handbook_508.pdf.
469 NTP. 2016. Workshop: Shift Work at Night, Artificial Light at Night, and Circadian Disruption. National Toxicology Program. Updated on 7/27/16. http://ntp.niehs.nih.gov/pubhealth/roc/candidates/meetings/workshop_alan.html
470 NTP. 2018. Night Shift Work and Light at Night (LAN): Human cancer studies Research Triangle Park, NC: National Toxicology Program. 46 pp. https://ntp.niehs.nih.gov/ntp/roc/protocols/electric-light_508.pdf.
471 NTP. 2019a. All Past Events: Peer Review of the Draft Report on Carcinogens Monograph on Night Shift Work and Light at Night, October 5, 2018. National Toxicology Program. Last updated: 4/30/19. https://ntp.niehs.nih.gov/go/meeting
472 NTP. 2019b. Report on Carcinogens Process & Listing Criteria. National Toxicology Program. Last updated: 8/16/19. https://ntp.niehs.nih.gov/go/rocprocess
473 O’Brien KM, Sandler DP, Taylor JA, Weinberg CR. 2017. Serum vitamin D and risk of breast cancer within five years. Environ Health Perspect 125(7): 077004. (Supported by the Office of Dietary Supplement Research Scholars Program, NIH, and NIEHS. Authors affiliated with NIH, NC.)28728134
474 O’Leary ES, Schoenfeld ER, Stevens RG, Kabat GC, Henderson K, Grimson R, Gammon MD, Leske MC, for the Electromagnetic Fields Breast Cancer on Long Island Study Group. 2006. Shift work, light at night, and breast cancer on Long Island, New York. Am J Epidemiol 164(4): 358–366. (Supported by NCI and NIEHS. Authors affiliated with Stony Brook University, NY; University of Connecticut Health Center, CT; University of North Carolina at Chapel Hill, NC.)16777931
475 Ogura-Ochi K, Fujisawa S, Iwata N, Komatsubara M, Nishiyama Y, Tsukamoto-Yamauchi N, Inagaki K, Wada J, Otsuka F. 2017. Regulatory role of melatonin and BMP-4 in prolactin production by rat pituitary lactotrope GH3 cells. Peptides 94: 19–24. (Supported by the Grants-in-Aid for Scientific Research, Foundation for Growth Science and Astellas Foundation for Research on Metabolic Disorders, Japan Foundation for Applied Enzymology [Japan], and The Uehara Memorial Foundation. Authors affiliated with Department of Medicine and Clinical Science, Japan; Okayama University Graduate School of Medicine, Japan.)28627372
476 Oh JH, Yoo H, Park HK, Do YR. 2015. Analysis of circadian properties and healthy levels of blue light from smartphones at night. Sci Rep 5: 11325. (Supported by the National Research Foundation [NRF] of Korea and the Korean government. Authors affiliated with Kookmin University, Korea.)26085126
477 Okamoto H, Tsunoda T, Teruya K, Takeda N, Uemura T, Matsui T, Fukazawa S, Ichikawa K, Takemae R, Tsuchida K, Takashima Y. 2008. An occupational health study of emergency physicians in Japan: health assessment by immune variables (CD4, CD8, CD56, and NK cell activity) at the beginning of work. J Occup Health 50(2): 136–146. (Supported by the Pfizer Health Research Foundation. Authors affiliated with Kyorin University, Japan.)18403864
478 Otálora BB, Madrid JA, Alvarez N, Vicente V, Rol MA. 2008. Effects of exogenous melatonin and circadian synchronization on tumor progression in melanoma-bearing C57BL6 mice. J Pineal Res 44(3): 307–315. (Supported by the Ministry of Science and Technology, and the Instituto de Salud Carlos III. Authors affiliated with University of Murcia, Spain.)18339126
479 Pahwa M, Labrèche F, Demers PA. 2018. Night shift work and breast cancer risk: what do the meta-analyses tell us? Scand J Work Environ Health 44(4): 432–435. (Supported by the Canadian Cancer Society, Ontario Ministry of Labor, and Cancer Care Ontario. Authors affiliated with Cancer Care Ontario, Canada; Institut de recherche Robert-Sauvé en santé et en sécurité du travail, Canada; Université de Montréal, Canada; University of Toronto, Canada; Simon Fraser University, Canada.)29790566
480 Pan A, Schernhammer ES, Sun Q, Hu FB. 2011. Rotating night shift work and risk of type 2 diabetes: two prospective cohort studies in women. PLoS Med 8(12): e1001141. (Supported by NIH, and the National Heart, Lung, and Blood Institute. Authors affiliated with Harvard School of Public Health, MA; Brigham and Women’s Hospital, MA; Harvard Medical School, MA.)22162955
481 Panda S. 2016. Circadian physiology of metabolism. Science 354(6315): 1008–1015. (Supported by NIH, the American Federation of Aging, the Harry B. Helmsley Charitable Trust, and the Glenn Center for Aging Research. Author affiliated with Salk Institute of Biological Studies, CA.)27885007
482 Panda S, Antoch MP, Miller BH, Su AI, Schook AB, Straume M, Schultz PG, Kay SA, Takahashi JS, Hogenesch JB. 2002. Coordinated transcription of key pathways in the mouse by the circadian clock. Cell 109(3): 307–320. (Supported by the Novartis Research Foundation, the National Science Foundation [NSF] Center for Biological Timing, and the National Institute of Mental Health. Authors affiliated with Genomics Institute of the Novartis Research Foundation. CA; Northwestern University, IL; Scripps Research Institute, CA; University of Virginia, VA.)12015981
483 Papagiannakopoulos T, Bauer MR, Davidson SM, Heimann M, Subbaraj L, Bhutkar A, Bartlebaugh J, Vander Heiden MG, Jacks T. 2016. Circadian rhythm disruption promotes lung tumorigenesis. Cell Metab 24(2): 324–331. (Supported by a NCI Cancer Center Support Core Grant, the Lung Cancer Research Foundation, the Koch Institute Frontier Fund, the American Cancer Society, and Hope Funds for Cancer Research. Authors affiliated with Massachusetts Institute of Technology, MA; New York University School of Medicine, NY.)27476975
484 Papantoniou K, Castaño-Vinyals G, Espinosa A, Aragonés N, Pérez-Gómez B, Ardanaz E, Altzibar JM, Sanchez VM, Gómez-Acebo I, Llorca J, Muñoz D, Tardón A, Peiró R, Marcos-Gragera R, Pollan M, Kogevinas M. 2015a. Breast cancer risk and night shift work in a case-control study in a Spanish population. Eur J Epidemiol 31(9): 867–878. (Supported by the ‘‘Accion Transversal del Cancer,’’ approved on the Spanish Ministry Council on the 11th October 2007, by the Instituto de Salud Carlos III-FEDER, the Fundación Marqués de Valdecilla, the ICGC International Cancer Genome Consortium CLL, the Spanish Ministerio de Economía y Competitividad, the Red Temática de Investigación del Cáncer, the Junta de Castilla y León, the the Consejería de Salud of the Junta de Andalucía, the Conselleria de Sanitat of the Generalitat Valenciana, the Recercaixa, the European Commission, the Spanish Association Against Cancer, the Scientific Foundation, the Catalan Government DURSI Grant and a predoctoral Grant PFIS. Authors affiliated with Centre for Research in Environmental Epidemiology, Spain; IMIM [Hospital del Mar Medical Research Institute], Spain; Universitat Pompeu Fabra, Spain; Carlos III Health Institute, Spain; Cancer Epidemiology Research Group, Spain; Instituto de Salud Publica de Navarra, Spain; Basque Regional Health Department, Spain; Universidad de León, Spain; University of Cantabria, Spain; IDIVAL, Spain; Universidad de Huelva, Spain; Universidad de Oviedo, Spain; Fundación para el Fomento de la Investigación Sanitaria y Biomédica de la Comunidad Valenciana, Spain; Girona Biomedical Research Institute, Spain; CIBER Epidemiologıía y Salud Pública, Spain; National School of Public Health, Greece.)26205167
485 Papantoniou K, Castaño-Vinyals G, Espinosa A, Aragonés N, Pérez-Gómez B, Burgos J, Gómez-Acebo I, Llorca J, Peiró R, Jimenez-Moleón JJ, Arredondo F, Tardón A, Pollan M, Kogevinas M. 2015b. Night shift work, chronotype and prostate cancer risk in the MCC-Spain case-control study. Int J Cancer 137(5): 1147–1157. (Supported by the “Accion Transversal del Cancer,” Spanish Ministry Council, the Instituto de Salud Carlos III-FEDER, and a predoctoral grant PFIS. Authors affiliated with Centre for Research in Environmental Epidemiology [CREAL], Spain; IMIM (Hospital Del Mar Medical Research Institute), Spain; Universitat Pompeu Fabra [UPF], Spain; CIBER Epidemiologıa Y Salud Publica, Spain; Carlos III Health Institute, Spain; Cancer Epidemiology Research Group, Spain; Hospital Ramon Y Cajal, Spain; Instituto Ramon Y Cajal De Investigacion Sanitaria, Spain; Universidad De Alcala De Henares, Spain; University of Cantabria, Spain; IDIVAL, Spain; Fundacion Para El Fomento De La Investigacion Sanitaria Y Biomedica De La Comunidad Valenciana, Spain; Hospitales Universitarios De Granada/Universidad De Granada, Spain; Hospital Infanta Elena, Spain; Universidad De Huelva, Spain; Universidad De Oviedo, Spain; National School of Public Health, Greece.)25530021
486 Papantoniou K, Castaño-Vinyals G, Espinosa A, Turner MC, Alonso-Aguado MH, Martin V, Aragonés N, Pérez-Gómez B, Pozo BM, Gómez-Acebo I, Ardanaz E, Altzibar JM, Peiro R, Tardon A, Lorca JA, Chirlaque MD, García-Palomo A, Jimenez-Moleon JJ, Ierssen T, Ederra M, Amiano P, Pollan M, Moreno V, Kogevinas M. 2017. Shift work and colorectal cancer risk in the MCC-Spain case-control study. Scand J Work Environ Health 43(3): 250–259. (Supported by the “Accion Transversal del Cancer”, approved on the Spanish Ministry Council on 11 October 2007, by the Instituto de Salud Carlos III-FEDER, by the Fundación Marqués de Valdecilla, by the ICGC International Cancer Genome Consortium CLL [The ICGC CLL-Genome Project is funded by Spanish Ministerio de Economía y Competitividad [MINECO] through the Instituto de Salud Carlos III [ISCIII] and Red Temática de Investigación del Cáncer [RTICC] del ISCIII], by the Junta de Castilla y León, by the Consejería de Salud of the Junta de Andalucía, by the Conselleria de Sanitat of the Generalitat Valenciana, by the Recercaixa, by the European Commission grants, by the Spanish Association Against Cancer [AECC] Scientific Foundation, by the Catalan Government DURSI grant, by a predoctoral grant PFIS, by FEDER, by the European Commission, by the the Catalan Government DURSI, and by the Canadian Institutes of Health Research. Authors affiliated with CREAL, Spain; Medical University of Vienna, Austria; IMIM, Spain; Universitat Pompeu Fabra, Spain; University of Ottawa, Canada; IDIBELL, Spain; Hospitalet de Llobregat, Spain; Universidad de León, Spain; Carlos III Health Institute, Spain; IIS Puerta de Hierro, Spain; Complejo Hospitales Universitarios de Granada, Spain; University of Cantabria, Spain; Instituto de Salud Publica de Navarra, Spain; Navarra Institute for Health Research, Spain; Public Health Division of Gipuzkoa, Spain; Biodonostia Research Institute, Spain; FISABIO, Spain; Universidad de Oviedo, Spain; CYSMA, Spain; Universidad de Huelva, Spain; IMIB-Arrixaca, Spain; Universidad Murcia, Spain; Universidad de Granada, Spain; University of Barcelona, Spain; CIBERESP, Spain.)28251241
487 Papantoniou K, Devore EE, Massa J, Strohmaier S, Vetter C, Yang L, Shi Y, Giovannucci E, Speizer F, Schernhammer ES. 2018. Rotating night shift work and colorectal cancer risk in the Nurses’ Health Studies. Int J Cancer 143(11): 2709–2717. (Supported by CDC/NIOSH and NIH. Authors affiliated with Medical University of Vienna, Austria; Brigham and Women’s Hospital, MA: Harvard Medical School, MA; Harvard T. H. Chan School of Public Health, MA; University of Colorado, CO; Chinese PLA General Hospital, China.)29978466
488 Papantoniou K, Pozo OJ, Espinosa A, Marcos J, Castaño-Vinyals G, Basagaña X, Juanola Pagès E, Mirabent J, Martin J, Such Faro P, Gascó Aparici A, Middleton B, Skene DJ, Kogevinas M. 2015c. Increased and mistimed sex hormone production in night shift workers. Cancer Epidemiol Biomarkers Prev 24(5): 854–863. (Supported by the Instituto de Salud Carlos III, the Centre for Research in Environmental Epidemiology, and the Royal Society Wolfson. Authors affiliated with CREAL, Spain; IMIM, Spain; UPF, Spain; CIBERESP, Spain; Deparatment d’Empresa i Ocupacio de la Generalitat de Catalunya, Spain; Parc de Salut Mar, Spain; Ferrocarrils de la Generalitat de Catalunya, Spain; SEAT, Spain; Hospital de Viladecans, Spain; University of Surrey, UK; National School of Public Health, Greece.)25737330
489 Papantoniou K, Pozo OJ, Espinosa A, Marcos J, Castaño-Vinyals G, Basagaña X, Ribas FC, Mirabent J, Martín J, Carenys G, Martín CR, Middleton B, Skene DJ, Kogevinas M. 2014. Circadian variation of melatonin, light exposure, and diurnal preference in day and night shift workers of both sexes. Cancer Epidemiol Biomarkers Prev 23(7): 1176–1186. (Supported by the Instituto de Salud Carlos III and the Centre for Research in Environmental Epidemiology. Authors affiliated with Centre for Research in Environmental Epidemiology [CREAL], Spain; IMIM [Hospital del Mar Medical Research Institute], Spain; Universitat Pompeu Fabra, Barcelona [UPF], Spain; Departament d´Empresa i Ocupacio, Spain; Parc de Salut Mar, Spain; Ferrocarrils de la Generalitat de Catalunya, Spain; SEAT, S.A., Spain; Hospital de Viladecans, Spain; CIBER Epidemiología y Salud Publica [CIBERESP], Spain; University of Surrey, UK; National School of Public Health, Greece.)24812038
490 Parent ME, El-Zein M, Rousseau MC, Pintos J, Siemiatycki J. 2012. Night work and the risk of cancer among men. Am J Epidemiol 176(9): 751–759. (Supported by the Health Canada, the National Cancer Institute of Canada, the Institut de recherche en santé et sécurité au travail du Québec, the Fonds de la recherche en santé du Québec, and the Canadian Institutes of Health Research. Authors affiliated with INRS, Canada; University of Quebec, Canada; CRCHUM, Canada; University of Montreal, Canada.)23035019
491 Parks CG, DeRoo LA, Miller DB, McCanlies EC, Cawthon RM, Sandler DP. 2011. Employment and work schedule are related to telomere length in women. Occup Environ Med 68(8): 582–589. (Supported by NIH, NIEHS, and a Department of Defense Breast Cancer Research Concept Award. Authors affiliated with NIEHS, NC; NIOSH, WV; University of Utah, UT.)21540175
492 Pauley SM. 2004. Lighting for the human circadian clock: recent research indicates that lighting has become a public health issue. Med Hypotheses 63(4): 588–596. (Support and author affiliations not reported.)15325001
493 Peirson SN, Brown LA, Pothecary CA, Benson LA, Fisk AS. 2018. Light and the laboratory mouse. J Neurosci Methods 300: 26–36. (Supported by the BBSRC and the Wellcome Trust. Authors affiliated with University of Oxford, UK.)28414048
494 Penney KL, Stampfer MJ, Jahn JL, Sinnott JA, Flavin R, Rider JR, Finn S, Giovannucci E, Sesso HD, Loda M, Mucci LA, Fiorentino M. 2013. Gleason grade progression is uncommon. Cancer Res 73(16): 5163–5168. (Supported by the Dana-Farber/Harvard Cancer Center Prostate SPORE, the National Cancer Institute, the National Heart, Lung, and Blood Institute, the National Research Service Award, and the Prostate Cancer Foundation. Authors affiliated with Harvard School of Public Health, MA; Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Dana-Farber Cancer Institute, MA; Trinity College, Ireland; Broad Institute, MA; University of Bologna, Italy.)23946472
495 Peplonska B, Bukowska A, Gromadzinska J, Sobala W, Reszka E, Lie JA, Kjuus H, Wasowicz W. 2012. Night shift work characteristics and 6-sulfatoxymelatonin (MT6s) in rotating night shift nurses and midwives. Occup Environ Med 69(5): 339–346. (Supported by the Polish-Norwegian Research Fund. Authors affiliated with Nofer Institute of Occupational Medicine, Poland; National Institute of Occupational Health, Norway.)22368032
496 Peplonska B, Bukowska A, Lie JA, Gromadzinska J, Zienolddiny S. 2016. Night shift work and other determinants of estradiol, testosterone, and dehydroepiandrosterone sulfate among middle-aged nurses and midwives. Scand J Work Environ Health 42(5): 435–446. (Supported by the Polish-Norwegian Research Programme. Authors affiliated with Nofer Institute of Occupational Medicine, Poland; National Institute of Occupational Health, Norway.)27501065
497 Peplonska B, Bukowska A, Wieczorek E, Przybek M, Zienolddiny S, Reszka E. 2017. Rotating night work, lifestyle factors, obesity and promoter methylation in BRCA1 and BRCA2 genes among nurses and midwives. PLoS One 12(6): e0178792. (Supported by the Polish-Norwegian Research Programme. Authors affiliated with Nofer Institute of Occupational Medicine, Poland; National Institute of Occupational Health, Norway.)28594926
498 Pesch B, Harth V, Rabstein S, Baisch C, Schiffermann M, Pallapies D, Bonberg N, Heinze E, Spickenheuer A, Justenhoven C, Brauch H, Hamann U, Ko Y, Straif K, Brüning T. 2010. Night work and breast cancer – results from the German GENICA study. Scand J Work Environ Health 36(2): 134–141. (Supported by the German Federal Ministry of Education and Research, the Research Institute of Occupational Medicine of the German Social Accident Insurance, the Robert Bosch Foundation of Medical Research, the Evangelische Kliniken Bonn GmbH, and the Deutsches Krebsforschungszentrum. Authors affiliated with Ruhr University Bochum, Germany; Evangelische Kliniken Bonn gGmbH, Germany; University Tübingen, Germany; Deutsches Krebsforschungszentrum, Germany; IARC, France; Dr Margarete Fischer-Bosch-Institute of Clinical Pharmacology, Germany.)20039012
499 Pfeffer M, Korf HW, Wicht H. 2018. Synchronizing effects of melatonin on diurnal and circadian rhythms. Gen Comp Endocrinol 258: 215–221. (Supported by the Dr. Senckenbergische Stiftung. Authors affiliated with Goethe-Universität Frankfurt, Germany.)28533170
500 Pinheiro SP, Schernhammer ES, Tworoger SS, Michels KB. 2006. A prospective study on habitual duration of sleep and incidence of breast cancer in a large cohort of women. Cancer Res 66(10): 5521–5525. (Supported by NIH. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; LBI-ACR VIEnna and ACR-IRT VIEnna, Austria; Harvard School of Public Health, MA.)16707482
501 Pinkerton LE, Hein MJ, Anderson JL, Little MP, Sigurdson AJ, Schubauer-Berigan MK. 2016. Breast cancer incidence among female flight attendants: exposure-response analyses. Scand J Work Environ Health 42(6): 538–546. (Supported by NCI, USDHHS, and NIOSH. Authors affiliated with NIOSH, OH; CACI, Inc., OH; NCI, MD.)27551752
502 Pinkerton LE, Waters MA, Hein MJ, Zivkovich Z, Schubauer-Berigan MK, Grajewski B. 2012. Cause-specific mortality among a cohort of U.S. flight attendants. Am J Ind Med 55(1): 25–36. (Supported by the Office of Women’s Health of the U.S. Department of Health and Human Services. Authors affiliated with NIOSH, OH.)21987391
503 Poole EM, Schernhammer ES, Tworoger SS. 2011. Rotating night shift work and risk of ovarian cancer. Cancer Epidemiol Biomarkers Prev 20(5): 934–938. (Supported by NCI. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA: Harvard School of Public Health, MA; LBI-ACR & ACR-ITR VIEnna/CEADDP, Austria.)21467237
504 Popovich IG, Zabezhinski MA, Panchenko AV, Piskunova TS, Semenchenko AV, Tyndyk ML, Yurova MN, Anisimov VN. 2013. Exposure to light at night accelerates aging and spontaneous uterine carcinogenesis in female 129/Sv mice. Cell Cycle 12(11): 1785–1790. (Supported by the President of the Russian Federation. Authors affiliated with N.N. Petrov Research Institute of Oncology, Russia.)23656779
505 Portnov BA, Stevens RG, Samociuk H, Wakefield D, Gregorio DI. 2016. Light at night and breast cancer incidence in Connecticut: An ecological study of age group effects. Sci Total Environ 572: 1020–1024. (Support not reported. Authors affiliated with University of Connecticut, CT; University of Haifa, Israel; Connecticut Children’s Medical Center, CT.)27531467
506 Prata Lima MF, Baracat EC, Simões MJ. 2004. Effects of melatonin on the ovarian response to pinealectomy or continuous light in female rats: similarity with polycystic ovary syndrome. Braz J Med Biol Res 2004(37): 987–995. (Support not reported. Authors affiliated with Faculdade de Medicina do Triângulo Mineiro, Brazil; Universidade Federal de São Paulo, Brazil.)
507 Prendergast BJ, Cable EJ, Patel PN, Pyter LM, Onishi KG, Stevenson TJ, Ruby NF, Bradley SP. 2013. Impaired leukocyte trafficking and skin inflammatory responses in hamsters lacking a functional circadian system. Brain Behav Immun 32: 94–104. (Supported by the National Institute of Allergy and Infectious Diseases. Authors affiliated with University of Chicago, IL; Stanford University, CA.)23474187
508 Presser HB, Ward BW. 2011. Nonstandard work schedules over the life course: a first look. Mon Labor Rev July: 3–16. (Supported by the Alfred P. Sloan Foundation. Authors affiliated with University of Maryland, MD.)
509 Pronk A, Ji BT, Shu XO, Xue S, Yang G, Li HL, Rothman N, Gao YT, Zheng W, Chow WH. 2010. Night-shift work and breast cancer risk in a cohort of Chinese women. Am J Epidemiol 171(9): 953–959. (Supoprted by NIH. Authors affiliated with NCI, MD; Vanderbilt University School of Medicine, TN; Shanghai Cancer Institute, China.)20375193
510 Pukkala E, Helminen M, Haldorsen T, Hammar N, Kojo K, Linnersjö A, Rafnsson V, Tulinius H, Tveten U, Auvinen A. 2012. Cancer incidence among Nordic airline cabin crew. Int J Cancer 131(12): 2886–2897. (Supported by the Nordic Cancer Union. Authors affiliated with Finnish Cancer Registry, Finland; University of Tampere, Finland; Cancer Registry of Norway, Norway; Karolinska Institutet, Sweden; STUK-Radiation and Nuclear Safety Authority, Finland; University of Iceland, Iceland; Icelandic Cancer Registry, Iceland; Institute for Energy Technology, Norway.)22447246
511 Pukkala E, Ojamo M, Rudanko SL, Stevens RG, Verkasalo PK. 2006. Does incidence of breast cancer and prostate cancer decrease with increasing degree of visual impairment. Cancer Causes Control 17(4): 573–576. (Support not reported. Authors affiliated with Finnish Cancer Registry, Finland; Finnish Register of Visual Impairment, Finland; University of Connecticut Health Center, CT; National Public Health Institute, Finland.)16596312
512 Puttonen S, Viitasalo K, Härmä M. 2011. Effect of shiftwork on systemic markers of inflammation. Chronobiol Int 28(6): 528–535. (Supported by the Academy of Finland and the Finnish Work Environment Fund. Authors affiliated with Finnish Institute of Occupational Health, Finland; Finnair Health Services, Finland; University of Helsinki, Finland.)21797781
513 Rabstein S, Harth V, Justenhoven C, Pesch B, Plöttner S, Heinze E, Lotz A, Baisch C, Schiffermann M, Brauch H, Hamann U, Ko Y, Brüning T, GENICA Consortium. 2014. Polymorphisms in circadian genes, night work and breast cancer: results from the GENICA study. Chronobiol Int 31(10): 1115–1122. (Supported by the German Federal Ministry of Education and Research, the Institute for Prevention and Occupational Medicine of the German Social Accident Insurance, Ruhr-University Bochum [IPA], the Robert Bosch Foundation, Stuttgart, Evangelische Kliniken Bonn GmbH, and Deutsches Krebsforschungszentrum, Heidelberg. Authors affiliated with Institute of the Ruhr-Universität Bochum [IPA], Germany; University Medical Centre Hamburg-Eppendorf, Germany; Bioscientia Center for Human Genetics, Germany; Evangelische Kliniken Bonn gGmbH, Germany; Dr. Margarete Fischer-Bosch – Institute of Clinical Pharmacology, Germany; University of Tübingen, Germany; German Cancer Research Center, Germany.)25229211
514 Rabstein S, Harth V, Pesch B, Pallapies D, Lotz A, Justenhoven C, Baisch C, Schiffermann M, Haas S, Fischer HP, Heinze E, Pierl C, Brauch H, Hamann U, Ko Y, Brüning T, GENICA Consortium. 2013. Night work and breast cancer estrogen receptor status – results from the German GENICA study. Scand J Work Environ Health 39(5): 448–455. (Supported by the German Federal Ministry of Education and Research, the Institute for Prevention and Occupational Medicine of the German Social Accident Insurance, Ruhr-University Bochum, the Robert Bosch Foundation, Stuttgart, Evangelische Kliniken Bonn GmbH, and the Deutsches Krebsforschungszentrum. Authors affiliated with Institute of the Ruhr-Universität Bochum, Germany; University Medical Centre Hamburg-Eppendorf, Germany; Dr Margarete Fischer-Bosch-Institute of Clinical Pharmacology, Germany; University of Tübingen, Germany; Medical Faculty of the University of Bonn, Germany; Deutsches Krebsforschungszentrum, Germany; Evangelische Kliniken Bonn gGmbH, Germany.)23543199
515 Radetsky LC, Rea MS, Bierman A, Figueiro MG. 2013. Circadian disruption: comparing humans with mice. Chronobiology Int 30(8): 1066–1071. (Supported by the Office of Naval Research and NCI. Authors affiliated with Rensselaer Polytechnic Institute, NY.)
516 Rahman SA, Shapiro CM, Wang F, Ainlay H, Kazmi S, Brown TJ, Casper RF. 2013. Effects of filtering visual short wavelengths during nocturnal shiftwork on sleep and performance. Chronobiol Int 30(8): 951–962. (Supported by the Canadian Institutes of Health Research, the Government of Ontario/Pharmacia Canada Inc./Genesis Research Foundation/OBGYN Graduate Scholarship in Science and Technology at the University of Toronto, Faculty of Medicine, and the Frederick Banting and Charles Best Canada Graduate Scholarships Doctoral Award from the Canadian Institutes of Health Research. Authors affiliated with Mount Sinai Hospital, Canada; University of Toronto, Canada; The Youthdale Child and Adolescent Sleep Centre, Canada.)23834705
517 Rahman SA, St Hilaire MA, Lockley SW. 2017. The effects of spectral tuning of evening ambient light on melatonin suppression, alertness and sleep. Physiol Behav 177: 221–229. (Supported by the Biological Illuminations LLC, a subsidiary of Lighting Science Group Corporation [LSGC], the National Center for Advancing Translational Sciences, and NIH/NHLBI. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA.)28472667
518 Rångtell FH, Ekstrand E, Rapp L, Lagermalm A, Liethof L, Búcaro MO, Lingfors D, Broman JE, Schiöth HB, Benedict C. 2016. Two hours of evening reading on a self-luminous tablet vs. reading a physical book does not alter sleep after daytime bright light exposure. Sleep Med 23: 111–118. (Supported by AFA Insurance, the Novo Nordisk Foundation, the Swedish Brain Foundation, and the Swedish Research Council. Authors affiliated with Uppsala University, Sweden.)27539026
519 Rao D, Yu H, Bai Y, Zheng X, Xie L. 2015. Does night-shift work increase the risk of prostate cancer? a systematic review and meta-analysis. Onco Targets Ther 8: 2817–2826. (Supported by the National Key Clinical Specialty Construction Project of China, Key Medical Disciplines of Zhejiang Province, Health Sector Scientific Research Special Project, Combination of Traditional Chinese and Western Medicine Key Disciplines of Zhejiang Province, Zhejiang Province Key Project of Science and Technology, National Natural Science Foundation of China, and Scientific Research Foundation of the Ministry of Public Health of China. Authors affiliated with Zhejiang University, China; Second Affiliated Hospital of Wenzhou Medical University, China; Yunnan Tumor Hospital and Third Affiliated Hospital of Kunming Medical University, China.)26491356
520 Rea MS, Bierman A, Figueiro MG, Bullough JD. 2008. A new approach to understanding the impact of circadian disruption on human health. J Circadian Rhythms 6: 7. (Supported by the CDC and the Trans-NIH Genes, Environment and Health Initiative Grant. Authors affiliated with Rensselaer Polytechnic Institute, NY.)18510756
521 Rea MS, Figueiro MG. 2014. Quantifying light-dependent circadian disruption in humans and animal models. Chronobiol Int 31(10): 1239–1246. (Supported by the Office of Naval Research, the National Cancer Institute, and the National Institute on Drug Abuse. Authors affiliated with Rensselaer Polytechnic Institute, NY.)25229212
522 Rea MS, Figueiro MG, Bullough JD, Bierman A. 2005. A model of phototransduction by the human circadian system. Brain Res Brain Res Rev 50(2): 213–228. (Support not reported. Authors affiliated with Rensselaer Polytechnic Institute, NY.)16216333
523 Reddy AB, Field MD, Maywood ES, Hastings MH. 2002. Differential resynchronisation of circadian clock gene expression within the suprachiasmatic nuclei of mice subjected to experimental jet lag. J Neurosci 22(17): 7326–7330. (Support not reported. Authors affiliated with University of Cambridge, UK.)12196553
524 Reichrath J, Berg K, Emmert S, Lademann J, Seckmeyer G, Zastrow L, Vogt T, Holick MF. 2016. Biologic effects of light: An enlighting prospective. Anticancer Res 36(3): 1339–1343. (Support not reported. Authors affiliated with Saarland University Hospital, Germany; Oslo University Hospital – Radium Hospital Montebello, Norway; University Medical Center Rostock, Germany; Universitätsmedizin Berlin, Germany; University of Hannover, Germany; Boston University Medical Center, MA.)26977035
525 Reid KJ, Abbott SM. 2015. Jet lag and shift work disorder. Sleep Med Clin 10(4): 523–535. (Support not reported. Authors affiliated with Northwestern University, IL.)26568127
526 Reinberg A, Ashkenazi I. 2008. Internal desynchronization of circadian rhythms and tolerance to shift work. Chronobiol Int 25(4): 625–643. (Supported by the Therese Tremel-Pontremoli donation for chronobiologic research at the Fondation Adolphe de Rothschild, Paris. Authors affiliated with Fondation A. de Rothschild, France; Tel Aviv University, Israel.)18622820
527 Reiter R. 2001. Reactive oxygen species, DNA damage and carcinogenesis: Intervention with melatonin. In Pineal Gland and Cancer. Neuroimmunoendocrine Mechanisms in Malignancy C Bartsch, H Bartsch, D Blask, eds. Heidelberg: Springer. p. 442–455. (Support and author affiliations not reported.)
528 Reiter RJ, Acuña-Castroviejo D, Tan DX, Burkhardt S. 2001. Free radical-mediated molecular damage. Mechanisms for the protective actions of melatonin in the central nervous system. Ann N Y Acad Sci 939: 200–215. (Support not reported. Authors affiliated with University of Texas Health Science Center at San Antonio, TX.)11462772
529 Reiter RJ, Tan DX, Galano A. 2014. Melatonin: exceeding expectations. Physiology (Bethesda) 29(5): 325–333. (Support not reported. Authors affiliated with UT Health Science Center, TX; Universidad Autonoma Metropolitana-Iztapalapa, Mexico.)25180262
530 Renehan AG, Zwahlen M, Egger M. 2015. Adiposity and cancer risk: new mechanistic insights from epidemiology. Nat Rev Cancer 15(8): 484–498. (Support not reported. Authors affiliated with University of Manchester, UK; University of Bern, Switzerland.)26205341
531 Rensselaer Polytechnic Institute. 2018. Lighting Answers: What is Light Pollution? Rensselaer Polytechnic Institute. Last accessed: 6/14/18. http://www.lrc.rpi.edu/programs/nlpip/lightinganswers/lightpollution/lightPollution.asp# (http://www.lrc.rpi.edu/programs/nlpip/lightinganswers/lightpollution/lightPollution.asp) Glossary can be found at http://www.lrc.rpi.edu/programs/nlpip/lightinganswers/lightpollution/glossary.asp
532 Reszka E, Peplonska B, Wieczorek E, Sobala W, Bukowska A, Gromadzinska J, Lie JA, Kjuus H, Wasowicz W. 2013. Circadian gene expression in peripheral blood leukocytes of rotating night shift nurses. Scand J Work Environ Health 39(2): 187–194. (Supported by the Polish-Norwegian Research Fund and ECNIS2. Authors affiliated with Nofer Institute of Occupational Medicine, Poland; National Institute of Occupational Health, Norway.)22552736
533 Reszka E, Przybek M. 2016. Circadian genes in breast cancer. Adv Clin Chem 75: 53–70. (Supported by the Polish-Norwegian Research Program, the National Centre for Research and Development, and the National Science Center, Poland. Authors affiliated with Nofer Institute of Occupational Medicine, Poland.)27346616
534 Reszka E, Przybek M, Muurlink O, Peplonska B. 2017. Circadian gene variants and breast cancer. Cancer Lett 390: 137–145. (Supported by the Polish-Norwegian Research Program, the National Centre for Research and Development, and the National Science Center, Poland. Authors affiliated with Nofer Institute of Occupational Medicine, Poland; Central Queensland University, Australia; Griffith Institute of Educational Research, Australia.)28109907
535 Reszka E, Wieczorek E, Przybek M, Jablońska E, Kalużny P, Bukowska-Damska A, Zienolddiny S, Peplońska B. 2018. Circadian gene methylation in rotating-shift nurses: a cross-sectional study. Chronobiol Int 35(1): 111–121. (Supported by the Nofer Institute of Occupational Medicine and the Polish-Norwegian Research Program carried out by the National Centre for Research and Development. Authors affiliated with Nofer Institute of Occupational Medicine, Poland; National Institute of Occupational Health, Norway.)29144171
536 Reynolds P, Cone J, Layefsky M, Goldberg DE, Hurley S. 2002. Cancer incidence in California flight attendants (United States). Cancer Causes Control 13(4): 317–324. (Supported by the California Breast Cancer Research Program. Authors affiliated with California Department of Health Services, CA; Public Health Institute, CA.)12074501
537 Ripperger JA, Schibler U. 2006. Rhythmic CLOCK-BMAL1 binding to multiple E-box motifs drives circadian Dbp transcription and chromatin transitions. Nat Genet 38(3): 369–374. (Supported by the Canton of Geneva, the Swiss National Science Foundation [through an individual grant to U.S. and the Swiss National Center for Competence in Research program grant ‘Frontiers in Genetics’], the Louis Jeantet Foundation of Medicine and the Bonizzi-Theler Stiftung. Authors affiliated with University of Geneva, Switzerland; University of Fribourg, Switzerland.)16474407
538 Rodgers KM, Udesky JO, Rudel RA, Brody JG. 2018. Environmental chemicals and breast cancer: An updated review of epidemiological literature informed by biological mechanisms. Environ Res 160: 152–182. (Supported by charitable gifts to Silent Spring Institute and grants from Avon Foundation for Women. Authors affiliated with Silent Spring Institute, MA.)28987728
539 Roenneberg T. 2012. What is chronotype? Sleep Biol Rhythms 10: 75–76. (Support not reported. Author affiliated with Ludwig-Maximilians-University, Germany.)
540 Roenneberg T, Allebrandt KV, Merrow M, Vetter C. 2012. Social jetlag and obesity. Curr Biol 22(10): 939–943. (Supported by the European Commission, the Netherlands Organization for Scientific Research, the University of Groningen Rosalind Franklin Program, and the Hersenstichting Nederland. Authors affiliated with University of Munich, Germany; University of Groningen, Netherlands.)22578422
541 Roenneberg T, Kuehnle T, Juda M, Kantermann T, Allebrandt K, Gordijn M, Merrow M. 2007. Epidemiology of the human circadian clock. Sleep Med Rev 11(6): 429–438. (Supported by the 6th European Framework Programme EUCLOCK and the Daimler-Benz-Stiftung project CLOCKWORK. Authors affiliated with University of Munich, Germany; University of Groningen, Netherlands.)17936039
542 Roenneberg T, Merrow M. 2007. Entrainment of the human circadian clock. Cold Spring Harb Symp Quant Biol 72: 293–299. (Supported by the supported by the 6th European Framework Programme EUCLOCK and the Daimler-Benz-Stiftung project CLOCKWORK. Authors affiliated with University of Munich, Germany; University of Groningen, Netherlands.)18419286
543 Rose DM, Jung D, Parera D, Konietzko J. 1999. [Time zone shifts and jet lag after long-distance flights]. Z Arztl Fortbild Qualitatssich 93(7): 485–490. (Support unknown due to foreign language. Authors affiliated with Johannes Gutenberg-Universität Mainz, Germany.)10568249
544 Ruben MD, Wu G, Smith DF, Schmidt RE, Francey LJ, Lee YY, Anafi RC, Hogenesch JB. 2018. A database of tissue-specific rhythmically expressed human genes has potential applications in circadian medicine. Sci Transl Med 10(eaat8806): 1–7. (Supported by the Cincinnati Children’s Hospital Medical Center, the National Institute of Neurological Disorders and Stroke, and the National Human Genome Research Institute, NIH, NCI, NHGRI, the National Heart, Lung, and Blood Institute, the National Institute on Drug Abuse, the National Institute of Mental Health, and NINDS. Authors affiliated with Cincinnati Children’s Hospital Medical Center, OH; University of Cincinnati School of Medicine, OH; University of Pennsylvania Perelman School of Medicine, PA.)
545 Ruby NF, Joshi N, Heller HC. 1998. Phase shift magnitude and direction determine whether Siberian hamsters reentrain to the photocycle. J Biol Rhythms 13(6): 506–517. (Supported by the National Institute of Child Health and Human Development and the National Institute of Aging. Authors affiliated with Stanford University, CA.)9850011
546 Rudic RD, McNamara P, Curtis AM, Boston RC, Panda S, Hogenesch JB, FitzGerald GA. 2004. BMAL1 and CLOCK, two essential components of the circadian clock, are involved in glucose homeostasis. PLoS Biol 2(11): e377. (Supported by the Penn Diabetes Center/Mouse Phenotyping, Physiology, and Metabolism Core, NIH, and the American Heart Association. Authors affiliated with University of Pennsylvania, PA; Phenomix Corporation, CA; Genomics Institute of the Novartis Research Foundation, CA.)15523558
547 Russo IH, Russo J. 1978. Developmental stage of the rat mammary gland as determinant of its susceptibility to 7,12-dimethylbenz[a]anthracene. J Natl Cancer Inst 61(6): 1439–1449. (Supported by the United Foundation of Greater Detroit and NCI. Authors affiliated with Michigan Cancer Foundation, MI.)102856
548 Russo IH, Russo J. 2011. Pregnancy-induced changes in breast cancer risk. J Mammary Gland Biol Neoplasia 16(3): 221–233. (Support not reported. Authors affiliated with Fox Chase Cancer Center, PA.)21805333
549 Russo J, Russo IH. 2008. Breast development, hormones, and cancer. In Innovative Endocrinology of Cancer LM Berstein, RJ Santen, eds. Landes Bioscience and Springer Science+Business Media. p. 52–56. (Support not reported. Authors affiliated with Fox Chase Cancer Center, PA.)
550 Rutters F, Lemmens SG, Adam TC, Bremmer MA, Elders PJ, Nijpels G, Dekker JM. 2014. Is social jetlag associated with an adverse endocrine, behavioral, and cardiovascular risk profile? J Biol Rhythms 29(5): 377–383. (Support not reported. Authors affiliated with VU University Medical Centre, Netherlands; Maastricht University, Netherlands.)25252710
551 Rybnikova N, Haim A, Portnov BA. 2015. Artificial Light at Night (ALAN) and breast cancer incidence worldwide: A revisit of earlier findings with analysis of current trends. Chronobiol Int 32(6): 757–773. (Support not reported. Authors affiliated with University of Haifa, Israel.)26102518
552 Rybnikova N, Portnov BA. 2018. Population-level study links short-wavelength nighttime illumination with breast cancer incidence in a major metropolitan area. Chronobiol Int: 1–11. (Supported by the Israel Ministry of Science, Technology and Space. Authors affiliated with University of Haifa, Israel.)
553 Sahar S, Sassone-Corsi P. 2007. Circadian clock and breast cancer: a molecular link. Cell Cycle 6(11): 1329–1331. (Support not reported. Authors affiliated with University of California at Irvine, CA.)17534151
554 Sainz RM, Mayo JC, Tan DX, León J, Manchester L, Reiter RJ. 2005. Melatonin reduces prostate cancer cell growth leading to neuroendocrine differentiation via a receptor and PKA independent mechanism. Prostate 63(1): 29–43. (Supported by Fulbright, the Spanish Ministry of Education, Culture & Sports, and FICYT. Authors affiliated with University of Texas Health Science Center, TX.)15378522
555 Saksvik IB, Bjorvatn B, Hetland H, Sandal GM, Pallesen S. 2011. Individual differences in tolerance to shift work – a systematic review. Sleep Med Rev 15(4): 221–235. (Support not reported. Authors affiliated with University of Bergen, Norway.)20851006
556 Salavaty A. 2015. Carcinogenic effects of circadian disruption: an epigenetic viewpoint. Chin J Cancer 34(9): 375–383. (No support received. Author affiliated with Shahid Chamran University of Ahvaz, Iran.)26253128
557 Salgado-Delgado R, Ángeles-Castellanos M, Buijs MR, Escobar C. 2008. Internal desynchronization in a model of night-work by forced activity in rats. Neuroscience 154(3): 922–931. (Supported by Servier Monde, DGAPA-PAPIIT-UNAM, and CONACyT. Authors affiliated with Universidad Nacional Autónoma de México, Mexico.)18472343
558 Salgado-Delgado R, Nadia S, Angeles-Castellanos M, Buijs RM, Escobar C. 2010. In a rat model of night work, activity during the normal resting phase produces desynchrony in the hypothalamus. J Biol Rhythms 25(6): 421–431. (Supported by CONACyT, DGAPA-PAPIIT-UNAM and the Programa de Becas posdoctorales de la UNAM. Authors affiliated with Universidad Nacional Autónoma de México, Mexico.)21135158
559 Salgado-Delgado RC, Saderi N, Basualdo Mdel C, Guerrero-Vargas NN, Escobar C, Buijs RM. 2013. Shift work or food intake during the rest phase promotes metabolic disruption and desynchrony of liver genes in male rats. PLoS One 8(4): e60052. (Supported by CONACyT, DGAPA-PAPIIT-UNAM, and PROMEP. Authors affiliated with Universidad Nacional Autónoma de México, Mexico; Universidad Autónoma de San Luis Potosí, Mexico.)23565183
560 Samuelsson LB, Bovbjerg DH, Roecklein KA, Hall MH. 2018. Sleep and circadian disruption and incident breast cancer risk: An evidence-based and theoretical review. Neurosci Biobehav Rev 84: 35–48. (Supported by the National Institute of General Medical Sciences and NCI. Authors affiliated with University of Pittsburgh, PA.)29032088
561 Samulin Erdem J, Notø HØ, Skare Ø, Lie J-AS, Petersen-Øverleir M, Reszka E, Peplońska B, Zienolddiny S. 2017a. Mechanisms of breast cancer risk in shift workers: association of telomere shortening with the duration and intensity of night work. Cancer Med 6(8): 1988–1997. (Supported by the Norway Grants, under the Polish-Norwegian Research Program and NIOH. Authors affiliated with National Institute of Occupational Health, Norway; Nofer Institute of Occupational Medicine, Poland.)28707432
562 Samulin Erdem J, Skare Ø, Petersen-Øverleir M, Notø HØ, Lie JS, Reszka E, Peplońska B, Zienolddiny S. 2017b. Mechanisms of breast cancer in shift workers: DNA methylation in five core circadian genes in nurses working night shifts. J Cancer 8(15): 2876–2884. (Supported by the Norway Grants, under the Polish-Norwegian Research Program and NIOH. Authors affiliated with National Institute of Occupational Health, Norway; Nofer Institute of Occupational Medicine, Poland.)28928877
563 Scheiermann C, Kunisaki Y, Frenette PS. 2013. Circadian control of the immune system. Nat Rev Immunol 13(3): 190–198. (Supported by NIH, the German Academic Exchange Service, and the Japan Society for the Promotion of Science. Authors affiliated with Albert Einstein College of Medicine, NY.)23391992
564 Schernhammer ES, Berrino F, Krogh V, Secreto G, Micheli A, Venturelli E, Grioni S, Sempos CT, Cavalleri A, Schünemann HJ, Strano S, Muti P. 2010. Urinary 6-sulphatoxymelatonin levels and risk of breast cancer in premenopausal women: the ORDET cohort. Cancer Epidemiol Biomarkers Prev 19(3): 729–737. (Supported by a Department of Defense Grant and NCI. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard School of Public Health, MA; LBI-ACR-CTO & ACR-ITR VIEnna/CEADDP, Austria; Fondazione IRCCS Istituto Nazionale Tumori, Italy; University of Buffalo, NY; McMaster University, Canada; Istituto Nazionale Tumori Regina Elena IRCCS, Italy.)20200429
565 Schernhammer ES, Berrino F, Krogh V, Secreto G, Micheli A, Venturelli E, Sieri S, Sempos CT, Cavalleri A, Schünemann HJ, Strano S, Muti P. 2008. Urinary 6-sulfatoxymelatonin levels and risk of breast cancer in postmenopausal women. J Natl Cancer Inst 100(12): 898–905. (Supported by the Department of Defense. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard School of Public Health, MA; LBI-ACR and ACR-ITR VIEnna/CEADDP, Austria; Fondazione Istituto di Ricovero e Cura a Carattere Scientifico [IRCCS] Istituto Nazionale Tumori, Italy; University at Buffalo, NY; Istituto Nazionale Tumori Regina Elena IRCCS, Italy; McMaster University, Canada.)18544743
566 Schernhammer ES, Feskanich D, Liang G, Han J. 2013. Rotating night-shift work and lung cancer risk among female nurses in the United States. Am J Epidemiol 178(9): 1434–1441. (Supported by NIH. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; ACR-ITR, Austria; LBI-ACR, Austria; Southeast University, China; Tianjin Medical University Cancer Institute and Hospital, China.)24049158
567 Schernhammer ES, Feskanich D, Niu C, Dopfel R, Holmes MD, Hankinson SE. 2009. Dietary correlates of urinary 6-sulfatoxymelatonin concentrations in the Nurses’ Health Study cohorts. Am J Clin Nutr 90(4): 975–985. (Supported by NCI. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard School of Public Health, MA; LBI-ACR VIEnna & ACR-ITR VIEnna, Austria; Harvard University, MA.)19675108
568 Schernhammer ES, Hankinson SE. 2005. Urinary melatonin levels and breast cancer risk. J Natl Cancer Inst 97(14): 1084–1087. (Supported by NCI. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard School of Public Health, MA; LBI-ACR VIEnna and ACR-ITR VIEnna, Austria.)16030307
569 Schernhammer ES, Kroenke CH, Dowsett M, Folkerd E, Hankinson SE. 2006a. Urinary 6-sulfatoxymelatonin levels and their correlations with lifestyle factors and steroid hormone levels. J Pineal Res 40(2): 116–124. (Supported by NCI. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard School of Public Health, MA; LBI-ACR Vienna & ACR-ITR, Austria; Royal Marsden Hospital, UK.)16441548
570 Schernhammer ES, Kroenke CH, Laden F, Hankinson SE. 2006b. Night work and risk of breast cancer. Epidemiology 17(1): 108–111. (Support not reported. Authors affiliated with Harvard Medical School, MA; LBI-ACR VIEnna & ACR-ITR VIEnna, Austria; Brigham and Women’s Hospital, MA; Harvard School of Public Health, MA.)16357603
571 Schernhammer ES, Laden F, Speizer FE, Willett WC, Hunter DJ, Kawachi I, Colditz GA. 2001. Rotating night shifts and risk of breast cancer in women participating in the Nurses’ Health Study. J Natl Cancer Inst 93(20): 1563–1568. (Supported by NCI, NIEHS, and the Austrian Federal Ministry of Education, Science and Culture. Authors affiliated with Harvard Medical School, MA; Brigham and Women’s Hospital, MA; Harvard Center for Cancer Prevention, MA; Dana-Faber/Harvard Cancer Center, MA; Harvard School of Public Health, MA.)11604480
572 Schernhammer ES, Laden F, Speizer FE, Willett WC, Hunter DJ, Kawachi I, Fuchs CS, Colditz GA. 2003. Night-shift work and risk of colorectal cancer in the Nurses’ Health Study. J Natl Cancer Inst 95(11): 825–828. (Supported by NCI, NIH, and the Austrian Research Centers [ARC] Seibersdorf Research, Health Physics Division. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Kaiser Franz-Josef-Spital, Austria; Harvard School of Public Health, MA; Dana-Farber Cancer Institute/Harvard Cancer Center, MA; Harvard Center for Cancer Prevention, MA.)12783938
573 Schernhammer ES, Razavi P, Li TY, Qureshi AA, Han J. 2011. Rotating night shifts and risk of skin cancer in the Nurses’ Health Study. J Natl Cancer Inst 103(7): 602–606. (Supported by NIH and the Department of Dermatology, Brigham and Women’s Hospital. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard School of Public Health, MA; LBI-ACR & ACR-ITR VIEnna/CEADDP, Austria; University of Southern California Los Angeles, LA.)21335547
574 Schernhammer ES, Rosner B, Willett WC, Laden F, Colditz GA, Hankinson SE. 2004. Epidemiology of urinary melatonin in women and its relation to other hormones and night work. Cancer Epidemiol Biomarkers Prev 13(6): 936–943. (Supported by NCI. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard School of Public Health, MA; KFJ-Spital, Austria; Dana Farber/Harvard Cancer Center, MA; Harvard Center for Cancer Prevention, MA.)15184249
575 Schibler U, Gotic I, Saini C, Gos P, Curie T, Emmenegger Y, Sinturel F, Gosselin P, Gerber A, Fleury-Olela F, Rando G, Demarque M, Franken P. 2015. Clock-talk: Interactions between central and peripheral circadian oscillators in mammals. Cold Spring Harb Symp Quant Biol 80: 223–232. (Supported by the University of Geneva, the State of Geneva, the European Research Council [ERCAdG TimeSignal], the Swiss National Science Foundation, the Louis Jeantet Foundation of Medicine, a Federation of European Biochemical Societies [FEBS] long-term postdoctoral fellowship, a European Molecular Biology Organization [EMBO] long-term fellowship, the University of Lausanne, the State of Vaud, the Swiss National Science Foundation, the European Mouse Disease Clinic [EUMODIC], a fellowship of the Marie Curie Intra-European program, and the Novartis Foundation. Authors affiliated with University of Geneva, Switzerland; Geneva University Hospitals, Switzerland; University of Lausanne, Switzerland; Rockefeller University, NY.)26683231
576 Schmidt TM, Chen SK, Hattar S. 2011. Intrinsically photosensitive retinal ganglion cells: many subtypes, diverse functions. Trends Neurosci 34(11): 572–580. (Supported by the National Institute of General Medical Sciences, National Eye Institute and the David and Lucile Packard Foundation. Authors affiliated with Johns Hopkins University, MD.)21816493
577 Schubauer-Berigan MK, Anderson JL, Hein MJ, Little MP, Sigurdson AJ, Pinkerton LE. 2015. Breast cancer incidence in a cohort of U.S. flight attendants. Am J Ind Med 58(3): 252–266. (Supported by the National Cancer Institute and the Office of Women’s Health of the U.S. Department of Health and Human Services. Authors affiliated with NIOSH, OH; NCI, MD.)25678455
578 Schwartzbaum J, Ahlbom A, Feychting M. 2007. Cohort study of cancer risk among male and female shift workers. Scand J Work Environ Health 33(5): 336–343. (Supported by the Swedish Council for Working Life. Authors affiliated with Ohio State University, OH; Karolinska Institutet, Sweden.)17973059
579 Schwimmer H, Metzer A, Pilosof Y, Szyf M, Machnes ZM, Fares F, Harel O, Haim A. 2014. Light at night and melatonin have opposite effects on breast cancer tumors in mice assessed by growth rates and global DNA methylation. Chronobiol Int 31(1): 144–150. (Supported by the University of Haifa. Authors affiliated with University of Haifa, Israel; McGill University, Canada.)24131150
580 SEER. 2018. Surveillance, Epidemiology, and End Results Program. National Cancer Institute. http://seer.cancer.gov/statfacts/html/breast.html
581 Sephton S, Spiegel D. 2003. Circadian disruption in cancer: a neuroendocrine-immune pathway from stress to disease? Brain Behav Immun 17(5): 321–328. (Support not reported. Authors affiliated with University of Louisville School of Medicine, KY; Stanford University School of Medicine, CA.)12946654
582 Sephton SE, Sapolsky RM, Kraemer HC, Spiegel D. 2000. Diurnal cortisol rhythm as a predictor of breast cancer survival. J Natl Cancer Inst 92(12): 994–1000. (Supported by the National Institute of Mental Health and the National Cancer Institute, National Institutes of Health, Department of Health and Human Services, the John D. and Catherine T. MacArthur Foundation and by the Fetzer Institute. Authors affiliated with University of Louisville School of Medicine, KY; Stanford University, CA.)10861311
583 Shah PN, Mhatre MC, Kothari LS. 1984. Effect of melatonin on mammary carcinogenesis in intact and pinealectomized rats in varying photoperiods. Cancer Res 44(8): 3403–3407. (Support not reported. Authors affiliated with Cancer Research Institute, India.)6430548
584 Sharifian A, Farahani S, Pasalar P, Gharavi M, Aminian O. 2005. Shift work as an oxidative stressor. J Circadian Rhythms 3: 15. (Support not reported. Authors affiliated with Tehran University of Medical Sciences, Iran.)16379673
585 Sharma A, Shrivastava J. 2004. Jet lag and cabin crew: Questionnaire survey. Ind J Aerospace Med 48(1): 10–14. (Support not reported. Authors affiliated with Air India, India.)
586 Shavers VL, Harlan LC, Stevens JL. 2003. Racial/ethnic variation in clinical presentation, treatment, and survival among breast cancer patients under age 35. Cancer 97(1): 134–147. (Support not reported. Authors affiliated with NCI, MD; Information Management Systems, MD.)12491515
587 Shi F, Chen X, Fu A, Hansen J, Stevens R, Tjonneland A, Vogel UB, Zheng T, Zhu Y. 2013. Aberrant DNA methylation of miR-219 promoter in long-term night shiftworkers. Environ Mol Mutagen 54(6): 406–413. (Supported by NIEHS, Yale University, Danish Cancer Society, and the National Science Foundation of China. Authors affiliated with Yale School of Public Health, CT; Beijing University of Chinese Medicine, China; Danish Cancer Society, Denmark; University of Connecticut Health Center, CT; National Research Centre for the Working Environment, Denmark.)23813567
588 Shuboni D, Yan L. 2010. Nighttime dim light exposure alters the responses of the circadian system. Neuroscience 170(4): 1172–1178. (Supported by the Psychology Department Start-up fund, MSU IRGP award and PURI award from College of Social Science of MSU. Authors affiliated with Michigan State University, MI.)20705120
589 Simó M, Navarro X, Yuste VJ, Bruna J. 2018. Autonomic nervous system and cancer. Clin Auton Res 28(3): 301–314. (Supported by the Instituto de Salud Carlos III and Fondo Europeo de Desarrollo Regional. Authors affiliated with IDIBELL, Spain; Universitat Autòmoma de Barcelona, Spain; CIBERNED, Spain.)29594605
590 Slawik H, Stoffel M, Riedl L, Veselý Z, Behr M, Lehmberg J, Pohl C, Meyer B, Wiegand M, Krieg SM. 2016. Prospective study on salivary evening melatonin and sleep before and after pinealectomy in humans. J Biol Rhythms 31(1): 82–93. (Support not reported. Authors affiliated with Klinikum rechts der Isar, Germany; Helios Klinikum, Germany; Universitäre Psychiatrische Kliniken, Switzerland.)26647380
591 Slominski A, Tobin DJ, Zmijewski MA, Wortsman J, Paus R. 2008. Melatonin in the skin: synthesis, metabolism and functions. Trends Endocrinol Metab 19(1): 17–24. (Support not reported. Authors affiliated with University of Tennessee HSC, TN; University of Bradford, UK; Southern Illinois University, IL; University of Luebeck, Germany.)18155917
592 Slominski AT, Zmijewski MA, Jetten AM. 2016. RORα is not a receptor for melatonin. Bioessays 38(12): 1193–1194. (Supported by NIH and the Polish Ministry of Science and Higher Education. Authors affiliated with University of Alabama at Birmingham, AL; VA Medical Center, AL; Medical University of Gdańsk, Poland; NIEHS, NC.)27739090
593 Slominski RM, Reiter RJ, Schlabritz-Loutsevitch N, Ostrom RS, Slominski AT. 2012. Melatonin membrane receptors in peripheral tissues: distribution and functions. Mol Cell Endocrinol 351(2): 152–166. (Supported by NIH/NIAMS and NIH/NHLBI. Authors affiliated with University of Tennessee Health Science Center, TN; UT Health Science Center, TX.)22245784
594 Smith MT, Guyton KZ, Gibbons CF, Fritz JM, Portier CJ, Rusyn I, DeMarini DM, Caldwell JC, Kavlock RJ, Lambert PF, Hecht SS, Bucher JR, Stewart BW, Baan RA, Cogliano VJ, Straif K. 2016. Key characteristics of carcinogens as a basis for organizing data on mechanisms of carcinogenesis. Environ Health Perspect 124(6): 713–721. (Supported by NIH and NIEHS. Authors affiliated with University of California - Berkeley, CA; IARC, France; US EPA, Washington, DC and NC; Environmental Defense Fund, Washington, DC; Texas A&M University, TX; University of Wisconsin School of Medicine and Public Health, WI; University of Minnesota, MN; NIEHS, NC; University of New South Wales, Australia.)26600562
595 Smolensky MH, Reinberg AE, Sackett-Lundeen L. 2017. Perspectives on the relevance of the circadian time structure to workplace threshold limit values and employee biological monitoring. Chronobiol Int 34(10): 1439–1464. (Support not reported. Authors affiliated with University of Texas at Austin, TX; Fondation A. de Rothschild, France; American Association for Medical Chronobiology and Chronotherapeutics, MN.)29215915
596 Smolensky MH, Sackett-Lundeen LL, Portaluppi F. 2015. Nocturnal light pollution and underexposure to daytime sunlight: Complementary mechanisms of circadian disruption and related diseases. Chronobiol Int 32(8): 1029–1048. (Support not reported. Authors affiliated with University of Texas at Austin, TX; American Association for Clinical Chronobiology and Chronotherapeutics, MN; University of Ferrara, Italy.)26374931
597 Sollars PJ, Pickard GE. 2015. The neurobiology of circadian rhythms. Psychiatr Clin North Am 38(4): 645–665. (Supported by NIH. Authors affiliated with University of Nebraska, NE.)26600101
598 Song G, Yoon KA, Chi H, Roh J, Kim JH. 2016. Decreased concentration of serum melatonin in nighttime compared with daytime female medical technologists in South Korea. Chronobiol Int 33(9): 1305–1310. (Support not reported. Authors affiliated with Seegene Medical Foundation, Korea; Konkuk University, Korea; Samkwang Medical Laboratories, Korea; Institute for Occupational Health, Korea; Yonsei University College of Medicine, Korea; Cheongju University, Korea.)27385051
599 Sookoian S, Gemma C, Fernández Gianotti T, Burgueño A, Alvarez A, González CD, Pirola CJ. 2007. Effects of rotating shift work on biomarkers of metabolic syndrome and inflammation. J Intern Med 261(3): 285–292. (Supported by the Universidad de Buenos Aires, the Agencia Nacional de Promoción Científica y Tecnológica, the Consejo Nacional de Investigaciones Científicas y Técnicas, and the Beca Ramón Carrillo-Arturo Oñativia Ministerio de Salud y Ambiente de la Nación. Authors affiliated with Universidad de Buenos Aires, Argentina.)17305651
600 Soták M, Sumová A, Pácha J. 2014. Cross-talk between the circadian clock and the cell cycle in cancer. Ann Med 46(4): 221–232. (Supported by the Czech Science Foundation. Authors affiliated with Academy of Sciences of the Czech Republic, Czech Republic.)24779962
601 Sowah D, Fan X, Dennett L, Hagtvedt R, Straube S. 2017. Vitamin D levels and deficiency with different occupations: a systematic review. BMC Public Health 17(1): 519. (Supported by the Department of Medicine, University of Alberta. Authors affiliated with University of Alberta, Canada.)28637448
602 Spiegel K, Weibel L, Gronfier C, Brandenberger G, Follenius M. 1996. Twenty-four-hour prolactin profiles in night workers. Chronobiol Int 13(4): 283–293. (Supported by the Institut de Recherches Internationales Servier, France. Authors affiliated with Laboratoire de Physiologie et de Psychologie Environnementales, France.)8889252
603 Srinivasan V, Pandi-Perumal SR, Brzezinski A, Bhatnagar KP, Cardinali DP. 2011. Melatonin, immune function and cancer. Recent Pat Endocr Metab Immune Drug Discov 5(2): 109–123. (Supported by the Argentine National Research Council. Authors affiliated with Sri Sathya Sai Medical Educational and Research Foundation, India; Karpagam University, India; Somnogen Inc., NY; The Hebrew University-Hadassah Medical School, Israel; University of Louisville, KY; Pontificia Universidad Católica Argentina, Argentina; University of Buenos Aires, Argentina.)22074586
604 Srinivasan V, Spence DW, Pandi-Perumal SR, Trakht I, Cardinali DP. 2008. Therapeutic actions of melatonin in cancer: possible mechanisms. Integr Cancer Ther 7(3): 189–203. (Support not reported. Authors affiliated with University Sains Malaysia, Malaysia; University Health Network, Canada; Somnogen Inc., NY; Columbia University, NY; University of Buenos Aires, Argentina.)18815150
605 Stehle JH, von Gall C, Korf HW. 2002. Organisation of the circadian system in melatonin-proficient C3H and melatonin-deficient C57BL mice: a comparative investigation. Cell Tissue Res 309(1): 173–182. (Supported by the Deutsche Forschungsgemeinschaft and the Heinrich und Fritz Riese-Stiftung. Authors affiliated with Johann Wolfgang Goethe University Frankfurt, Germany; University of Massachusetts Medical School, MA.)12111547
606 Stehle JH, von Gall C, Korf HW. 2003. Melatonin: a clock-output, a clock-input. J Neuroendocrinol 15(4): 383–389. (Supported by the Deutsche Forschungsgemeinschaft and the Heinrich und Fritz Riese-Stiftung. Authors affiliated with Johann Wolfgang Goethe-University Frankfurt, Germany; University of Massachusetts Medical School, MA.)12622838
607 Steinlechner S. 2012. Chapter 2.12: Biological rhythms of the mouse. In The Laboratory Mouse H Hedrich, ed. San Diego, CA: Elsevier. p. 383–407. (Support not reported. Author affiliated with University of Veterinary Medicine, Germany.)
608 Stevens RG. 1987. Electric power use and breast cancer: a hypothesis. Am J Epidemiol 125(4): 556–561. (Supported by the US Department of Energy. Author affiliated with Pacific Northwest Laboratory, WA.)3548332
609 Stevens RG. 2009. Light-at-night, circadian disruption and breast cancer: assessment of existing evidence. Int J Epidemiol 38(4): 963–970. (Supported by NIEHS. Author affiliated with University of Connecticut Health Center, CT.)19380369
610 Stevens RG. 2012. Does electric light stimulate cancer development in children? Cancer Epidemiol Biomarkers Prev 21(5): 701–704. (Supported by Children with Cancer UK. Author affiliated with University of Connecticut Health Center, CT.)22354903
611 Stevens RG. 2017. Letter in reference to Vistisen et al: “Short-term effects of night shift work on breast cancer risk: a cohort study of payroll data”. Scand J Work Environ Health 43(1): 95. (Support not reported. Author affiliated with University of Connecticut, CT.)27935621
612 Stevens RG, Brainard GC, Blask DE, Lockley SW, Motta ME. 2014. Breast cancer and circadian disruption from electric lighting in the modern world. CA Cancer J Clin 64(3): 207–218. (Supported by the Institute for Integrative Health, NCI, and the National Space Biomedical Research Institute. Authors affiliated with Thomas Jefferson Medical College, PA; Tulane University School of Medicine, LA; Harvard Medical School, MA; Tufts Medical School, MA.)24604162
613 Stevens RG, Davis S. 1996. The melatonin hypothesis: electric power and breast cancer. Environ Health Perspect 104(Suppl 1): 135–140. (Supported by NCI and the US Department of Energy. Authors affiliated with Pacific Northwest Laboratory, WA; University of Washington, WA.)8722117
614 Stevens RG, Davis S, Mirick DK, Kheifets L, Kaune W. 2000. Alcohol consumption and urinary concentration of 6-sulfatoxymelatonin in healthy women. Epidemiology 11(6): 660–665. (Supported by the Electric Power Research Institute, NCI, and NIH. Authors affiliated with University of Connecticut Health Center, CT; Fred Hutchinson Cancer Research Center, WA; University of Washington, WA; Electric Power Research Institute, CA; EM Factors, WA.)11055626
615 Stevens RG, Davis S, Thomas DB, Anderson LE, Wilson BW. 1992. Electric power, pineal function, and the risk of breast cancer. FASEB J 6(3): 853–860. (Supported by the US Department of Energy. Authors affiliated with Pacific Northwest Laboratory, WA; Fred Hutchinson Cancer Research Center, WA.)1740235
616 Stevens RG, Hansen J, Costa G, Haus E, Kauppinen T, Aronson KJ, Castaño-Vinyals G, Davis S, Frings-Dresen MH, Fritschi L, Kogevinas M, Kogi K, Lie JA, Lowden A, Peplonska B, Pesch B, Pukkala E, Schernhammer E, Travis RC, Vermeulen R, Zheng T, Cogliano V, Straif K. 2011. Considerations of circadian impact for defining ‘shift work’ in cancer studies: IARC Working Group Report. Occup Environ Med 68(2): 154–162. (Supported by the Health and Safety Executive and the German Social Accident Insurance. Authors affiliated with University of Connecticut Health Center, CT; Danish Cancer Society, Denmark; University of Milan, Italy; University of Minnesota, MN; Finnish Institute of Occupational Health, Finland; Queen’s University, Canada; CREAL, Spain; IMIM-Hospital del Mar, Spain; Fred Hutchinson Cancer Research Center, WA; Academic Medical Center, Netherlands; University of Western Australia, Australia; Municipal Institute of Medical Research, Spain; Institute for Science of Labour, Japan; National Institute of Occupational Health, Norway; Stockholm University, Sweden; Nofer Institute of Occupational Medicine, Poland; Ruhr-University Bochum, Germany; Finnish Cancer Registry, Finland; Brigham and Women’s Hospital and Harvard Medical School, MA; University of Oxford, UK; University of Utrecht, Netherlands; Yale University School of Medicine, CT; IARC, France.)20962033
617 Stevens RG, Rea MS. 2001. Light in the built environment: potential role of circadian disruption in endocrine disruption and breast cancer. Cancer Causes Control 12(3): 279–287. (Supported by the US Department of Energy. Authors affiliated with University of Connecticut Health Center, CT; Rensselaer Polytechnic Institute, NY.)11405333
618 Stevens RG, Zhu Y. 2015. Electric light, particularly at night, disrupts human circadian rhythmicity: is that a problem? Philos Trans R Soc Lond B Biol Sci 370(1667). (Supported by the University of Connecticut and Yale University. Authors affiliated with University of Connecticut Health Center, CT; Yale University, CT.)
619 Storch KF, Lipan O, Leykin I, Viswanathan N, Davis FC, Wong WH, Weitz CJ. 2002. Extensive and divergent circadian gene expression in liver and heart. Nature 417(6884): 78–83. (Supported by the Edward R. and Anne G. Lefler Center, Harvard Medical School and the National Eye Institute, a Deutsche Forschungsgemeinschaft Postdoctoral Fellowship, the National Institute of Child Health and Human Development, and the National Human Genome Research Institute. Authors affiliated with Harvard Medical School, MA; Harvard School of Public Health, MA; Northeastern University, MA; Harvard University, MA.)11967526
620 Stranges S, Dorn JM, Shipley MJ, Kandala NB, Trevisan M, Miller MA, Donahue RP, Hovey KM, Ferrie JE, Marmot MG, Cappuccio FP. 2008. Correlates of short and long sleep duration: a cross-cultural comparison between the United Kingdom and the United States: the Whitehall II Study and the Western New York Health Study. Am J Epidemiol 168(12): 1353–1364. (Supported by the Medical Research Council, the British Heart Foundation, the United Kingdom Health and Safety Executive, the United Kingdom Department of Health, the US National Heart, Lung, and Blood Institute, the US National Institute on Aging, the Agency for Health Care Policy and Research, US Department of Health and Human Services, the John D. and Catherine T. MacArthur Foundation Research Networks on Successful Midlife Development and Socioeconomic Status and Health, the US National Institute on Alcohol Abuse and Alcoholism, and the US National Institutes of Health. Authors affiliated with University of Warwick Medical School, UK; State University of New York at Buffalo, NY; University College London Medical School, UK.)18945686
621 Sturgeon SR, Doherty A, Reeves KW, Bigelow C, Stanczyk FZ, Ockene JK, Liu S, Manson JE, Neuhouser ML. 2014. Urinary levels of melatonin and risk of postmenopausal breast cancer: Women’s health initiative observational cohort. Cancer Epidemiol Biomarkers Prev 23(4): 629–637. (Supported by NCI, the National Heart, Lung, and Blood Institute, NIH, and the U.S. Department of Health and Human Services. Authors affiliated with University of Massachusetts Amherst, MA; University of Massachusetts Medical School, MA; Harvard Medical School, MA; University of Southern California Keck School of Medicine, CA; Brown University, RI; Rhode Island Hospital, RI; Fred Hutchinson Cancer Research Center, WA.)24510738
622 Suba Z. 2012. Light deficiency confers breast cancer risk by endocrine disorders. Recent Pat Anticancer Drug Discov 7(3): 337–344. (Support not reported. Author affiliated with Surgical and Molecular Tumor Pathology Centre, Hungary.)22694289
623 Taheri S, Lin L, Austin D, Young T, Mignot E. 2004. Short sleep duration is associated with reduced leptin, elevated ghrelin, and increased body mass index. PLoS Med 1(3): e62. (Supported by NIH and the Howard Hughes Medical Institute. Authors affiliated with Stanford University, CA; University of Wisconsin, WI.)15602591
624 Tai SY, Huang SP, Bao BY, Wu MT. 2016. Urinary melatonin-sulfate/cortisol ratio and the presence of prostate cancer: A case-control study. Sci Rep 6: 29606. (Supported by the Kaohsiung Medical University Hospital, the Institute of Labor, Occupational Safety and Health, Ministry of Labor, the Ministry of Science and Technology, Taiwan’s National Health Research Institutes, and the Research Center for Environmental Medicine, Kaohsiung Medical University. Authors affiliated with Kaohsiung Medical University, Taiwan; Kaohsiung Municipal Ta-Tung Hospital, Taiwan; National Sun Yat-Sen University, Taiwan; China Medical University, Taiwan; China Medical University Hospital, Taiwan; Asia University, Taiwan; Kaohsiung Municipal Hsiao-Kang Hospital, Taiwan; Kaohsiung Medical University Hospital, Taiwan.)27387675
625 Takahashi JS, Hong HK, Ko CH, McDearmon EL. 2008. The genetics of mammalian circadian order and disorder: implications for physiology and disease. Nat Rev Genet 9(10): 764–775. (Support not reported. Authors affiliated with Northwestern University, IL)18802415
626 Talib WH. 2018. Melatonin and cancer hallmarks. Molecules 23(3): 518. (Supported by the Applied Science Private University, Amman, Jordan. Author affiliated with Applied Science Private University, Jordan.)
627 Talibov M, Pukkala E, Martinsen JI, Tryggvadottir L, Weiderpass E, Hansen J. 2018. Night-shift work and hematological cancers: a population based case-control study in three Nordic countries. Scand J Work Environ Health 44(3): 258–264. (No financial support recieved. Authors affiliated with University of Tampere, Finland; Finnish Cancer Registry, Finland; Cancer Registry of Norway, Norway; Icelandic Cancer Registry, Iceland; University of Iceland, Iceland; Karolinska Institutet, Sweden; University of Tromsø, Norway; Folkhälsan Research Center, Finland; Danish Cancer Society Research Center, Denmark.)29323398
628 Tamarkin L, Cohen M, Roselle D, Reichert C, Lippman M, Chabner B. 1981. Melatonin inhibition and pinealectomy enhancement of 7,12-dimethylbenz(a)anthracene-induced mammary tumors in the rat. Cancer Res 41(11 Pt 1): 4432–4436. (Support not reported. Authors affiliated with NIH, MD.)6796259
629 Taylor PJ, Pocock SJ. 1972. Mortality of shift and day workers 1956-68. Br J Ind Med 29(2): 201–207. (Support not reported. Authors affiliated with London School of Hygiene and Tropical Medicine, UK.)5021999
630 Teboul M, Barrat-Petit MA, Li XM, Claustrat B, Formento JL, Delaunay F, Lévi F, Milano G. 2005. Atypical patterns of circadian clock gene expression in human peripheral blood mononuclear cells. J Mol Med (Berl) 83(9): 693–699. (Supported by the Ministère de la Recherche, Association pour la Recherche sur le Cancer, and Fondation pour la Recherche Médicale. Authors affiliated with Université de Nice-Sophia Antipolis, France; Pôle universitaire St Jean D’Angely, France; Université Paris XI, France; Hôpital Neurocardiologique, France; Centre Antoine-Lacassagne, France.)16096739
631 Temneanu RO, Motoc A, Zugun FE, Folescu R, Lupuşoru CE, Zamfir CL. 2012. The relevance of circadian rhythms disruption on pulmonary SOD expression in rat. Rom J Morph Embryol 53(3): 789–793. (Support not reported. Authors affiliated with “Grigore T. Popa” University of Medicine and Pharmacy, Romania; “Victor Babeş” University of Medicine and Pharmacy, Romania.)
632 Thapan K, Arendt J, Skene DJ. 2001. An action spectrum for melatonin suppression: evidence for a novel non-rod, non-cone photoreceptor system in humans. J Physiol 535(Pt 1): 261–267. (Supported by EUBIOMED2. Authors affiliated with University of Surrey, UK.)11507175
633 Torpey E. 2015. Careers for Night Owls and Early Birds. U.S. Bureau of Labor Statistics. Published on 10/15. https://www.bls.gov/careeroutlook/2015/article/night-owls-and-early-birds.htm
634 Touitou Y, Motohashi Y, Reinberg A, Touitou C, Bourdeleau P, Bogdan A, Auzéby A. 1990. Effect of shift work on the night-time secretory patterns of melatonin, prolactin, cortisol and testosterone. Eur J Appl Physiol Occup Physiol 60(4): 288–292. (Supported by le Conseil Scientifique de l’Université P. et M. Curie [Formation recommandée par la Direction de la Recherche] and Caisse Nationale d’Assurance Maladie des Travailleurs Salariés. Authors affiliated with Faculté de Médecine Pitié-Salpêtrière, France; CNRS, France; Service Médical Shell Française, France.)2357985
635 Touitou Y, Reinberg A, Touitou D. 2017. Association between light at night, melatonin secretion, sleep deprivation, and the internal clock: Health impacts and mechanisms of circadian disruption. Life Sci 173: 94–106. (Support not reported. Authors affiliated with Fondation Ophtalmologique A. de Rothschild, France; UHSA - Groupe Hospitalier Paul Guiraud, France.)28214594
636 Touvier M, Chan DS, Lau R, Aune D, Vieira R, Greenwood DC, Kampman E, Riboli E, Hercberg S, Norat T. 2011. Meta-analyses of vitamin D intake, 25-hydroxyvitamin D status, vitamin D receptor polymorphisms, and colorectal cancer risk. Cancer Epidemiol Biomarkers Prev 20(5): 1003–1016. (Supported by the World Cancer Research Fund. Authors affiliated with Imperial College London, UK; INSERM/INRA/CNAM/Paris13 University, France; University of Leeds, UK; Wageningen University and Research Centre, Netherlands.)21378269
637 Travis RC, Balkwill A, Fensom GK, Appleby PN, Reeves GK, Wang XS, Roddam AW, Gathani T, Peto R, Green J, Key TJ, Beral V. 2016. Night shift work and breast cancer incidence: Three prospective studies and meta-analysis of published studies. J Natl Cancer Inst 108(12): djw169. (Supported by the UK Health and Safety Executive, Cancer Research UK, and the Medical Research Council. Authors affiliated with University of Oxford, UK; GlaxoSmithKline R&D, UK; Oxford University Hospitals NHS Trust, UK.)27758828
638 Travis RC, Reeves GK, Peto R, Key TJ, Beral V. 2017. Response. J Natl Cancer Inst 109(4): djx008. (Support not reported. Authors affiliated with University of Oxford, UK.)
639 Travlos GS, Wilson RE, Murrell JA, Chignell CF, Boorman GA. 2001. The effect of short intermittent light exposures on the melatonin circadian rhythm and NMU-induced breast cancer in female F344/N rats. Toxicol Pathol 29(1): 126–136. (Support not reported. Authors affiliated with NIEHS, NC; Analytical Sciences, Inc., NC.)11215676
640 Trivedi AK, Kumar V. 2014. Melatonin: an internal signal for daily and seasonal timing. Indian J Exp Biol 52(5): 425–437. (Support not reported. Authors affiliated with University of Delhi, India.)24851405
641 Truong T, Liquet B, Menegaux F, Plancoulaine S, Laurent-Puig P, Mulot C, Cordina-Duverger E, Sanchez M, Arveux P, Kerbrat P, Richardson S, Guénel P. 2014. Breast cancer risk, nightwork, and circadian clock gene polymorphisms. Endocr Relat Cancer 21(4): 629–638. (Supported by the French National Institute of Cancer, the Fondation de France, the French Agency for Environmental and Occupational Health Safety [ANSES – ex-AFSSET], the French National Research Agency [ANR], and the League against Cancer. Authors affiliated with INSERM, France; Université Paris-Sud, France; MRC, UK; University of Queensland, Australia; Université Paris Descartes, France; Center Georges-François Leclerc, France; Center Eugène Marquis, France.)24919398
642 Tsai RJ, Luckhaupt SE, Sweeney MH, Calvert GM. 2014. Shift work and cancer screening: do females who work alternative shifts undergo recommended cancer screening? Am J Ind Med 57(3): 265–275. (Supported by the U.S. government. Authors affiliated with NIOSH, OH.)24488817
643 Tse LA, Lee PMY, Ho WM, Lam AT, Lee MK, Ng SSM, He Y, Leung KS, Hartle JC, Hu H, Kan H, Wang F, Ng CF. 2017. Bisphenol A and other environmental risk factors for prostate cancer in Hong Kong. Environ Int 107: 1–7. (Supported by the Health and Medical Research Fund, Hong Kong Special Administrative Region, China. Authors affiliated with Chinese University of Hong Kong, China; Prince of Wales Hospital, China; Guilin Medical College, China; Hong Kong Polytechnic University, China; San Jose State University, CA; University of Toronto, Canada; Fudan University, China.)28644961
644 Tucker P, Folkard S. 2012. Working Time, Health and Safety: A Research Synthesis Paper. Conditions of Work and Employment Series No. 31. Geneva: International Labour Office. 67 pp. https://ideas.repec.org/p/ilo/ilowps/994704513402676.html.
645 Turek FW. 2016. Circadian clocks: Not your grandfather’s clock. Science 354(6315): 992–993. (Support not reported. Author affiliated with Northwestern University, IL.)27885003
646 Turek FW, Joshu C, Kohsaka A, Lin E, Ivanova G, McDearmon E, Laposky A, Olson S, Easton A, Jensen DR, Eckel RH, Takahashi JS, Bass J. 2005. Obesity and metabolic syndrome in circadian Clock mutant mice. Science 308(5724): 1043–1045. (Supported by NIH. Authors affiliated with Northwestern University and the Feinberg School of Medicine, IL; ENH Research Institute, IL; Howard Hughes Medical Institute, MD; University of Colorado Medical School, CO.)15845877
647 Turner PL, Mainster MA. 2008. Circadian photoreception: ageing and the eye’s important role in systemic health. Br J Ophthalmol 92(11): 1439–1444. (Supported by Advanced Medical Optics, Incorporated. Authors affiliated with University of Kansas School of Medicine, KS.)18757473
648 Tynes T, Hannevik M, Andersen A, Vistnes AI, Haldorsen T. 1996. Incidence of breast cancer in Norwegian female radio and telegraph operators. Cancer Causes Control 7(2): 197–204. (Support not reported. Authors affiliated with Cancer Registry of Norway, Norway; Radiation Protection Authority, Norway; University of Oslo, Norway.)8740732
649 Ulas T, Buyukhatipoglu H, Kirhan I, Dal MS, Eren MA, Hazar A, Demir ME, Aydogan T, Karababa F, Uyanikoglu A, Kurkcuoglu IC. 2012. The effect of day and night shifts on oxidative stress and anxiety symptoms of the nurses. Eur Rev Med Pharmacol Sci 16(5): 594–599. (Support not reported. Authors affiliated with Harran University, Turkey; Dicle University, Turkey.)22774399
650 Ulhôa MA, Marqueze EC, Burgos LG, Moreno CR. 2015. Shift work and endocrine disorders. Int J Endocrinol 2015: 826249. (Supported by FAPESP. Authors affiliated with UNEC, Brazil; IMES, Brazil; Catholic University of Santos, Brazil; University of São Paulo, Brazil; Stockholm University, Sweden.)25892993
651 UNESCO. 2015. About the Year of Light. United Nations Educational, Scientific, and Cultural Organization. Last accessed: 3/21/18. http://www.light2015.org/Home/About.html
652 Ünsal-Kaçmaz K, Mullen TE, Kaufmann WK, Sancar A. 2005. Coupling of human circadian and cell cycles by the timeless protein. Mol Cell Biol 25(8): 3109–3116. (Supported by NIH, NCI, and NIEHS. Authors affiliated with University of North Carolina, NC.)15798197
653 Uth K, Sleigh R. 2014. Deregulation of the circadian clock constitutes a significant factor in tumorigenesis: a clockwork cancer. Part I: clocks and clocking machinery. Biotechnol Biotechnol Equip 28(2): 176–183. (Support not reported. Authors affiliated with CMCBR, UK.)26019503
654 Uzoigwe CE, Sanchez Franco LC. 2018. Night shifts: chronotype and social jetlag. BMJ 361: k1666. (Support not reported. Authors affiliated with Harcourt House, UK; Stepping Hill Hospital, UK.)29666053
655 van den Heiligenberg S, Deprés-Brummer P, Barbason H, Claustrat B, Reynes M, Lévi F. 1999. The tumor promoting effect of constant light exposure on diethylnitrosamine-induced hepatocarcinogenesis in rats. Life Sci 64(26): 2523–2534. (Supported by INSERM, ARTBC, Hôpital Paul Brousse, and the “Dr. Saal van Zwanenbergstichting.” Authors affiliated with Université Paris XI, France; Hôpital Paul Brousse, France; Hôpital Neurocardiologique, France; Service de Cancérologie Expérimentale, Belgium.)10403512
656 van der Lely S, Frey S, Garbazza C, Wirz-Justice A, Jenni OG, Steiner R, Wolf S, Cajochen C, Bromundt V, Schmidt C. 2015. Blue blocker glasses as a countermeasure for alerting effects of evening light-emitting diode screen exposure in male teenagers. J Adolesc Health 56(1): 113–119. (Supported by Jacobs Foundation, Zurich, Switzerland. Authors affiliated with Psychiatric Hospital of the University of Basel, Switzerland; University Children’s Hospital Zürich, Switzerland; University of Basel, Switzerland; Ilmenau University of Technology, Germany.)25287985
657 Van der Maren S, Moderie C, Duclos C, Paquet J, Daneault V, Dumont M. 2018. Daily profiles of light exposure and evening use of light-emitting devices in young adults complaining of a delayed sleep schedule. J Biol Rhythms 33(2): 192–202. (Supported by the Natural Sciences and Engineering Research Council of Canada, the Université de Montréal, Fonds de la Recherche du Québec-Santé [FRQS], and NSERC. Authors affiliated with Sacre-Coeur Hospital of Montreal, Canada; University of Montreal, Canada.)29463186
658 Van Dycke KC, Rodenburg W, van Oostrom CT, van Kerkhof LW, Pennings JL, Roenneberg T, van Steeg H, van der Horst GT. 2015. Chronically alternating light cycles increase breast cancer risk in mice. Curr Biol 25(14): 1932–1937. (Supported by the RIVM Strategic Programme and the Dutch Ministry of Social Affairs and Employment. Authors affiliated with National Institute for Public Health and the Environment, Netherlands; Erasmus University Medical Center, Netherlands; Ludwig-Maximilian University, Germany; Leiden University Medical Center, Netherlands.)26196479
659 van Mark A, Weiler SW, Schröder M, Otto A, Jauch-Chara K, Groneberg DA, Spallek M, Kessel R, Kalsdorf B. 2010. The impact of shift work induced chronic circadian disruption on IL-6 and TNF-α immune responses. J Occup Med Toxicol 5: 18. (Support not reported. Authors affiliated with University of Lübeck, Germany; AUDI AG Ingolstadt, Germany; Free University and Humboldt-University, Germany; EUGT, Germany; Research Center Borstel, Germany.)20602750
660 VanderWeele DJ, Brown CD, Taxy JB, Gillard M, Hatcher DM, Tom WR, Stadler WM, White KP. 2014. Low-grade prostate cancer diverges early from high grade and metastatic disease. Cancer Sci 105(8): 1079–1085. (Supported by the AACI Fellowship for Translational Cancer Research and DOD Prostate Cancer Research Program PRTA and the Chicago Cancer Genomes Project. Authors affiliated with University of Chicago, IL; University of Pennsylvania, PA; NorthShore University Health System, IL.)24890684
661 Vangelova KK. 2008. Variations of cortisol, fatigue and sleep disturbances in sound engineers: effect of job task and fast backward-rotating shifts. Rev Environ Health 23(1): 83–89. (Support not reported. Authors affiliated with National Center of Public Health Protection, Bulgaria.)18557600
662 Verkasalo PK, Pukkala E, Stevens RG, Ojamo M, Rudanko SL. 1999. Inverse association between breast cancer incidence and degree of visual impairment in Finland. Br J Cancer 80(9): 1459–1460. (Supported by the Academy of Finland, the Finnish Cancer Foundation, and the US Department of Energy. Authors affiliated with University of Helsinki, Finland; National Public Health Institute, Finland; Finnish Cancer Registry, Finland; Pacific Northwest National Laboratory, WA; Finnish Register of Visual Impairment, Finland.)10424751
663 Vermeulen R. 2016. Types and Characteristics of Shift Work and the Concept of Shift Work as a Complex Exposure Scenario. Universitat Utrecht, Institute for Risk Assessment Science. 26 pp.
664 Vinogradova IA, Anisimov VN, Bukalev AV, Ilyukha VA, Khizhkin EA, Lotosh TA, Semenchenko AV, Zabezhinski MA. 2010. Circadian disruption induced by light-at-night accelerates aging and promotes tumorigenesis in young but not in old rats. Aging (Albany NY) 2(2): 82–92. (Supported by the President of the Russian Federation and the Russian Foundation for Basic Research. Authors affiliated with Petrozavodsk State University, Russia; N.N. Petrov Research Institute of Oncology, Russia; Russian Academy of Sciences, Russia.)20354269
665 Vinogradova IA, Anisimov VN, Bukalev AV, Semenchenko AV, Zabezhinski MA. 2009. Circadian disruption induced by light-at-night accelerates aging and promotes tumorigenesis in rats. Aging (Albany NY) 1(10): 855–865. (Supported by the President of the Russian Federation, the Russian Foundation for Basic Research, and the Russian Foundation for Humanistic Research. Authors affiliated with Petrozavodsk State University, Russia; N.N. Petrov Research Institute of Oncology, Russia.)20157558
666 Vinogradova IA, Chernova IV. 2006. [Effect of light regimens on the age dynamics of estrous function and serum prolactin level in rats]. Adv Gerontol 19: 60–65. (Support unknown due to foreign language. Authors affiliated with Petrozavodsk State University, Russia.)17152722
667 Viola AU, James LM, Schlangen LJ, Dijk DJ. 2008. Blue-enriched white light in the workplace improves self-reported alertness, performance and sleep quality. Scand J Work Environ Health 34(4): 297–306. (Supported by Philips Lighting. Authors affiliated with University of Surrey, UK; Philips Lighting, Netherlands.)18815716
668 Vistisen HT, Garde AH, Frydenberg M, Christiansen P, Hansen AM, Andersen J, Bonde JP, Kolstad HA. 2017. Short-term effects of night shift work on breast cancer risk: a cohort study of payroll data. Scand J Work Environ Health 43(1): 59–67. (Supported by the Danish Work Environment Research Fund and NordForsk, Nordic Program on Health and Welfare. Authors affiliated with Aarhus University Hospital, Denmark; National Research Centre for the Working Environment, Denmark; Aarhus University, Denmark; Danish Breast Cancer Corporative Group, Denmark; University of Copenhagen, Denmark; Danish Cancer Society Research Center, Denmark; Bispebjerg University Hospital, Denmark.)27841916
669 Viswanathan AN, Hankinson SE, Schernhammer ES. 2007. Night shift work and the risk of endometrial cancer. Cancer Res 67(21): 10618–10622. (Supported by NIH. Authors affiliated with Dana-Farber Cancer Institute, MA; Harvard Medical School, MA; Brigham and Women’s Hospital, MA; Applied Cancer Research-Institute for Translational Research Vienna, Austria; Harvard School of Public Health, MA.)17975006
670 VoPham T, Weaver MD, Vetter C, Hart JE, Tamimi RM, Laden F, Bertrand KA. 2018. Circadian misalignment and hepatocellular carcinoma incidence in the United States. Cancer Epidemiol Biomarkers Prev 27(7): 719–727. (Supported by NIH and NHLBI. Authors affiliated with Harvard T.H. Chan School of Public Health, MA; Brigham and Women’s Hospital, MA; Harvard Medical School, MA; University of Colorado, CO; Broad Institute of Harvard and MIT, MA; Slone Epidemiology Center at Boston University, MA.)29636342
671 Wada K, Nakamura K, Tamai Y, Tsuji M, Masue T, Watanabe K, Ando K, Nagata C. 2013. Associations of urinary 6-sulfatoxymelatonin with demographics, body mass, sex steroids, and lifestyle factors in preschool Japanese children. Ann Epidemiol 23(2): 60–65. (Supported by the Ministry of Education, Culture, Sports, Science, and Technology and the Ministry of Health, Labor, and Welfare of Japan. Authors affiliated with Gifu University Graduate School of Medicine, Japan; Aichi Bunkyo Women’s College, Japan.)23266102
672 Wahnschaffe A, Haedel S, Rodenbeck A, Stoll C, Rudolph H, Kozakov R, Schoepp H, Kunz D. 2013. Out of the lab and into the bathroom: evening short-term exposure to conventional light suppresses melatonin and increases alertness perception. Int J Mol Sci 14(2): 2573–2589. (Supported by BMBF. Authors affiliated with Charité–Universitätsmedizin Berlin, Germany; Trilux GmbH & Co.KG, Germany; Leibniz Institute for Plasma Science and Technology, Germany; German Heart Institute, Germany.)23358248
673 Walasa WM, Carey RN, Si S, Fritschi L, Heyworth JS, Fernandez RC, Boyle T. 2018. Association between shiftwork and the risk of colorectal cancer in females: a population-based case-control study. Occup Environ Med 75: 344–350. (Supported by the Australian National Health and Medical Research Council, the University of Adelaide, NHMRC, Canadian Institutes of Health Research, and the Cancer Council Western Australia. Authors affiliated with Curtin University, Australia; University of Western Australia, Australia; University of Adelaide, Australia; University of South Australia, Australia.)29438001
674 Waldrop RD, Saydjari R, Rubin NH, Rayford PL, Townsend CM, Jr., Thompson JC. 1989. Photoperiod influences the growth of colon cancer in mice. Life Sci 45(8): 737–744. (Support not reported. Authors affiliated with University of Texas Medical Branch, TX; University of Arkansas for Medical Sciences Little Rock, AR.)2506401
675 Wang F, Yeung KL, Chan WC, Kwok CC, Leung SL, Wu C, Chan EY, Yu IT, Yang XR, Tse LA. 2013. A meta-analysis on dose-response relationship between night shift work and the risk of breast cancer. Ann Oncol 24(11): 2724–2732. (Supported by the Research Grants Council of Hong Kong. Authors affiliated with Chinese University of Hong Kong, China; North District Hospital, China; Princess Margaret Hospital, China; Yan Chai Hospital, China; NCI, MD.)23975662
676 Wang P, Ren FM, Lin Y, Su FX, Jia WH, Su XF, Tang LY, Ren ZF. 2015a. Night-shift work, sleep duration, daytime napping, and breast cancer risk. Sleep Med 16(4): 462–468. (Supported by the National Natural Science Foundation of China and the Guangdong Provincial Natural Science Foundation. Authors affiliated with Sun Yat-sen University, China; Chinese University of Hong Kong, China; CUHK Shenzhen Research Institute, China.)25794454
677 Wang X, Ji A, Zhu Y, Liang Z, Wu J, Li S, Meng S, Zheng X, Xie L. 2015b. A meta-analysis including dose-response relationship between night shift work and the risk of colorectal cancer. Oncotarget 6(28): 25046–25060. (Supported by the National Natural Science Foundation of China, the Scientific research foundation of the ministry of public health, and the Zhejiang province key project of science and technology. Authors affiliated with Zhejiang University, China.)26208480
678 Wang XS, Armstrong ME, Cairns BJ, Key TJ, Travis RC. 2011. Shift work and chronic disease: the epidemiological evidence. Occup Med (Lond) 61(2): 78–89. (Supported by the Health and Safety Executive, UK, Cancer Research UK, and the Medical Research Council, UK. Authors affiliated with University of Oxford, UK.)21355031
679 Wang XS, Tipper S, Appleby PN, Allen NE, Key TJ, Travis RC. 2014. First-morning urinary melatonin and breast cancer risk in the guernsey study. Am J Epidemiol 179(5): 584–593. (Supported by Cancer Research UK and the Lloyds TSB Charitable Foundation for the Channel Islands. Authors affiliated with University of Oxford, UK.)24418683
680 Waters MA, Grajewski B, Pinkerton LE, Hein MJ, Zivkovich Z. 2009. Development of historical exposure estimates of cosmic radiation and circadian rhythm disruption for cohort studies of Pan Am flight attendants. Am J Ind Med 52(10): 751–761. (Support not reported. Authors affiliated with NIOSH, OH.)19722196
681 WCRF. 2018. Continuous Update Project: Diet, Nutrition, Physical Activity and Breast Cancer. World Cancer Research Fund/American Institute for Cancer Research. Last accessed: 5/4/18. http://dietandcancerreport.org
682 WebFinance. 2018. Compressed Workweek. WebFinance, Inc. Last accessed: 6/14/18. http://www.businessdictionary.com/definition/compressed-workweek.html
683 Wegrzyn LR, Tamimi RM, Rosner BA, Brown SB, Stevens RG, Eliassen AH, Laden F, Willett WC, Hankinson SE, Schernhammer ES. 2017. Rotating night shift work and risk of breast cancer in the nurses’ health studies. Am J Epidemiol 186(5): 532–540. (Supported by the CDC, NIOSH, and NIH. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard T.H. Chan School of Public Health, MA; University of Massachusetts, MA; University of Connecticut Health Center, CT; Medical University of Vienna, Austria; Applied Cancer Research-Institution for Translational Research Vienna, Austria.)28541391
684 Wehrens SMT, Christou S, Isherwood C, Middleton B, Gibbs MA, Archer SN, Skene DJ, Johnston JD. 2017. Meal timing regulates the human circadian system. Curr Biol 27(12): 1768–1775. (Supported by the UK Biotechnology and Biological Sciences Research Council. Authors affiliated with University of Surrey, UK.)28578930
685 Weibel L, Brandenberger G. 1998. Disturbances in hormonal profiles of night workers during their usual sleep and work times. J Biol Rhythms 13(3): 202–208. (Support not reported. Authors affiliated with Institut de Physiologie-Faculté de Médecine, France)9615284
686 Wendeu-Foyet MG, Bayon V, Cénée S, Trétarre B, Rébillard X, Cancel-Tassin G, Cussenot O, Lamy PJ, Faraut B, Kheder SB, Léger D, Menegaux F. 2018. Night work and prostate cancer risk: Results from the EPICAP study. OEM 75(8): 573–581. (Supported by the Institut National du Cancer, Fondation ARC, the Ligue nationale contre le cancer, the Ligue contre le cancer du Val-de-Marne, Fondation de France, Agence nationale de sécurité sanitaire de l’alimentation, de l’environnement et du travail [ANSES], and Paris-Sud University. Authors affiliated with INSERM, France; Hôtel Dieu, France; VIFASOM, France; Hérault Cancer Registry, France; Clinique Beau Soleil, France; Hopital Tenon, France; Sorbonne Université, France; Imagenome, France.)
687 White AJ, Weinberg CR, Park YM, D’Aloisio AA, Vogtmann E, Nichols HB, Sandler DP. 2017. Sleep characteristics, light at night and breast cancer risk in a prospective cohort. Int J Cancer 141(11): 2204–2214. (Supported by NIH. Authors affiliated with NIEHS, NC; NIH, NC; Social & Scientific Systems, Inc., NC; University of North Carolina, NC.)28791684
688 Wille JJ, Jr. 2003. Circadian rhythm of tumor promotion in the two-stage model of mouse tumorigenesis. Cancer Lett 190(2): 143–149. (Supported by NIDDK. Author affiliated with Southern Research Institute, AL.)12565168
689 Winter M, Blettner M, Zeeb H. 2014. Prevalence of risk factors for breast cancer in German airline cabin crew: a cross-sectional study. J Occup Med Toxicol 9: 27. (Support not reported. Authors affiliated with Johannes Gutenberg University Mainz, Germany; Leibniz Institute for Prevention Research and Epidemiology-BIPS, Germany; University of Bremen, Germany.)25067940
690 Wirth MD, Andrew ME, Burchfiel CM, Burch JB, Fekedulegn D, Hartley TA, Charles LE, Violanti JM. 2017. Association of shiftwork and immune cells among police officers from the Buffalo Cardio-Metabolic Occupational Police Stress study. Chronobiol Int: 1–11. (Supported by NIOSH. Authors affiliated with University of South Carolina, SC; Connecting Health Innovations, SC; NIOSH, WV; WJB Dorn VA Medical Center, SC; State University of New York, NY.)
691 Wirth MD, Burch J, Shivappa N, Steck SE, Hurley TG, Vena JE, Hébert JR. 2014a. Dietary inflammatory index scores differ by shift work status: NHANES 2005 to 2010. J Occup Environ Med 56(2): 145–148. (Supported by the South Carolina Statewide Cancer Prevention and Control Program, NCI, and the University of South Carolina Office of Research and by the South Carolina Cancer. Authors affiliated with University of South Carolina, SC; WJB Dorn VA Medical Center, SC; University of Georgia, GA.)24451608
692 Wirth MD, Burch J, Shivappa N, Violanti JM, Burchfiel CM, Fekedulegn D, Andrew ME, Hartley TA, Miller DB, Mnatsakanova A, Charles LE, Steck SE, Hurley TG, Vena JE, Hébert JR. 2014b. Association of a dietary inflammatory index with inflammatory indices and metabolic syndrome among police officers. J Occup Environ Med 56(9): 986–989. (Supported by NIOSH, the University of South Carolina Office of Research and by the South Carolina Cancer Prevention and Control Research Network funded under a Cooperative Agreement from the Centers for Disease Control and Prevention and the National Cancer Institute. Authors affiliated with University of South Carolina, SC; WJB Dorn VA Medical Center, SC; State University of New York, NY; CDC, WV; University of Georgia, GA.)25046320
693 Wittenbrink N, Ananthasubramaniam B, Münch M, Koller B, Maier B, Weschke C, Bes F, de Zeeuw J, Nowozin C, Wahnschaffe A, Wisniewski S, Zaleska M, Bartok O, Ashwal-Fluss R, Lammert H, Herzel H, Hummel M, Kadener S, Kunz D, Kramer A. 2018. High-accuracy determination of internal circadian time from a single blood sample. J Clin Invest 128(9): 3826–3839. (Supported by the Bundesministerium für Bildung und Forschung, Germany, and Intellux Berlin GmbH, Germany. Authors affiliated with Charité Universitätsmedizin Berlin, Germany; Humboldt-Universität zu Berlin, Germany; St-Hedwig-Krankenhaus, Germany; Intellux Berlin GmbH, Germany; Hebrew University, Israel; Brandeis University, MA; )29953415
694 Wood B, Rea MS, Plitnick B, Figueiro MG. 2013. Light level and duration of exposure determine the impact of self-luminous tablets on melatonin suppression. Appl Ergon 44(2): 237–240. (Supported by Sharp Laboratories of America. Authors affiliated with Rensselaer Polytechnic Institute, NY.)22850476
695 Wood PA, Yang X, Taber A, Oh EY, Ansell C, Ayers SE, Al-Assaad Z, Carnevale K, Berger FG, Peña MM, Hrushesky WJ. 2008. Period 2 mutation accelerates Apc^Min/+^ tumorigenesis. Mol Cancer Res 6(11): 1786–1793. (Supported by the NIH Centers of Biomedical Research Excellence [COBRE] and COBRE Pathology and Animal Core. Authors affiliated with University of South Carolina, SC.)19010825
696 Wu AH, Stanczyk FZ, Wang R, Koh WP, Yuan JM, Yu MC. 2013. Sleep duration, spot urinary 6-sulfatoxymelatonin levels and risk of breast cancer among Chinese women in Singapore. Int J Cancer 132(4): 891–896. (Supported by NCI. Authors affiliated with University of Southern California Keck School of Medicine, CA; University of Pittsburgh Cancer Institute, PA; National University of Singapore, Singapore.)22644618
697 Wu G, Ruben MD, Schmidt RE, Francey LJ, Smith DF, Anafi RC, Hughey JJ, Tasseff R, Sherrill JD, Oblong JE, Mills KJ, Hogenesch JB. 2018. Population-level rhythms in human skin with implications for circadian medicine. Proc Natl Acad Sci U S A. (Supported by Proctor and Gamble, the National Institute of Neurological Disorders and Stroke, the National Human Genome Research Institute, the Defense Advanced Research Projects Agency, and the National Institute of General Medical Sciences. Authors affiliated with Cincinnati Children’s Hospital Medical Center, OH; University of Cincinnati School of Medicine, OH; Perelman School of Medicine at the University of Pennsylvania, PA; Vanderbilt University School of Medicine, TN; Procter & Gamble Company, OH.)
698 Wu J, Dauchy RT, Tirrell PC, Wu SS, Lynch DT, Jitawatanarat P, Burrington CM, Dauchy EM, Blask DE, Greene MW. 2011. Light at night activates IGF-1R/PDK1 signaling and accelerates tumor growth in human breast cancer xenografts. Cancer Res 71(7): 2622–2631. (Supported by the Stephen C. Clark Fund, E. Donnall Thomas Resident Research Fund, the American Association for Laboratory Animal Science Grants for Laboratory Animal Science [GLAS] Award, and a Tulane University School of Medicine and Louisiana Cancer Research Consortium Startup Grant. Authors affiliated with Bassett Healthcare Network, NY; Tulane University School of Medicine and Tulane Cancer Center, LA.)21310824
699 Wu J, Sánchez de la Peña S, Halberg F, Cornélissen G, Wetterberg L, Halberg E, Lakatua D, Bingham C, Harvey J, Bazin H, Zheng T, Leung B, Tran B. 1988. Chronosynergistic effects of lighting schedule-shift and cefodizime on plasmacytoma growth and host survival time. Chronobiologia 15(1–2): 105–128. (Supported by the U.S. Public Health Service, Colin Medical Instruments, Komaki, Japan, Hoechst Foundation, Milan, Italy, Medtronic Inc., Minneapolis, MN, USA, Minnesota Medical Foundation, Earl Bakken and Dr. Betty Sullivan Funds. Authors affiliated with Chengdu College of Traditional Chinese Medicine, China; University of Minnesota, MN; St. Göran’s Hospital and Karolinska Institute, Sweden; St. Paul-Ramsey Medical Center, MN; Université Catholique de Louvain, Belgium; Beijing University of Medical Sciences, China.)3416672
700 Wu M, Zeng J, Chen Y, Zeng Z, Zhang J, Cai Y, Ye Y, Fu L, Xian L, Chen Z. 2012. Experimental chronic jet lag promotes growth and lung metastasis of Lewis lung carcinoma in C57BL/6 mice. Oncol Rep 27(5): 1417–1428. (Supported by the National Natural Science Foundation of China and the Scientific Research Foundation for the Returned Overseas Chinese Scholars, State Education Ministry of China. Authors affiliated with Sun Yat-Sen University, China.)22344888
701 Wu MW, Cai YC, Sun JA, Yang H, Li JL, Wang L, Zhang JX, Zhu L, Xian LJ. 2010. Effects of experimental chronic jet lag on hematological and immune parameters in mice. Biol Rhythm Res 41(5): 363–378. (Supported by the National Natural Science Foundation of China, and by the Scientific Research Foundation for the Returned Overseas Chinese Scholars, State Education Ministry, PR China. Authors affiliated with Sun Yat-sen University, China; Guangxi Medical University, China.)
702 Wu MW, Li XM, Xian LJ, Lévi F. 2004. Effects of meal timing on tumor progression in mice. Life Sci 75(10): 1181–1193. (Supported by the Programme de Recherches Avancées de Coopération Franco-Chinoises, INSERM ARTBC, Hôpital Paul Brousse, and the Villejuif [France] Clinical Key Program of the Ministry of Public Health of P.R. China. Authors affiliated with ISERM, France; Sun Yat-sen University, China.)15219806
703 Xiao Q, Signorello LB, Brinton LA, Cohen SS, Blot WJ, Matthews CE. 2016. Sleep duration and breast cancer risk among black and white women. Sleep Med 20: 25–29. (Supported by the Intramural Research Program of the National Institutes of Health, National Cancer Institute, National Institutes of Health, Department of Health and Human Services. Authors affiliated with NIH, MD; International Epidemiology Institute, MD; Vanderbilt University Medical Center, TN.)27318222
704 Yamazaki S, Numano R, Abe M, Hida A, Takahashi R, Ueda M, Block GD, Sakaki Y, Menaker M, Tei H. 2000. Resetting central and peripheral circadian oscillators in transgenic rats. Science 288(5466): 682–685. (Supported by NIH, the Japanese Ministry of Education, Science, Sports, and Culture, and the Japanese Ministry of Health and Welfare. Authors affiliated with University of Virginia, VA; University of Tokyo, Japan; Y.S. New Technology Institute Inc., Japan.)10784453
705 Yang WS, Deng Q, Fan WY, Wang WY, Wang X. 2014. Light exposure at night, sleep duration, melatonin, and breast cancer: a dose-response analysis of observational studies. Eur J Cancer Prev 23(4): 269–276. (Supported by Health Science and Technology Project from Jiangxi Provincial Health Department of China. Authors affiliated with Jiujiang University, China.)24858716
706 Yang X, Wood PA, Ansell CM, Quiton DF, Oh EY, Du-Quiton J, Hrushesky WJ. 2009a. The circadian clock gene Per1 suppresses cancer cell proliferation and tumor growth at specific times of day. Chronobiol Int 26(7): 1323–1339. (Support not reported. Authors affiliated with WJB Dorn Veterans Affairs Medical Center, SC; University of South Carolina, SC.)19916834
707 Yang X, Wood PA, Oh EY, Du-Quiton J, Ansell CM, Hrushesky WJ. 2009b. Down regulation of circadian clock gene Period 2 accelerates breast cancer growth by altering its daily growth rhythm. Breast Cancer Res Treat 117(2): 423–431. (Support not reported. Authors affiliated with WJB Dorn VA Medical Center, SC; University of South Carolina, SC.)18651214
708 Yasuniwa Y, Izumi H, Wang K-Y, Shimajiri S, Sasaguri Y, Kawai K, Kasai H, Shimada T, Miyake K, Kashiwagi E, Hirano G, Kidani A, Akiyama M, Han B, Wu Y, Ieiri I, Higuchi S, Kohno K. 2010. Circadian disruption accelerates tumor growth and angio/stromagenesis through a wnt signaling pathway. PLoS One 5(12): e15330. (Supported by KAKENHI and the UOEH Grants for Advanced Research and the Vehicle Racing Commemorative Foundation. Authors affiliated with University of Occupational and Environmental, Japan; Kyushu University, Japan; Nihon Medical School, Japan; China Medical University, China.)21203463
709 Yeh CR, Da J, Song W, Fazili A, Yeh S. 2014. Estrogen receptors in prostate development and cancer. Am J Clin Exp Urol 2(2): 161–168. (Support not reported. Authors affiliated with University of Rochester Medical Center, NY.)25374919
710 Yong LC, Li J, Calvert GM. 2017. Sleep-related problems in the US working population: prevalence and association with shiftwork status. Occup Environ Med 74(2): 93–104. (Support not reported. Authors affiliated with NIOSH, OH.)27609325
711 Yong M, Blettner M, Emrich K, Nasterlack M, Oberlinner C, Hammer GP. 2014a. A retrospective cohort study of shift work and risk of incident cancer among German male chemical workers. Scand J Work Environ Health 40(5): 502–510. (Supported by the Deutsche Gesetzliche Unfallversicherung. Authors affiliated with BASF SE, Germany; Johannes Gutenberg University Mainz, Germany; Laboratoire National de Santé, Luxembourg.)24892305
712 Yong M, Fischer D, Germann C, Lang S, Vetter C, Oberlinner C. 2016. Are chronotype, social jetlag and sleep duration associated with health measured by Work Ability Index? Chronobiol Int 33(6): 721–729. (Support not reported. Authors affiliated with BASF Societas Europaea, Germany; Ludwig-Maximilians-University, Germany; Brigham and Women’s Hospital and Harvard Medical School, MA.)27092579
713 Yong M, Nasterlack M, Messerer P, Oberlinner C, Lang S. 2014b. A retrospective cohort study of shift work and risk of cancer-specific mortality in German male chemical workers. Int Arch Occup Environ Health 87(2): 175–183. (Support not reported. Authors affiliated with BASF Societas Europaea, Germany.)23377535
714 Zeitzer JM, Dijk DJ, Kronauer R, Brown E, Czeisler C. 2000. Sensitivity of the human circadian pacemaker to nocturnal light: melatonin phase resetting and suppression. J Physiol 526 Pt 3: 695–702. (Supported by the National Aeronautics and Space Administration, the National Institute of Mental Health, National Heart, Lung, and Blood Institute, the National Institute on Aging, National Space Biomedical Research Institute, the National Institute of General Medical Sciences, the General Clinical Research Center Program of the National Center for Research Resources, and a Phillips fellowship. Authors affiliated with Harvard Medical School, MA; Brigham and Women’s Hospital, MA; Harvard University, MA; Massachusetts General Hospital, MA; MIT Division of Health Sciences and Technology, MA.)10922269
715 Zeng ZL, Wu MW, Sun J, Sun YL, Cai YC, Huang YJ, Xian LJ. 2010. Effects of the biological clock gene Bmal1 on tumour growth and anti-cancer drug activity. J Biochem 148(3): 319–326. (Supported by the Clinical Key Program of Public Health Ministry, P. R. China and the National Natural Science Fund, P. R. China. Authors affiliated with Sun Yat-sen University, China.)20576619
716 Zheng H, Patel M, Hryniewicz K, Katz SD. 2006. Association of extended work shifts, vascular function, and inflammatory markers in internal medicine residents: a randomized crossover trial. JAMA 296(9): 1049–1050. (Supported by NIH and the National Heart, Lung, and Blood Institute. Authors affiliated with Yale University School of Medicine, CT.)16954481
717 Zhu Y, Stevens RG, Hoffman AE, FitzGerald LM, Kwon EM, Ostrander EA, Davis S, Zheng TZ, Stanford JL. 2009. Testing the circadian gene hypothesis in prostate cancer: A population-based case-control study. Cancer Res 69(24): 9315–9322. (Supported by NIH, the Fred Hutchinson Cancer Research Center, Yale University and the National Human Genome Research Institute. Authors affiliated with Yale University School of Medicine, CT; University of Connecticut Health Center, CT; Fred Hutchinson Cancer Research Center, WA; NIH, MD.)19934327
718 Zhu Y, Stevens RG, Hoffman AE, Tjonneland A, Vogel UB, Zheng T, Hansen J. 2011. Epigenetic impact of long-term shiftwork: pilot evidence from circadian genes and whole-genome methylation analysis. Chronobiol Int 28(10): 852–861. (Supported by NIEHS, Yale University, and the Danish Cancer Society. Authors affiliated with Yale University School of Medicine, CT; University of Connecticut Health Center, CT; Danish Cancer Society, Denmark; National Research Centre for the Working Environment, Denmark.)22080730
719 Zielinska-Dabkowska KM. 2018. Make lighting healthier. Nature 553(7688): 274–276. (Support not reported. Author affiliated with Gdansk University of Technology, Poland.)
720 Zienolddiny S, Haugen A, Lie JA, Kjuus H, Anmarkrud KH, Kjærheim K. 2013. Analysis of polymorphisms in the circadian-related genes and breast cancer risk in Norwegian nurses working night shifts. Breast Cancer Res 15(4): R53. (Supported by the Research Council of Norway and the Norwegian Cancer Society. Authors affiliated with National Institute of Occupational Health, Norway; Institute of Population-based Cancer Research, Norway.)23822714
721 Zubidat AE, Haim A. 2017. Artificial light-at-night – a novel lifestyle risk factor for metabolic disorder and cancer morbidity. J Basic Clin Physiol Pharmacol 28(4): 295–313. (No support received. Authors affiliated with University of Haifa, Israel.)28682785