# Preface

The National Toxicology Program (NTP) conducted cancer hazard assessments of night shift work and light at night for possible listing in the Report on Carcinogens (RoC) because of important potential health concerns associated with these two exposure scenarios.

For night shift work and light at night, the RoC review process proceeded through development of a draft RoC monograph, public comment, and external peer review. Following additional internal deliberation and agency input, it was determined that the cancer hazard conclusions for these two exposure scenarios would be published as a cancer hazard assessment report. To avoid confusion with traditional RoC listings, NTP has used descriptors in this report other than the RoC listing categories to communicate the cancer hazard conclusions for night shift work and light at night.

The substance profiles (from the draft RoC monograph) for these two exposure scenarios have been used to inform the summary of the scientific evidence supporting NTP’s cancer hazard assessment conclusions for the two exposure scenarios that can lead to circadian disruption—persistent night shift work and certain lighting conditions.