# Glossary

Acrophase: The time of the highest or peak melatonin levels based on the parameters of a cosine function fitted to the raw data.
Amplitude: The difference between the lowest and highest level of melatonin based on the parameters of a cosine function fitted to the raw data.
Block hours: A term used in the airline industry to measure the time an aircraft is in use (or the period of work for the air crew), beginning with the time the aircraft pushes back from the departure gate and ending when it reaches the arrival gate following landing.
Chronotype: A measure of preference for activity earlier or later in the day.
Circadian disruption: Internally or externally induced, acute or chronic temporal disorganization including but not limited to misalignment of the time structure in living systems potentially leading to adverse health outcomes.
Circadian light: Light that impacts the circadian system, which is measured by the light that causes suppression of melatonin synthesis
Cosinor modeling: A procedure for the analysis of biological rhythms based on the fitting of a cosine wave to the raw data.
D’Amico classification: A system designed to evaluate the risk of recurrence of prostate cancer as low, intermediate, or high based on a combination of measures such as blood PSA levels, Gleason scores, and tumor stages.
Dim light melatonin onset: The onset of melatonin secretion (prior to bedtime) under dim light conditions. Dim light melatonin onset is the most sensitive and direct index for identifying an individual’s biorhythm.
Diurnal: Occurring or active during the daytime.
Entrainment: The synchronization of a self-sustaining oscillation (such as a circadian rhythm) by a forcing oscillation (the zeitgeber). Under conditions of steady entrainment, the period of the self-sustaining oscillation conforms to that of the zeitgeber, and there is a stable phase relationship between the two of them.
Evening types: Evening-types (E-types) find difficult to get up in the morning and require more time to reach their optimal status.
Gleason score: A grading system used to determine the aggressiveness of prostate cancer on a scale up to 10 based on evaluation of tissue from a biopsy.
Jet lag: A malaise associated with the disruption of bodily rhythms caused by high speed air travel across time zones.
Job exposure matrix: A cross classification between a list of job titles and occupational exposures which may be chemicals, physical or biological agents, or psychosocial or ergonomic factors.
Light exposure/activity monitor: A device to approximate eye-level exposure to light, which also records the physical activity of the subject wearing the device.
Light intensity data loggers: A device to approximate eye-level exposure to light.
Light trespass: Light being cast where it is not wanted or needed.
Likert scale: A rating system used in questionnaires that offers a range or resonses to a specific question or statement that may range from very positive (e.g., “strongly agree”) to very negative (e.g., “strongly disagree”); the categories are often coded numerically.
Lux: A photometric unit that takes into account the sensitivity of the human visual system to different wavelengths.
Mesor: A circadian rhythm-adjusted mean based on the parameters of a cosine function fitted to the raw data, or the average level of melatonin.
Morning types: Morning-types (M-types), are active early in the morning and soon reach their peak in mental and physical performance but tire early in the evening.
Nocturnal: Occurring or active during the nighttime.
Phase shift: A discrete displacement of an oscillation along the time axis. Phase shifts may be either advances (i.e., the phase reference point occurs earlier than normal) or delays (i.e., the phase reference point occurs later than normal).
Retinohypothalamic tract: the monosynaptic pathway that connects the retina (in the eye) to the hypothalamus (in the diencephalon).
Self-luminous display: An electronic device (e.g., cell phones, computer screens, e-readers, or tablets) display having in itself the property of emitting light, thereby requiring no backlight.
Shift work: Any arrangement of daily working hours other than standard daylight hours (7:00 AM or 8:00 AM to 5:00 PM or 6:00 PM). Night work is typically defined as working time that extends into the night (e.g., at least 3 hours worked between midnight and 5:00 AM).
Sky glow at night: The brightening of the sky caused by outdoor lighting and natural atmospheric and celestial factors.
Social jet lag: Misalignment between one’s circadian and social clocks, e.g. waking to an alarm clock on weekdays for work or school and then sleeping and waking without an alarm on the weekend (i.e., “sleeping in”).
Spectral power distribution: A pictorial representation of the radiant power emitted by a light source at each wavelength or band of wavelengths in the visible region of the electromagnetic spectrum.
Suprachiasmatic nucleus (SCN): a small group of nerve cells lying in the ventral hypothalamus and possessing the properties of a circadian pacemaker.
Transmeridian travel: East-to-west or west-to-east travel.
Visible light: Light that reaches the eye, which can be either monochromatic (light of a single wavelength or limited range of wavelengths interpreted by the human eye as a single color, such as violet, blue, green, yellow, orange, or red) or polychromatic (light composed of more than one wavelength, including white light, which includes all wavelengths of visible light from 380 to about 780 nm).
Xenograft: A surgical graft of tissue from one species to an unlike species.
Zeitgeber: German word for time giver; is used in circadian biology to describe any daily environmental cue that synchronizes or entrains the circadian system