# Collaborators

Role | Collaborator | Affiliation
Co-project leads; Responsible for execution and coordination of project activities, including conception, design, planning, conduct, or technical review of the cancer hazard evaluations. | Ruth M. Lunn, DrPH | NIEHS, DNTP, ORoC
Co-project leads; Responsible for execution and coordination of project activities, including conception, design, planning, conduct, or technical review of the cancer hazard evaluations. | Pamela J. Schwingl, PhD | ILS
Evaluation Team; Contributed to design, conduct, technical review, and interpretation of studies for the cancer hazard evaluation | Stanley T. Atwood, MS | ILS
Evaluation Team; Contributed to design, conduct, technical review, and interpretation of studies for the cancer hazard evaluation | Sanford C. Garner, PhD | ILS
Evaluation Team; Contributed to design, conduct, technical review, and interpretation of studies for the cancer hazard evaluation | Gloria D. Jahnke, DVM | NIEHS, DNTP, ORoC
Evaluation Team; Contributed to design, conduct, technical review, and interpretation of studies for the cancer hazard evaluation | Suril S. Mehta, DrPH | NIEHS, DNTP, ORoC
Contributors
Role | Contributor | Affiliation
Provided technical assistance for report preparation | Whitney Arroyave, PhD | ILS
Provided technical assistance for report preparation | Andrew Ewens, PhD | ILS
Provided technical assistance for report preparation | Alton Peters, MS | ILS
Technical Advisors; Provided critical review of specific sections of the report | David Blask, PhD, MD | Tulane University School of Medicine, New Orleans, LA
Technical Advisors; Provided critical review of specific sections of the report | Mariana Figueiro, PhD | Rensselaer Polytechnic Institute, Troy, New York
Technical Advisors; Provided critical review of specific sections of the report | Johnni Hansen, PhD | Danish Cancer Society Copenhagen, Denmark
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | John Bucher, PhD (Chair) | NIEHS, DNTP
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Windy A. Boyd, PhD | NIEHS, DNTP
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Tania Carreón-Valencia, PhD | NIOSH
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Claire Caruso, PhD, RN | NIOSH
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Suzanne Fenton, PhD | NIEHS, DNTP
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Gopi Gadupudi, PhD | NIEHS, DNTP
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Stephanie Holmgren, MSLS, MBA | NIEHS, DNTP
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Christina Lawson, PhD | NIOSH
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Scott Masten, PhD | NIEHS, DNTP
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Arun Pandiri, PhD | NIEHS, DNTP
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Leslie Reinlib, PhD | NIEHS, DERT
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Amy Wang, PhD, BVM | NIEHS, DNTP
NIEHS Internal Review Committee; Provided critical review of scientific and technical elements of the cancer hazard evaluations | Alexandra White, PhD | NIEHS, DIR
Acknowledgements
Role | Participant | Affiliation
Administrative assistance | Ella J. Darden, BS | ILS
Administrative assistance | Tracy L. Saunders, BS | ILS
Editorial assistance | Susan Dakin, PhD | Independent consultant
Web-based database developer | Andy J. Shapiro, MS | NIEHS (formerly)
Literature searches | Jessica A. Geter, MSLS | ILS (formerly)
Literature searches | Lara Handler, MSLS | ILS
Organized the peer review meeting | Mary Wolfe, PhD | NIEHS
Logistical support for the peer review meeting | Susan S. Blaine, BA | ICF
Logistical support for the peer review meeting | Katherine R. Helmick, MPH | ICF
Logistical support for the peer review meeting | Jeanne Luh, PhD | ICF
Logistical support for the peer review meeting | Kelly A. Shipkowski, PhD | ICF
Logistical support for the peer review meeting | River B. Williams, BS | ICF

ICF = ICF Incorporated, LLC.

DIR = Division of Intramural Research.

ILS = Integrated Laboratory Systems, Inc.

DNTP = Division of the National Toxicology Program.

NIEHS = National Institute of Environmental Health Sciences.

NIOSH = National Institute of Occupational Safety and Health.

ORoC = Office of the Report on Carcinogens, DNTP, NIEHS.