# Peer-Review Panel Members

- Laura Beane Freeman, Ph.D. (Chair)
  Senior Investigator
  Occupational and Environmental Epidemiology Branch
  Division of Cancer Epidemiology and Genetics
  National Cancer Institute
  Rockville, Maryland, USA
- Massimo Bracci, M.D., Ph.D.
  Researcher
  Department of Clinical and Molecular Sciences
  Università Politecnica delle Marche
  Ancona, Italy
- Loning Fu, Ph.D.
  Associate Professor
  Baylor College of Medicine
  Houston, Texas, USA
- Steven Hill, Ph.D.
  Professor
  Department of Structural and Cellular Biology
  Tulane University School of Medicine
  New Orleans, Louisiana
- Francis Lévi, M.D., Ph.D.
  Professor, Biomedicine
  Warwick Medical School
  Warwick University
  Coventry, United Kingdom
- Florence Menegaux, M.D., Ph.D.
  Researcher
  Epidemiology Cancer and Environment Team
  Research Center on Epidemiology and Population Health (CESP)
  Institut National de la Santé et de la Recherche Médicale (INSERM)
  Villejuif, France
- Marie-Elise Parent, Ph.D.
  Professor, Epidemiology
  Institut National de la Recherche Scientifique – Institut Armand-Frappier Research Center
  Quebec, Canada
- Eva Schernhammer, M.D., Dr.P.H., M.P.H., M.Sc.
  Adjunct Professor
  Department of Epidemiology
  Harvard T.H. Chan School of Public Health
  Boston, Massachusetts, USA