# Peer Review

Peer review of the “Draft Report on Carcinogens Monograph on Night Shift Work and Light at Night” was conducted by an ad hoc expert panel at a public meeting on October 5, 2018, in the Rodbell Auditorium at the National Institute of Environmental Health Sciences, David P. Rall Building, Research Triangle Park, NC (see NTP 2019a for materials, minutes, and panel recommendations from meeting). The selection of panel members and conduct of the peer review were performed in accordance with the Federal Advisory Committee Act and implementing federal policies and regulations.

The panel members served as independent scientists, not as representatives of any institution, company, or governmental agency.

The charge to the peer-review panel was as follows:

1. Comment on whether the “Draft Report on Carcinogens Monograph on Night Shift Work and Light at Night” is technically correct, clearly stated, and objectively presented.
2. Provide opinion on whether a significant number of U.S. residents (a) work (or formerly worked) night shifts and (b) are (or were in the past) exposed to light at night.

The panel was asked to vote on the following:

1. Whether the scientific evidence supports the level of evidence conclusions regarding carcinogenicity from cancer studies in humans.
2. Whether the scientific evidence supports NTP’s preliminary policy decision on the listing status in the Report on Carcinogens (RoC) of persistent night shift work that causes circadian disruption and certain lighting conditions that cause circadian disruption.

The peer-review report is available on the NTP website (NTP 2019b). Following peer review, a decision was made not to submit night shift work and light at night for RoC listing. The peer-review report was then used to revise the assessments and inform the final cancer hazard assessment conclusions for night shift work and light at night (see Introduction).