# 7 Evidence Integration and Overall Cancer Hazard Assessment

Modern electric lighting practices have helped to transform our society into one in which people work, sleep, and receive goods and services at any time of the day or night. These practices have resulted in, among others, exposure to LAN and night shift work.

- Night shift work is defined as typically working at least 3 hours between midnight and 5:00 AM and includes exposure to electric LAN, sleep disturbances, or changes in meal timing, as well as other potential factotrs (e.g., decreased exposure to sunlight, and lower vitamin D levels).
- LAN refers to excessive exposure to electric light during the biological night which is the time when the circadian clock promotes sleep.

Because light is the critical regulator of circadian rhythms, exposure to LAN can cause circadian disruption, which can be linked to potential adverse health effects, such as cancer. Other characteristics of night shift work such as meal time changes are also related to circadian regulation.

The objective of this cancer hazard assessment is to define exposure to (1) LAN and (2) night shift work in ways that are supported by the scientific evidence and to reach an overall cancer hazard assessment for these two exposure scenarios. Although the evidence is evaluated separately for LAN and night shift work, these exposures overlap; studies specific to LAN may be relevant to night shift work and vice versa.

This section describes the methods for evidence integration (Section 7.1), summarizes the cancer evaluations for night shift work (Section 7.2) and LAN (Section 7.3), and presents the cancer hazard assessment conclusions (Section 7.4). Because the data on transmeridian travel were inadequate for evaluation, no overall preliminary recommendation was made for this exposure scenario. Section 7.5 provides a brief summary of resources and recommendations for limiting night shift work practices or lighting conditions that would cause circadian disruption.

## 7.1 Methods for evidence integration

The cancer hazard assessment integrates relevant evidence across many studies using a triangulation approach that investigated the pathway from exposure (LAN and night shift work) to circadian disruption to cancer, including the following relationships:

- LAN and night shift work and cancer in humans (Sections 3 and 4) and experimental animals (Section 5)
- LAN and night shift work and biomarkers of circadian disruption (Section 2)
- Circadian disruption and cancer, including biological effects associated with cancer (Section 6)
- LAN and night shift work and biological effects associated with cancer (Section 6)

This section presents a series of evidence-based figures and tables that summarize the assessments from those sections, to provide transparency of the decision-making process for reaching a cancer hazard assessment conclusion for LAN and night shift work. In general, for each relationship, the tables provide information regarding the approaches used to evaluate the relationship, strengths and limitations of the studies, an assessment of confidence in the evidence, and integration of the evidence. The process starts with assessment of the evidence for each relationship (such as between exposure and breast cancer) for a specific evidence stream (such as human epidemiology studies) (see Table 7-2). The assessments of the various types of evidence are brought forward to the overall evaluation to reach cancer hazard assessment conclusion (see Table 7-1). The level-of-evidence conclusions from studies in humans and the overall cancer hazard assessment were reached by applying the RoC listing criteria to these assessments. Because of the complexity of the carcinogenicity pathway, the confidence in the mechanistic data requires integrating many types of data before these data are integrated with the toxicology and epidemiology data (Table 7-3). The tables are focused on breast cancer; evidence from humans for cancer at other tissue sites is also summarized.

## 7.2 Night shift work

Epidemiology studies provide evidence that persistent night shift work (permanent or rotating) increases breast cancer risk. Biomonitoring, toxicology, and mechanistic studies provide evidence that night-shift-induced circadian disruption is associated with several key events that are relevant to carcinogenicity pathways and also provide support for the patterns of risks observed in the epidemiology studies. An overview of the key evidence is discussed below and summarized in greater detail in Tables 7-1 through 7-3. Figure 7-1 is a schematic diagram of the evidence for the links from night shift work exposure to circadian disruption to biological effects to breast cancer.

Few night shift workers are able to adapt their circadian rhythms to their altered sleep-work cycle (Jensen et al. 2016), and women with more persistent shift work may have health problems. The epidemiology data are inadequate to determine the specific roles of LAN, altered sleep patterns, or other factors in development of breast cancer. However, lifestyle behaviors (such as smoking or alcohol consumption) not related to circadian disruption were controlled for in the epidemiology studies and cannot explain the excess risk. Therefore, the exposure scenario that best fits the available epidemiological evidence is “persistent night shift work,” which includes exposure to LAN, sleep disruptions, changes in meal timing, and other characteristics of night shift work. Persistent shift work may be a surrogate for conditions that are associated with chronic circadian disruption.

Numerous epidemiology studies provide strong evidence that “persistent night shift work” — defined as frequent, long-term, or working a large number of night shifts over a lifetime, especially beginning in early adulthood (see Section 3 and Table 7-1) — increases the risk of developing breast cancer. Night shift work was associated with an increased risk of breast cancer in 11 of the 13 most informative studies and in 6 of 8 studies that were considered less informative because of study limitations. Moreover, the excess risk was observed in studies of different occupations and in different geographic locations, which helps to minimize concerns that chance or bias may explain the positive findings.

The most convincing evidence for a positive association between night shift work and breast cancer was from studies of women who started working nights at an early age and worked nights frequently or for many years. A pooled analysis of 5 case-control studies conducted in Australia, Canada, and Europe, all using the same definition of night shift work (Cordina-Duverger et al. 2018), found the highest risk of breast cancer among pre-menopausal women who worked at least 3 nights per week for 10 years, 10-hour shifts, and within the last 2 years. No excess risk was found in post-menopausal women. These findings are supported by the Nurses’ Health Studies (Wegrzyn et al. 2017), which applied similar methods to younger and older cohorts and found an excess risk for long duration of rotating night shift work among the women in the younger cohort but not in the older cohort, and in both cohorts among women followed for at least 10 years — that is, starting at younger ages. Excess risk of breast cancer was also found in some cohorts of older women with long duration of working night shifts; however, in most cases, the age when they started working nights was not known.

The finding of an association with more recent exposure may suggest that night shift work is acting as a promoter, which is supported by cancer studies finding that (1) simulated shift work decreased the latency of mammary gland tumors in a cancer-prone mouse model (Van Dycke et al. 2015), chronic jet lag promoted mammary tumors initiated by N-nitroso-N-methylurea (Fang et al. 2017), and (2) numerous studies in experimental animals showing that LAN (defined as exposure to continuous light, dim light, interrupted light during sleeping, or changes in the duration of LAN) promoted proliferation of mammary-gland tumors or growth of human breast-tumor xenografts (see Section 5 and Table 7-2). Finally, the evidence from human cancer studies is stronger for hormone-receptor-positive subtypes of breast cancer (e.g., ER+, PR+, and HER2+), which is consistent with the mechanistic data (see Sections 3 and 6 and Table 7-1).

The available mechanistic and other relevant data primarily provide (1) evidence that simulated shift work or chronic jet lag promotes the growth of mammary-gland and other types of tumors in experimental animals (see Section 5 and Table 7-2), (2) evidence that circadian disruption, including effects mediated by the sympathetic nervous system, melatonin suppression and clock-gene desynchrony, plays a role in shift-work-mediated carcinogenicity, and (3) evidence (from studies in humans and experimental animal models) that night shift work is associated with biological effects that are recognized as key characteristics of carcinogens (see Sections 2 and 6 and Table 7-2). In general, although it is likely that other exposures associated with shift work (e.g., sleep deprivation, altered meal timing, or vitamin D deficiency), some of which also contribute to circadian disruption, also plays a role in the carcinogenicity associated with shift work; the cancer databases are generally less well developed than the data from studies of LAN and circadian disruption.

The key evidence supporting a role for circadian disruption mechanisms in carcinogenicity includes (1) field studies showing that night shift work is associated with melatonin suppression and circadian disruption (see Section 2), (2) cancer studies in animals and humans showing a link between low melatonin levels and breast cancer risk or mammary-gland tumor growth, and (3) mechanistic studies showing that both clock-gene regulation and melatonin are important in suppressing cancer development (see Tables 7-2 and 7-3). There is also evidence that night shift work causes several other biological effects that are known to be key characteristics of carcinogens or are associated with carcinogenicity (e.g., decreased DNA repair, increased oxidative stress, increased inflammation, altered circulating levels of estrogen, and epigenetic changes that modify the expression of core clock genes or clock-controlled genes), including some that are consistent with development of hormone-receptor-related breast cancer (e.g., altered estrogen levels or function). A strength of the database is that several of the animal cancer studies (involving exposure to LAN or simulated shift work/chronic jet lag) also measured some effects associated with cancer (e.g., DNA damage repair), thus providing links between exposure, intermediate biological effects, and cancer. Moreover, several biological effects observed in night shift workers (including some of the key characteristics of carcinogens) were the same as some of those mediated by low melatonin levels or deregulation of core clock genes. Overall, these data provide strong, although indirect, support for the role of circadian disruption in breast cancer carcinogenicity among night shift workers. A key early event may be the epigenetic changes reported in some studies of night shift workers, which are considered to be paramount for both the clock-gene-deregulation and melatonin-suppression modes of action. Epidemiology studies also provide some evidence that working night shifts is related to an increased risk of prostate cancer; this database is not as robust as that for breast cancer, and the evidence is not as strong. The database was inadequate to evaluate the relationship of night shift work with colorectal cancer, lung cancer, or other hormonal cancers in women.

Figure 7-1 Integration of evidence from studies relevant to night shift work and breast cancer

Evidence from studies in humans and experimental animals for the relationship between night shift work and biomarkers of circadian disruption, biological effects (e.g., mainly key characteristics of carcinogens), and cancer. The evidence supporting this figure is outlined in Tables 7-1 to 7-3. The strength and directness of the evidence are indicated by the weight (thin, medium, or thick) and pattern (solid = direct, dashed = indirect) of the arrows. Proposed mechanism: purple = melatonin; green = circadian clock gene desynchrony; and peach = direct biological effects of night shift work. * = Biological effect was measured in animal cancer study. ** = Biological effects were measured in animal cancer study of LAN.

The figure presents the evidence from studies that are relevant for evaluating the relationship between night shift work and human cancer. Relevant studies included three primary evidence streams: (1) epidemiology studies of night shift workers and cancer, (2) human and experimental animal studies of shift work or jet lag and circadian disruption, and (3) mechanistic studies of circadian disruption and cancer. Epidemiological studies provide strong evidence that persistent night shift work is associated with an increased risk for breast cancer in women. There is also strong evidence that night shift work causes melatonin suppression and some evidence that night shift works alters clock gene expression and induces other biological effects that are recognized a key characteristics of carcinogens including decreased DNA repair, oxidative damage, epigenetic changes, and increased inflammation or altered immune response. Some studies in humans suggest that low nocturnal melatonin levels are associated with an increased cancer risk. Animal studies show some evidence that simulated shift work or chronic jet lag decreases mammary gland tumor latency, alters clock gene expression, and also induces biological affects recognized as key characteristics of carcinogens. Studies using mice with clock gene mutations show an increased incidence of several cancers, but not breast cancer. Mechanistic studies show that altered clock gene expression affects numerous pathways associated with cancer including tumor suppressors, DNA repair, metabolism, cell cycle, cell proliferation, and apoptosis. Melatonin has also been shown to possess oncostatic properties including anti-oxidant, anti-estrogenic, anti-proliferative, anti-inflammatory, and anti-metastatic effects and that when exogenous melatonin is given to mice exposed to simulated shift work, tumor growth is decreased.

## 7.3 LAN

Toxicological and mechanistic studies in animals provide strong evidence that LAN promotes breast cancer proliferation and growth (see Section 5 and Table 7-2), causes biological effects that are identified as key characteristics of carcinogens or associated with carcinogenicity (see Section 6 and Table 7-2), and that the effects are mediated in part by circadian disruption (see Sections 2 and 6, and Tables 7-2 and 7-3). Figure 7-2 is a schematic diagram of the evidence for the links between excessive exposure to LAN, circadian disruption, intermediate biological effects, and breast cancer. Other studies suggest that total light, including the type of light received during the day, is important in circadian regulation, night time melatonin secretion, and carcinogenicity.

The database of animal studies on mammary-gland tumors is much larger for LAN exposure than for simulated shift work. These studies clearly demonstrate that melatonin suppression plays a direct role in LAN-associated carcinogenicity. A limitation of the experimental animal studies is that rodents are more sensitive to light-induced melatonin suppression than are humans. However, human breast tumors grew rapidly in nude rats perfused (in situ) with melatonin-depleted blood collected from pre-menopausal women exposed to bright LAN or during the daytime, whereas perfusion with melatonin-rich blood collected from women during the nighttime without exposure to LAN suppressed tumor growth (Blask et al. 2005, Blask et al. 2009). These data support the relevance of the LAN animal models to humans. In almost all studies, LAN also promoted the growth of other types of cancer — of the brain (glioma), cervix (human cells), liver, lung, kidney, peripheral nervous system, prostate, and skin — in studies that either co-exposed the animals to chemical carcinogens or transplanted human or animal cancer cells into LAN-exposed animals (see Section 5). Exposure of rats to continuous LAN increased the incidences of leukemia and lung tumors and the total incidence of tumors (Anisimov et al. 2004).

As in the shift-work studies, there is evidence for an indirect role of altered clock-gene expression in LAN-induced carcinogenicity, which is induced by altering neural and endocrine signaling pathways of the circadian timing system to peripheral tissues. Some studies found that experimental animals exposed to LAN showed biological effects (e.g., oxidative stress or altered DNA damage repair, increased inflammation or immune effects, metabolic effects) that are key characteristics of carcinogens or associated with carcinogenicity. Although the database is limited by the number of studies that evaluated each specific effect, the collective evidence from studies of both LAN and night shift work (which includes exposure to LAN) supports the conclusion that LAN causes similar biological effects in humans and animals that are consistent with the proposed carcinogenicity mechanisms associated with circadian disruption (see Section 6 and Tables 7-1 and 7-2).

Other evidence indicates that total light exposure, not limited to LAN, is important in regulating circadian disruption. Some experimental studies suggest that blue light exposure during the daytime or morning can help reduce LAN-induced melatonin suppression (Kozaki et al. 2015, 2016, Nagashima et al. 2018) and improve measures of sleep quality and mood (Viola et al. 2008). In addition, night-time sensitivity to light-induced circadian disruption (usually measured by melatonin suppression) is influenced by light exposure during the day (reviewed by Figueiro 2017).

Two cohort studies in the United States (Hurley et al. 2014, James et al. 2017), a case-referent study (using lung cancer cases as the comparison group) (Bauer et al. 2013), and a population-based case-control study in Spain (Garcia-Saenz et al. 2018) found an increased risk of breast cancer among women in the highest category of LAN exposure or blue-light LAN exposure (Garcia-Saenz et al. 2018). These findings are supported by a case-control study which found that Israeli women living near strong artificial LAN sources had a 50% increased risk of breast cancer; however, no information was provided on the sources or proximity of the LAN (Keshet-Sitton et al. 2016). However, it is not clear whether exposure to outdoor LAN, as measured by satellite data, is a relevant direct measure of light or is rather a surrogate for other activities enabled by light. The Spanish case-control study (Garcia-Saenz et al. 2018) found an increased risk of breast cancer among long-term residents of areas with the highest levels of exposure to outdoor light in the blue spectrum but not outdoor light in the overall visible spectrum, suggesting a possible link to LAN exposure. Findings from studies of light exposure in the bedroom or sleep areas were inconsistent. Overall, the database for exposure to LAN (indoor or outdoor) was considered inadequate to evaluate the risk of breast cancer.

Finally, whether light causes circadian disruption depends on many characteristics, including level or intensity, duration of exposure, wavelength(s), timing of exposure, and photic history (e.g., the amount of daytime light). Studies in experimental animals found that compared to exposure to white light during the day, enriched blue light exposure during the day had a positive effect on circadian regulation and decreased the growth of implanted prostate and liver tumors. The term “LAN” does not fully capture these characteristics; therefore, the recommended cancer hazard assessment conclusion is for “certain lighting practices that cause circadian disruption.”

Figure 7-2 Integration of evidence from studies relevant to LAN and breast cancer

Evidence from studies in humans and experimental animals for the relationship between LAN and biomarkers of circadian disruption, biological effects (e.g., mainly key characteristics of carcinogens), and cancer. The evidence supporting this figure is outlined in Tables 7-1 to 7-3. The strength and directness of the evidence are indicated by the weight (thin, medium, or thick) and pattern (solid = direct, dashed = indirect) of the arrows. Proposed mechanism: purple = melatonin; green = circadian clock gene desynchrony; and peach = direct biological effects of night shift work.

The figure is similar to figure 7-1 but presents the evidence linking exposure to light and night and cancer. There is some, but inadequate, evidence from epidemiology studies for an association between exposure to light at night and breast cancer. However, there is strong evidence from human and animal studies that exposure to light at night causes melatonin suppression and some evidence that it alters clock gene expression. Studies in mice also provide some evidence that exposure to light at night induces biological affects that are relevant to cancer or recognized as key characteristics of carcinogens including altered estrogen levels, altered metabolism, oxidative stress, altered DNA repair, and inflammation or altered immune function. In vivo and in vitro mechanistic studies show that melatonin suppression inhibits multiple oncostatic pathways, thus, leading to enhanced tumor progression and growth. Melatonin’s oncostatic properties include anti-oxidant, anti-estrogenic, anti-proliferative, anti-inflammatory, and anti-metastatic effects. Human breast cancer cells implanted into nude rats grew rapidly when perfused with melatonin depleted blood collected from women exposed to light at night; however, tumor growth was suppressed when perfused with melatonin-rich blood that was collected from women during the nighttime that were not exposed to LAN. In addition, mechanistic studies show that altered clock gene expression affects many other genes and pathways that can affect tumor growth including tumor suppressors, DNA repair, metabolism, cell cycle, cell proliferation, and apoptosis.

## 7.4 NTP cancer hazard assessment conclusions

Table 7-1 summarizes the evidence supporting the cancer hazard assessment conclusions. Tables 7-2 and 7-3 summarize in more detail the key evidence from human and animal cancer studies

There is high confidence for a causal relationship between human cancer and persistent night shift work — i.e., frequent and long-term night shift work, especially beginning in early adulthood—that causes circadian disruption.

- This conclusion is based on sufficient evidence of carcinogenicity from the collective body of cancer epidemiological studies and mechanistic studies in humans and in experimental animals. Human epidemiological studies provide strong evidence that persistent night shift work is associated with an increased risk of breast cancer and mechanistic and other related studies provide evidence that circadian disruption plays a major role in the cancer pathway in humans.
- In a pooled analysis of 5 case-control studies, female night shift workers found to be at elevated risk for breast cancer in epidemiology studies are those who started working before age 30 and worked at least 3 times/week and for 10 or more years; however, the exact conditions (e.g., number of years worked) that put an individual at increased risk may depend on the specific combination of these metrics (e.g., duration may be longer if frequency is less) or other factors.

There is moderate confidence for a causal relationship between human cancer and certain lighting conditions — i.e., excessive LAN exposure combined with insufficient daylight exposure — that cause circadian disruption. This conclusion is based on strong evidence that LAN acts through mechanisms that are likely to cause cancer in humans.

- Toxicological and mechanistic data indicate that exposure to LAN causes melatonin suppression and other types of circadian disruption, which lead to the proliferation and growth of breast or mammary-gland cancer in experimental animals.
- LAN causes biological effects that are characteristics of recognized carcinogens.
- Studies in humans show that LAN causes melatonin suppression.
- The characteristics of electric light that are most likely to cause circadian disruption include a combination of short wavelengths (e.g., blue light), longer duration, exposure to electric light during the biological night, and higher light intensity or levels. The exact conditions (e.g., duration) depends on the combination of these metrics. In addition to exposure to electric LAN, total light exposure (e.g., insufficient exposure to daylight) is also important in circadian regulation and thus is part of certain lighting conditions.

Table 7-1 Overall evaluation: Evidence integration

Exposure or MOA | End point or outcome | Evidence stream or approach | Confidence in the evidence | Overall evaluation
Night shift work | Breast cancer | Human epidemiology studies; 21 studies of independent populations; Pooled analysis of 5 case-control studies; Experimental animal study; Simulated shift work and jet lag in susceptible transgenic mice; Mechanistic and biomonitoring data; Melatonin suppression hypothesis; Circadian disruption hypothesis; Biological effects associated with cancer; Other effects: sleep deprivation and vitamin D deficiency | Strong evidence that persistent night shift work (frequent and long-term night shift work, especially among women who began night shift work at a younger age) is associated with an increased risk of breast cancer; Some evidence that simulated shift work or chronic jet lag decreased latency to mammary-gland tumor development or increased mammary-gland multiplicity; Indirect evidence that melatonin suppression contributes to breast cancer development in night shift workers; Strong but indirect evidence that circadian disruption contributes to breast cancer development; Night shift work is associated with effects that are consistent with several of the key characteristics of carcinogens and also consistent with effects mediated by melatonin and altered clock-gene expression. Epigenetic effects may be a key early step responsible for altered gene expression; Role of vitamin D and sleep in night shift work is unclear | High confidence to establish a causal relationship with human cancer; Persistent night shift work that causes circadian disruption; Sufficient evidence of carcinogenicity of persistent night shift work from studies in humans, including cancer epidemiology studies and human mechanistic studies; Limited but strong evidence of carcinogenicity of persistent night shift work from human epidemiology studies; Strong toxicological and mechanistic data providing evidence that circadian disruption plays a role in the cancer pathway in humans; Risk patterns in human cancer studies — younger age, hormone-receptor positive — supported by mechanistic data and biology of breast cancer development; Exposure to LAN may contribute to cancer risk, but data are inadequate to evaluate a direct association
Night shift work | Prostate cancer | Human epidemiology studies; 10 studies of independent populations; Experimental animal studies; LAN (long vs. short day and mouse prostate xenograft study); LAN and other cancers: numerous initiation-promotion and xenograft studies; Simulated shift work or chronic jet lag (other cancer); Mechanistic and biomonitoring data; - See breast cancer | Limited evidence that night shift work causes prostate cancer in humans; Some evidence that exposure to LAN promotes prostate cancer growth in experimental animals; Strong evidence that simulated shift work promotes tumor proliferation and growth in experimental animals; Although prostate cancer has not been evaluated to the same extent as breast cancer, many of the conclusions from the mechanistic data are applicable to prostate cancer, which is also a hormone-related cancer | Limited evidence of carcinogenicity of night shift work from studies in humans
LAN | Breast cancer | Human epidemiology studies; 5 studies of outdoor light; 10 studies of light in the sleeping area (2 studies also reported on outdoor light); Experimental animal studies; Primarily initiation-promotion studies of continuous, dim, or interrupted light or bright blue-enriched light during the day; Mechanistic and biomonitoring data; Melatonin suppression hypothesis; Circadian disruption theory; Biological effects associated with cancer | Inadequate evidence that LAN (indoor or outdoor) causes breast cancer risk; Strong evidence from studies in experimental animals that exposure to LAN promotes human breast cancer proliferation or growth and mouse mammary-gland tumor growth; Bright blue-enriched light during the day increased the level of nighttime melatonin levels and decreased tumor growth in experimental animals; Strong evidence that melatonin suppression plays a role in LAN-induced breast carcinogenicity in experimental animals | Moderate confidence to establish a causal relationship with human cancer; Certain lighting conditions —i.e., excessive LAN exposure combined with insufficient exposure to daylight — that cause circadian disruption; Strong toxicological and mechanistic data that exposure to LAN causes melatonin suppression and other types of circadian disruption, which leads to breast or mammary-gland cancer proliferation and growth in experimental animals; LAN induces biological effects in experimental animals associated with (1) carcinogenicity and (2) melatonin suppression and circadian clock gene deregulation; - Some of these biological effects are observed among night shift workers; Exposure to excessive LAN can cause circadian disruption in humans

Table 7-2 Detailed analysis of key evidence

Exposure | Outcome or effect | Evidence stream/approach | Strengths & limitations | Assessment of the evidence
Studies of night shift work (or simulated shift work) and cancer
Night shift work | Breast cancer | Human cancer epidemiology studies; 21 independent populations; - 12 case-control studies; - 1 pooled analysis of 5 case-control studies; - 9 cohort studies | Case-control studies; Strengths; Detailed exposure assessment; Limitations; Retrospective exposure assessment; Cohort studies; Strengths; No differential recall bias or issues with confounding; NHS/NHS2 was able to evaluate timing of exposure, as similar methods were used for both young and old cohorts; Limitations; Biases towards the null: left truncation, non-differential exposure misclassification, low sensitivity | Collective evidence (21 studies); Strengths; Adequacy of database: 13 informative (high or moderate quality) studies; - 9 case-control and 4 cohort studies; Consistency across studies, geographic locations, and occupations; evidence of an association in 11 of 13 informative studies and 6 of 8 lower-utility studies; Consistent patterns of risk for work at younger ages at high duration or frequency seen in pooled analysis and a high-quality cohort study; Unlikely to be explained by lifestyles confounders; Patterns of exposure: highest risk found for persistent night shift work (duration, timing, frequency); exposure response found for duration and frequency in several studies; High-quality pooled case-control analysis provides strong evidence of an association of night work with increased breast cancer risk; Limitations; Evidence primarily from case-control studies and 2 cohort studies; somewhat inconsistent evidence in cohort studies; Unable to evaluate circadian disruption per se, or other components of night shift work.
Night shift work | Prostate cancer | 10 studies of independent populations; - 5 cohort studies; - 5 case-control studies | Strength; Controlled for known risk factors for prostate cancer; Limitations; Non-differential exposure misclassification; Low sensitivity | Adequacy of the database: 5 informative studies; potential biases in low-quality studies are most likely towards the null; Consistent findings of an association among the most informative studies, with some support from lower-quality studies; Some evidence for an exposure-duration response in 2 studies; risks found for long duration of working nights; Few informative studies, and limited metrics evaluated
Night shift work | Colorectal cancer | 5 studies of 6 independent populations | Limitations; Potential for unmeasured confounding; Non-differential exposure misclassification; Low sensitivity | Adequacy of the database: only 3 informative studies; - Limited metrics evaluated; Increased risk with ever exposure or long duration of exposure found in the informative studies, and some evidence of an exposure-duration response; Potential differential risk between colon and rectal cancers; Possibility of unmeasured confounding
Night shift work | Lung cancer | 5 studies of independent populations | Strengths; Controlled for known risk factors; Limitations; Non-differential exposure misclassification; Low sensitivity | Adequacy of the database: only 3 informative studies; Four studies showed inconsistent findings with ever exposure to night shift work; One study population (NHS/NHS2 cohort) saw an exposure-duration response; Some evidence of increased risk among smokers, likely confounding the relationship
Night shift work | Female hormonal cancers | 3 studies of independent populations; - 2 ovarian; - 1 endometrial | Strengths; Controlled for known risk factors; Limitations; Non-differential exposure misclassification; Low sensitivity | Database was inadequate, given limited number of studies
Simulated shift work or jet lag | Mammary-gland tumors | Experimental animals (mice); 2 studies; Shift work; - Transgenic mouse (p53 conditional mutant); melatonin deficient; - Inverted LD cycle; Jet-lagged model; - Female C3(1)/Tag transgenic mice; - Advance light onset by 12 hr, followed by a 12-hr LD cycle for seven days. | Strengths; Both studies measured markers of circadian disruption (e.g., clock genes); Limitations; Limited reporting on number of tumors for each exposure group; Cancer-susceptible model or initiation/promotion design limited the ability to look at tumor incidence or spontaneous tumors; Melatonin-deficient mice | Simulated shift work or jet lag decreased latency to mammary-gland tumor development or increased multiplicity; Only 2 studies of mammary-gland tumors available; Simulated shift work or jet lag promoted progression or growth of other types of tumors
Simulated shift work or jet lag | Other tumors | Experimental animals; (rats and mice); Animal models; - Spontaneous tumors; - Initiation/promotion; - Xenografts | Strengths; Multiple studies that included melatonin-proficient animals; Limitations; Some studies of spontaneous tumors were of limited utility because of poor reporting; pathology and necropsy methods were unclear, especially for looking at number or incidences of specific tumor types; Other studies looked only at tumor growth, latency or animal survival | Consistent evidence of tumor promotion and growth; Tumors: liver, lymphoma, Ehrlich carcinoma, sarcoma 180, Glasgow osteosarcoma, pancreatic adenocarcinoma, lung carcinoma, plasmacytoma; Some evidence that chronic jet lag increased spontaneous liver tumors
LAN and transmeridian travel cancer studies
LAN | Breast cancer | Humans (epidemiology); 2 cohort studies, 1 case referent study, and 1 case-control study of outdoor light using satellite data and addresses; 1 case-control study of living near strong LAN source, 10 studies (2 cohort and 8 case-control studies) on light in the sleep area, based on self-report | Strengths; One study evaluated exposure to blue light; Limitations; Non-differential misclassification in exposure assessment; Potential confounding from lifestyle factors | A few studies found an association with outdoor light or living near a strong LAN source; however, it is not clear whether LAN was a proxy for other activities; Inconsistent across studies of indoor light; somewhat more consistent for measures of presumed higher exposure; Difficult to compare findings across studies, as exposure metrics varied
LAN (proxy) | Mammary-gland tumors or human breast tumors | Experimental animals; (rats and mice); Light exposures; - Continuous light; - Dim or interrupted light; - Blood from humans exposed to LAN; Animal models; - Spontaneous tumors; - Initiation/promotion; - Xenografts | Strengths; Some studies used human breast tissue or cells and measured tumor growth; Limitations; Studies of spontaneous tumors were of limited utility because of poor reporting; pathology and necropsy methods were unclear, especially for looking at number or incidences of specific tumor types; Other studies looked only at tumor growth, latency, or animal survival | Consistent evidence of tumor promotion from studies of continuous light or dim LAN; Consistent evidence that dim LAN promotes human breast cancer growth and mouse mammary-gland tumor growth; Melatonin-depleted blood from humans exposed to LAN promoted breast cancer growth; Decreased latency of all tumors in rats exposed at early but not late age; non-significant increase in incidence of mammary-gland tumors; Animals more sensitive to LAN than humans; Dim LAN or light during the night may be more relevant to human exposure than continuous light
LAN (proxy) | Other tumors | Same as above | Strengths; Some studies used human tumors or cells (cervical) and measured tumor growth; Limitations; same as above | Consistent evidence of tumor promotion and growth from studies of continuous light, intermittent light, or dim LAN; Tumor types: brain (glioma), mammary gland, human breast, human cervix, liver, lung, skin, kidney, peripheral nervous system, and prostate.; Some evidence that continuous light or long light days (natural lighting conditions of NW Russia) increased spontaneous tumors or decreased latency of several types of spontaneous tumors including mammary gland, lung, leukemia/lymphoma, and Leydig-cell tumors.
Transmeridian travel | Breast cancer | Humans (epidemiology); 1 prospective cohort, 2 retrospective cohorts, and 1 nested case-control study of female flight attendants | Strengths; Large cohorts of flight attendants; linkage with population-based cancer registries.; Limitations; Potential selection of oldest survivors; inadequate information on number of time zones crossed; exposure metrics highly correlated; potentially uncontrolled confounding; limited ability to differentiate most highly exposed individuals | Inadequate evidence to assess carcinogenicity of transmeridian travel from studies in humans; Strongest evidence is for a small subset of high-parity women from a nested case-control study with high-quality exposure assessment; some evidence from 2 low-utility studies based on poor exposure assessment that failed to adequately capture number of time zones crossed
Melatonin studies
LAN exposure among night shift workers | Melatonin suppression or breast cancer | Melatonin: Field studies; Breast cancer: 1 case-control study | Strengths; Measured light exposure; Limitations; Few subjects in each study; Some studies done on shift workers (compared day vs. night shift workers); Some studies measured day and night at same calendar but not chronological time (e.g., related to sleep) | Unclear because of limited studies; Some studies found an inverse relationship between light levels and melatonin levels; Some studies found evidence of melatonin suppression for night shift vs. day shift in rotating-shift workers; Case-control study found a modest association with high level of exposure to LAN during night work (OR = 1.25, 95% CR = 0.98–1.59)
LAN | Melatonin suppression and human breast cancer or mammary-gland tumors | Studies in experimental animals; Light initiation-promotion studies ± melatonin; Dim light human cancer xenograft or implant studies ± melatonin; Human blood from women exposed to LAN | Strengths; Evaluated role of melatonin in LAN-induced tumors; Human relevance; Limitations; Measured only tumor progression and growth | Co-exposure to melatonin restored mammary-gland tumor inhibitory activity in initiation-promotion studies of continuous light; Co-exposure to melatonin restored human breast cancer inhibitory activity in xenograft studies of dim light or blood from women exposed to LAN
Melatonin levels | Breast cancer | 5 informative cohort studies measuring urinary melatonin levels and follow-up for breast cancer | Strength; Well-designed large cohorts; Limitations; Inconsistencies across studies in urine sampling | Some evidence of inverse relationship with urinary melatonin level, especially among post-menopausal women; inconsistent findings, especially with time period of follow-up, in pre-menopausal women
Abnormal melatonin rhythms (proxy) | Breast cancer; Prostate cancer | Breast cancer; 2 cohort studies (3 publications) and 1 cross-sectional survey of visually impaired people; Prostate cancer; 2 cohort studies | Strengths; Information on different types of visual impairment; Limitations; No control for other potential confounders; however, confounding would likely overestimate the risk; Small number of cases; Cross-sectional study | Decreased breast cancer incidence in blind people; cancer risk decreased with increasing amount of vision loss; Some evidence of decreased prostate cancer among blind people; The degree of melatonin suppression varied with the causes of vision loss; Most blind people have abnormal circadian rhythms; some may have normal rhythms

Table 7-3 Evidence-based mechanistic data

Exposure or MOA | End point or outcome | Evidence stream or approach | Confidence in the evidence | Overall evaluation
Circadian disruption:; Melatonin suppression | Breast cancer | Molecular epidemiology studies measuring nocturnal urinary melatonin levels (or cosinor analysis) in night-shift workers; - Some studies measured LAN and melatonin level among shift workers; Experimental studies of LAN and melatonin suppression in humans; Experimental studies of LAN, melatonin suppression, and tumor promotion in animals; Melatonin studies and cancer in humans (levels or using blind people as a surrogate) and animals; Experimental studies: in vivo or in vitro mechanistic studies | Strong evidence for melatonin suppression in night-shift workers; Database for melatonin suppression in shift-work animal models is inadequate; Strong evidence that electrical LAN exposure in people’s everyday lives (depending on the wavelength, level, duration, and photic history) can cause melatonin suppression; Some evidence that higher melatonin levels are related to decreased cancer incidence; Strong evidence that melatonin can reduce tumor growth and for its oncostatic properties, which may offer protection from all biological effects considered to be hallmarks of cancer; - Oncostatic properties involve epigenetic mechanisms relevant to cancer, particularly breast cancer | Indirect evidence that melatonin suppression contributes to breast cancer development in night-shift workers; Strong evidence that melatonin suppression plays a role in LAN-induced breast carcinogenicity in experimental animals; Data inadequate to evaluate whether LAN during night work contributes to cancer risk
Circadian disruption:; Altered clock-gene expression; SNS dysfunction | Cancer | Molecular epidemiology studies of clock gene expression in night shift workers; Experimental animal studies of simulated shift work or jet lag and SNS dysfunction and/or clock-gene expression; three were carcinogenicity studies; Experimental studies of light and clock-gene expression in humans and animals; Experimental animal studies: clock-gene genetic models (knockout or mutation) and cancer; Experimental studies: in vivo or in vitro mechanistic studies | Some evidence that shift work and LAN alter clock-gene expression in humans and experimental animals; - Limited number of studies with varied protocols; - Most studied Period genes; Moderate evidence that altered clock-gene expression and SNS dysfunction are related to tumor growth; Strong evidence that the circadian system plays an important role in suppressing the hallmarks of cancer; - Tumor suppressor, role in DNA repair, metabolism, cell cycle, cell proliferation, and apoptosis; - Circadian clock is regulated at the epigenetic level; Studies in mice show some evidence that chronic CJL-induced SNS dysfunction has a key role in inhibiting the ATM-p53 tumor suppressor pathway while promoting oncogenic pathways in the liver and other tissues; Some studies in shift workers have found effect modification of clock-gene polymorphisms for both breast and prostate cancer | Strong (although indirect) evidence that disrupted circadian homeostasis (i.e., altered clock-gene expression and SNS signaling) play a role in LAN and shift-work-associated cancers
Night-shift work | Key characteristics of carcinogens | Molecular epidemiology studies among shift workers; Experimental animal studies: simulated shift work or jet-lag models | Moderate evidence for epigenetic changes (clock genes or cancer pathways) in humans; Moderate evidence for changes in estrogen levels in humans; Some evidence to moderate evidence for ↓ DNA repair, ↑ oxidative DNA damage, and ↑ inflammation in night shift workers or animal studies; - DNA repair and inflammation linked to breast tumors in experimental animals; - Oxidative DNA damage correlated with low melatonin levels in shift workers | Shift-work-induced biological effects are related to those controlled by clock genes and/or melatonin; Epigenetic effects are consistent with modes of action involving melatonin circadian clock-gene deregulation; these may be early events; Studies in experimental animals provide a link between biological effects and tumor progression or growth
LAN | Key characteristics of carcinogens | Experimental animal studies | Strong evidence for metabolic changes that promote tumor growth; - Linked to LAN-promoted growth and progression of breast and other tumors in animals; Some evidence for ↑ oxidative stress, ↑ DNA damage, ↑ inflammation, and changes in estrogen levels or function; - DNA damage, oxidative stress, and estrogen effects linked to mammary-gland or other tumor growth in experimental animals | LAN-induced biological effects are related to those controlled by clock genes and/or melatonin; Studies in experimental animals provide a link between biological effects and tumor progression or growth

## 7.5 Resources and Recommendations for Limiting Exposure

The cancer hazard conclusion for night shift work is for specific working conditions, i.e., persistent night shift work that causes circadian disruption. Several agencies and health organizations — e.g., National Institute for Occupational Safety and Health (NIOSH), Occupational Safety and Health Administration (OSHA) and the Canadian Centre for Occupational Health and Safety (CCOHS) — have provided recommendations for limiting the types of working conditions that may be associated with cancer. They include: (1) guidelines for employers regarding scheduling worker shifts such as the type, number of shifts and recovery, and rest periods and (2) recommendations, training, and factual information for employees working night shifts. Links to these resources are listed below.

- NIOSH: https://www.cdc.gov/niosh/topics/workschedules/
- OSHA: https://www.osha.gov/SLTC/workerfatigue/additionalinformation.html
- CCOHS: https://www.ccohs.ca/oshanswers/ergonomics/shiftwrk.html

Several federal agencies have issued regulations regarding night shift schedules (such as limiting the frequency and length of night shifts and requiring recovery or rest periods) or provide guidance to reduce working conditions that could lead to circadian disruption; these are listed below. Other federal regulatory agencies (e.g., the Federal Motor Carrier Safety Administration and the Department of Veterans Affairs) have promulgated regulations associated with duty time. Those regulations limit the number of hours worked in general (e.g., limitations on driving time), without specifically addressing work performed within the time period (midnight to 5:00 AM) defined as night work in this profile, and therefore are not included here. Currently, no specific OSHA standard exists for extended or unusual work shifts; however, OSHA does provide recommendations for shift workers and employees as mentioned above.

Table 7-4 Federal regulations to limit exposure to night shift work resulting in circadian disruption

Agency | Limits hours worked during night | Limits frequency consecutive night shifts | Provides for recovery or rest periods
Federal Aviation Administration (FAA) | X | X | X
Federal Railroad Administration (FRA) | | X | X
Nuclear Regulatory Commission (NRC) | | | X

American Conference of Governmental Industrial Hygienists (ACGIH) has provided guidance for optimizing lighting conditions (e.g. balance of using blue wavelength-depleted light and blue-wavelength-enriched light that is appropriate for the task) in occupational settings to minimize circadian disruption.