# 6 Mechanistic and Other Relevant Data

Epidemiological studies provide evidence that persistent night shift work increases the risk for breast cancer, and to a lesser degree, prostate cancer (see Sections 3 and 4, respectively). Some human studies have also reported an association between environmental exposure to light at night (LAN) (outdoor or indoor) and increased breast cancer risk; however, it is unclear whether these studies were measuring LAN that affects the circadian system or were using LAN as a proxy for other human activities associated with LAN. Studies in experimental animals demonstrate that exposure to light (including dim light) during the biological night or phase shifts in the light-dark cycle promote tumor growth and development (Section 5).

The proposed mechanism by which persistent night shift work and LAN cause cancer is by circadian disruption. As discussed in Section 2, studies in experimental animals and humans have shown that night shift work and LAN suppress nighttime melatonin secretion and cause circadian disruption. In addition to melatonin suppression, night shift work, transmeridian travel (i.e., jet lag), and LAN induce phase shifts to varying degrees in the central and peripheral clocks. Inherent differences in both the rate of phase shift and the rate of phase adjustment (i.e., re-entrainment) leads to internal desynchronization within and between various cells, tissues, and brain regions (Haus and Smolensky 2013).

This section reviews the mechanistic data associated with night shift work and LAN (or light during the biological night) and cancer including a discussion of mechanistic issues related to breast cancer (Section 6.1), proposed mechanisms of circadian disruption and cancer (Section 6.2), and a review of studies evaluating the relationship of LAN and shiftwork and key characteristics of carcinogens (Section 6.3) (Smith et al. 2016). As mentioned in Sections 1 and 2, shift work is a complex exposure scenario and includes other factors in addition to LAN (e.g., reduced exposure to sunlight and vitamin D deficiency, sleep deprivation, and altered meal timing). The potential link of these exposures to cancer are also reviewed (Section 6.4).

## 6.1 Overview of breast cancer development

Breast cancer is a heterogeneous and complex disease involving multiple risk factors, subtypes, and mechanisms of action that are not fully understood (Russo and Russo 2011, Institute of Medicine 2012, Anderson et al. 2014, Chollet-Hinton et al. 2017). It is clear that the mechanisms and etiologic factors involved in breast cancer development vary by age at exposure, intensity of exposure, genetic background, reproductive history, hormone receptor status, and stage of breast tissue development at the time of exposure (Institute of Medicine 2012).

There are two principal etiological subtypes (an earlier onset subtype with a peak frequency near age 50 and a later onset subtype with a peak frequency near age 70) that underlie the clinical spectrum of breast cancer (Anderson et al. 2014). In addition to differences in the age-specific incidence rate curves, these two clinical subtypes also have different risk factors, clinical courses, and molecular profiles. The earlier onset breast cancers are generally estrogen receptor (ER)-negative with an aggressive clinical course while the later onset breast cancers are ER-positive with a less aggressive clinical course. Molecular data show that these two breast cancer subtypes are fundamentally different diseases arising from two main cell types (luminal vs. basal/myoepithelial) and are distinguished by differences in gene expression patterns (e.g., ER, progesterone receptor [PR], human epidermal growth factor receptor 2 [HER2]).

### 6.1.1 Breast development and susceptibility

Epidemiological data and rodent models of mammary carcinogenesis demonstrate that there are high risk tumor susceptibility windows that encompass different stages of development (i.e., prenatal life, infancy, puberty, early adulthood, and timing of first pregnancy) (Russo and Russo 2008, Russo and Russo 2011). Other than genetic susceptibility, some known risk factors for breast cancer are associated with reproductive events that influence lifelong estrogen exposure including age at menarche, age at menopause, absence of childbearing, age at first full-term pregnancy, and/or number of full-term pregnancies (Dall and Britt 2017). The protective effect of parity is restricted to hormone receptor-positive tumors (ER+, PR+) and diminishes with age such that women who give birth to their first child at age 35 or older have a greater risk of breast cancer than women who remain childless. The data further show that the timing of hormone exposure (i.e., early life) is more important to overall lifetime cancer risk than the number of years exposed or cumulative lifetime exposure (Rodgers et al. 2018).

Although the data clearly show that the young mammary gland represents a window of cancer susceptibility, the underlying mechanisms are less clear (Russo and Russo 2011, Dall and Britt 2017). Proposed mechanisms are related to the peripubertal stage when mammary growth is exponential, and highly proliferative terminal end buds are present throughout the gland (Fenton 2006). Increased sensitivity has been attributed to the high proliferative index of the mammary gland at puberty, thus increasing the probability of mutations and error-prone DNA repair (Dall and Britt 2017). Another possibility is that the increased number and density of terminal end buds is related to the presence of transformation-sensitive mammary stem cells; however, experimental support for mammary stem cells being housed and enriched in the terminal end buds is conflicting.

The mechanisms underlying the protective effect of parity against breast cancer are not completely understood; however, rodent models show that it is hormonally driven (Dall and Britt 2017). Pregnancy stimulates terminal differentiation in the mammary tissue through conversion of immature type 1 lobules to fully differentiated type 3 lobules. Mammary tissue in nulliparous women consists primarily of type 1 lobules. Type 3 lobules are more growth quiescent and are more resistant to oncogenic transformation than rapidly proliferating cells. However, the protective effect of parity may be eliminated if the mammary tissue is exposed to environmental carcinogens or endocrine disrupting chemicals prior to the pregnancy (Russo and Russo 2011).

### 6.1.2 Timing of shift work and LAN exposure and breast cancer development

The timing of exposure to LAN early in life affects breast cancer risk throughout life (Stevens 2012, Stevens et al. 2014). The risk of breast cancer among women beginning shift work at a younger age (i.e., before 30 or before their first full-term pregnancy) and continuing to work for 10 or more years was significantly elevated in several studies (see Section 3). Women shift workers also appear to have a greater risk for hormone receptor-positive breast cancers and have a shorter latency period than observed in day workers. Thus, the data suggest that timing of exposure to shift work or LAN during susceptible hormonal stages (e.g., working shifts at early ages and/or prior to the first full-term pregnancy) is more likely to increase breast cancer risk.

These data are consistent with the hypothesized hormonal pathway as a potential mechanism linking shift work and breast cancer. This pathway is related in part to melatonin suppression and is discussed in the following section.

Studies in experimental animals support the human findings. Rodent models show that the number and size of the terminal end buds are related to sensitivity to chemical carcinogens (Russo and Russo 1978, Dall and Britt 2017) and that the timing of light exposure affects tumor yield (Stevens et al. 2014). Constant light (150 lux), initiated in utero and continued immediately after birth, significantly increased mammary gland sensitivity to DMBA-induced carcinogenesis in rats when administered to female offspring at age 55 days (Mhatre et al. 1984, Shah et al. 1984). The increased sensitivity in the offspring was attributed to a clear positive correlation between circulating levels of prolactin and morphogenic and mitogenic effects on mammary epithelium as measured by development of terminal end buds and alveolar buds and DNA synthesis. In contrast, when female rats were exposed to constant light (~175 lux) at age 26 days and administered DMBA at age 52 days, tumor yield was significantly lower than in rats exposed to 8 hours light and 16 hours dark (Anderson et al. 2000). In this case, constant light exposure significantly accelerated mammary tissue development beyond the stage that is normally observed in virgin animals (i.e., to the lactation stage). Thus, the tissue had differentiated beyond the period of optimum sensitivity. The effects of LAN on sex hormones are further discussed in Section 6.3.6.

## 6.2 Circadian disruption and cancer: mechanistic links

Circadian disruption has been linked to cancer and thus is proposed to be the major mechanism by which night shift work and electric LAN cause cancer. Studies in humans and experimental animals provide evidence that these exposure scenarios disrupt melatonin homeostasis and deregulate clock genes in the central clock and peripheral tissues and that disruption of SCN clock-controlled neuroendocrine homeostasis drives symptoms associated with these exposures and promotes tumorigenesis. Sympathetic signaling has been hypothesized to regulate tumor suppression in a peripheral clock-dependent manner (Dibner et al. 2010, Greene 2012). Some of the major pathways linking circadian disruption and cancer include upregulation of oncogenes, downregulation of tumor suppressors, and altered fatty acid uptake and cell energy metabolism.

Other evidence that supports a link between circadian disruption and cancer comes from studies showing disruption of the clock regulatory loops, mutations, deregulated expression, and translocations of core clock genes in human breast, prostate, and other cancers. In addition, expression of some clock genes (Davis and Mirick 2006, Cadenas et al. 2014, Karantanos et al. 2014, Mazzoccoli et al. 2014, Altman 2016, Reszka and Przybek 2016) and other markers of circadian disruption (e.g., rest-activity rhythms and cortisol rhythms) have been identified as independent prognostic factors for overall survival in breast, colorectal, and other cancer patients (Mormont et al. 2000, Sephton et al. 2000, Lévi et al. 2014, Ballesta et al. 2017). This section describes the mechanistic data that link circadian disruption to cancer as measured by disruption of the sympathetic branch of the autonomic nervous system (SNS), melatonin suppression, and altered clock gene expression patterns.

### 6.2.1 Sympathetic nervous system

The SNS is a major neural output pathway of the SCN central clock as it innervates all peripheral organs except skeletal muscle (Buijs and Kalsbeek 2001, Furness 2006, McCorry 2007) and SNS dysfunction has been implicated as playing a role in various human cancers, including breast and prostate (reviewed in Lee et al. 2010). Although the link between SNS circadian dysfunction in human shift work and jet lag disorders is widely recognized (Adams et al. 1998, Carter et al. 2002, Ishii et al. 2004, Gangwisch et al. 2013, Reid and Abbott 2015), the role of SNS dysfunction in night shift work- or LAN-induced cancer has not been investigated in human epidemiological studies. However, a few studies in experimental animals show that chronic simulated jet lag desynchronizes the central clock-SNS-peripheral clock axis and that SNS circadian dysfunction can directly promote oncogenic activation. This section briefly describes studies of the links between SNS dysfunction and cancer, studies on shift work and SNS function, and possible mechanisms of circadian disruption-related cancer.

#### SNS and cancer

The relationship between the SNS and cancer is likely mediated by catecholamines (i.e., norepinephrine and epinephrine) via chronic stress-response pathways that can result in adverse biological effects, including cancer development and growth (reviewed by Greene 2012). Catecholamines or adrenergic receptors are involved in tumor cell proliferation, angiogenesis, metastasis, and expression of inflammatory and chemotactic cytokines. For example, epinephrine-mediated ß-adrenergic receptor activation reduced the sensitivity of prostate and breast cancer cells to apoptosis while breast cancer metastasis was strongly induced by chronic stress via ß-adrenergic receptors. Accumulated evidence has also shown that inhibition of ß-adrenergic receptor-mediated SNS dysfunction can reduce the risk of various cancers and also potentially improve anticancer therapeutic indices in humans (Sephton and Spiegel 2003, Cole et al. 2015, Simó et al. 2018). Since the SNS also controls melatonin secretion via ß1 adrenergic pathways (Nesbitt et al. 2014), it is likely that SNS circadian dysfunction is also a key pathophysiological mechanism that drives LAN-induced melatonin suppression.

#### Shift work and SNS

Two studies in mice show that chronic simulated jet lag desynchronizes the central clock-SNS-peripheral clock axis and that SNS circadian dysfunction can directly promote oncogenic activation (Lee et al. 2010, Kettner et al. 2016). These studies show that chronic jet lag-induced SNS dysfunction plays a key role in suppression of the ATM-p53 tumor suppressor pathway as well as promotion of multiple oncogenic pathways in peripheral tissues including those controlled by Ap1, Creb, ß-Catenin, and c-Myc. Ablation of genes encoding the three ß-adrenergic receptors in mice completely prevented chronic jet lag-induced Ap1, Creb, ß-Catenin, and c-Myc activation and spontaneous hepatocellular carcinoma (Kettner et al. 2016). Lee et al. (2010) demonstrated that chronic jet lag induced tumors in the same organ systems as observed in circadian gene-mutant mice. Fu et al. (2005) also demonstrated in a mutant mouse model that ß-adrenergic signaling simultaneously activated the peripheral clock via Per genes and the cell-cycle clock via the cAMP response element binding protein (CREB)-AP1-Myc signaling in osteoblasts. Activation of peripheral clocks by SNS signaling is required for preventing uncontrolled cell-cycle progression as clock-gene-deficient cells exhibit elevated CREB-AP1-Myc signaling and accelerated cell proliferation in response to ß-adrenergic receptor activation (Fu et al. 2005, Lee et al. 2010).

### 6.2.2 Melatonin suppression

Melatonin has a prominent role in circadian biology and exerts its effects through both receptor-mediated and receptor-independent pathways. As such, it is often used as a biological marker of circadian regulation and disruption (IARC 2010). Although melatonin is produced in other tissues (e.g., skin and gastrointestinal tract), circulating levels of melatonin are primarily produced by the pineal gland (see Section 1.1.1). LAN exposure was first proposed as a possible risk factor for breast cancer in women in the late 1980s based on the observation that breast cancer risk increases dramatically as societies industrialize and that exposure to LAN suppresses melatonin production by the pineal gland and shifts its rhythm (Stevens 1987, Stevens et al. 1992, Papantoniou et al. 2014, Gómez-Acebo et al. 2015). These observations led to formulation of the melatonin hypothesis (Stevens 1987, Stevens and Davis 1996). The mechanism originally proposed for the melatonin hypothesis was as follows: (1) LAN and/or electric fields produced by electricity lowers melatonin production, (2) lower melatonin levels in the blood enhances estrogen production by the ovary and prolactin production by the pituitary gland, and (3) constant exposure to estrogen and prolactin increases the turnover rate of breast epithelial stem cells and increases the risk of breast cancer (Stevens 1987). Most of the information on the melatonin and prolactin relationship is from nocturnal rodents and shows that prolactin secretion is inhibited by melatonin via the MT1 receptor; however, this does not seem to be the case in humans where the prolactin and melatonin circadian rhythms are approximately in phase (Dubocovich et al. 2003, Dubocovich and Markowska 2005, Goel et al. 2009, Hardeland 2014).

Studies relevant to evaluating the relationship of melatonin suppression and cancer (primarily female breast cancer) are discussed below and include studies of melatonin levels and cancer in humans and experimental animals as well as mechanistic studies on the biological effects (primarily key characteristics of carcinogens) of melatonin.

#### Human studies of melatonin suppression and breast cancer and prostate cancer

Data for breast cancer and melatonin levels are available from six prospective studies in independent cohorts, including the Nurses’ Health Study (NHS) (Schernhammer et al. 2009, Devore et al. 2017), Nurses’ Health Study 2 (NHS2) (Schernhammer and Hankinson 2005, Brown et al. 2015), Women’s Health Initiative (WHI) (Sturgeon et al. 2014), the Guernsey cohort (Wang et al. 2014), the Hormones and Diet in the Etiology of Breast Cancer Risk (ORDET) pre- and post-menopausal cohorts (Schernhammer et al. 2008, Schernhammer et al. 2010), and the Singapore Study (Wu et al. 2013). The findings suggest that melatonin levels are inversely associated with breast cancer risks among postmenopausal women; however, findings are conflicting in studies of pre-menopausal women (Figure 6-1).

The Singapore study (Wu et al. 2013) collected randomly timed spot urine specimens, which are not considered valid measures of the overnight peak and accumulation of melatonin, thus only five cohorts are included in the discussion or forest plot. Concern that preclinical breast cancer may influence melatonin levels led investigators in all cohorts, with the exception of Wang et al. (2014), to examine estimates by the number of years between the time the samples were collected and when breast cancer was first diagnosed. Two NHS2 studies reported no differences in the association of melatonin levels (based on first morning spot urine samples) and breast cancer risk with or without shift workers (Schernhammer and Hankinson 2005, Brown et al. 2015); however, no information was provided on whether the populations included shift workers in the other studies (Schernhammer et al. 2008, Schernhammer et al. 2009, Schernhammer et al. 2010, Sturgeon et al. 2014, Wang et al. 2014, Devore et al. 2017).

Figure 6-1 Relationship of urinary melatonin levels (top quartile vs. bottom quartile) and risk of breast cancer

The figure depicts a forest plot of the risk of breast cancer and urinary melatonin levels in pre- and postmenopausal women. Of the 3 studies reporting on premenopausal women, none reported statistically significant elevated risk estimates. Of the 5 studies reporting on postmenopausal women, 3 studies reported significant inverse relationship between urinary melatonin levels and breast cancer.

Overall, results are mixed among premenopausal women. In the updated NHS2 study (Brown et al. 2015), the risk of breast cancer was significantly lower among women with melatonin levels in the lowest quartile who were diagnosed within 5 years of sample collection, but not among those diagnosed 5 or more years after collection; furthermore, this reduced risk was limited to cases accrued only during the early years of follow-up. Opposite results were found in the premenopausal ORDET cohort (Schernhammer et al. 2010), in which high melatonin levels were non-significantly associated with reduced risk of breast cancer among those diagnosed more than 4 years after sample collection. Among post-menopausal women, Devore et al. (2017) (NHS) and Schernhammer et al. (2008) (ORDET) reported overall statistically significant inverse relationships between melatonin levels and breast cancer risk. Similar to findings in the updated NHS2 premenopausal cohort (Brown et al. 2015), the updated NHS postmenopausal study (Devore et al. 2017) found no effect among cases recruited during the latter half of follow-up. In the ORDET post-menopausal cohort (Schernhammer et al. 2008), the inverse effect became stronger among women diagnosed four or more years after sample collection. Neither the WHI (Sturgeon et al. 2014) nor Guernsey cohorts (Wang et al. 2014) reported any effect.

Heterogeneity in the results could potentially arise from differences in urine sampling, with the ORDET cohorts using 12-hour overnight collections and the NHS/NHS2 cohorts primarily using first morning urines, with some small percentage using spot urines. In addition, an unreported number of urine samples collected in the WHI may not have been a first morning void (Sturgeon et al. 2014). Smoking prevalence, which varied widely across cohorts (e.g., 24.5% in the ORDET cohorts; 7% in the NHS2 cohort) may also influence the results, as smoking stimulates cytochrome P450 1A2 activity, which is the primary enzyme in melatonin metabolism.

While studies of hormone levels in recently diagnosed cases should be considered with some caution due to issues of temporality, two studies reported findings on melatonin levels in cancer cases and controls. A recent small cross-sectional clinical study in Brazil compared melatonin levels in women recently diagnosed with breast cancer, women under adjuvant chemotherapy, and nurses working night-shifts with melatonin levels in healthy, age-matched controls (de Castro et al. 2018). Breast cancer cases had lower levels of melatonin compared to healthy controls, and levels were even lower in night-shift nurses and in patients under adjuvant chemotherapy. Tai et al. (2016) examined the relationship between two circadian-related hormones with oncostatic and immunosuppressive activity (melatonin and cortisol) and the presence of prostate cancer in a case-control study (120 prostate cancer patients and 240 age-matched controls). This study reported that patients with lower urinary melatonin sulfate levels or a lower urinary melatonin/cortisol ratio were more likely to have prostate cancer.

#### Human studies of melatonin suppression and cancer in blind populations

The melatonin hypothesis also predicted that studies of totally blind populations would show a decreased risk of LAN-induced cancers because melatonin levels would not be suppressed by LAN exposure (Feychting et al. 1998, Stevens 2009). Several studies support this prediction, reporting that breast cancer incidence in women is inversely associated with blindness as well as the degree of visual impairment (Hahn 1991, Feychting et al. 1998, Verkasalo et al. 1999, Kliukiene et al. 2001, Pukkala et al. 2006, Flynn-Evans et al. 2009). Severe visual impairment includes individuals with a complete lack of light perception (~15% of the legally blind population) as well as those with varying degrees of light perception (Lewy et al. 2004). Abnormally phased, or free running, circadian rhythms are common among individuals with no light perception; however, daily melatonin treatment usually helps them entrain. In a study of 49 registered blind individuals with different causes of visual loss, Lockley et al. (1997) reported that the majority of subjects (14 of 19) with some light perception had normally entrained melatonin rhythms while the majority of subjects with no light perception had abnormal melatonin rhythms (23 of 30) or free-running rhythms (17 of 30).

Two studies also suggest that prostate cancer risk may be lower in blind populations. Feychting et al. (1998) found a non-significantly decreased risk of prostate cancer in totally blind people with no light perception (SIR = 0.71, 95% CI = 0.43 to 1.09). Pukkula et al. (2006) reported a non-statistically significant decrease in the SIR of prostate cancer; however, this estimate was based on only one observed case (SIR = 0.28, 95% CI = 0.01 to 1.56) in 21 years of follow-up.

Overall, these data suggest that there may be a lower risk of hormone-dependent tumors in visually impaired individuals, and the protective effect may depend on the degree and type of visual impairment.

#### Animal studies of melatonin and cancer

There is compelling evidence that melatonin can reduce the incidence and growth of tumors, especially breast cancer, through mechanisms that affect tumor initiation, promotion, and progression (Blask et al. 2002a, Mediavilla et al. 2010, Blask et al. 2014, Hill et al. 2015). This section describes effects of melatonin on reducing development and growth of tumors promoted by LAN or independent from LAN (see Section 5 for more details of LAN effects on tumor growth).

LAN studies: LAN exposure, including dim LAN as low as 0.2 lux, suppresses nocturnal melatonin levels in a dose-dependent manner (as measured in serum or urinary metabolites) in rodents and stimulates tumor growth (Anisimov et al. 1994, Dauchy et al. 1997, Dauchy et al. 1999, Blask et al. 2002a, Blask et al. 2005, Cos et al. 2006, Blask et al. 2009, Blask et al. 2014, Dauchy et al. 2014, Schwimmer et al. 2014). Most of these studies used continuous bright or dim LAN; however, two studies (Cos et al. 2006, Schwimmer et al. 2014) also used a 30-minute light pulse during the middle of the scotophase (i.e., period of darkness). Some of these studies also investigated the effects of exogenous melatonin (oral or injected), melatonin-enriched blood, and/or melatonin-depleted blood (collected from women exposed to LAN or collected during the daytime) on tumor growth and are described below.

Administration of exogenous melatonin inhibited the growth of LAN-induced spontaneous tumors and LAN promotion of chemically induced mammary and colon tumors (Tamarkin et al. 1981, Shah et al. 1984, Kothari 1987, Anisimov et al. 2012). In a similar fashion, LAN-promotion of MCF-7 xenografts (including steroid receptor-positive and -negative tumors) in nude rats or rat hepatomas implanted in Buffalo rats (see Section 5) was inhibited when tumors were perfused in situ with melatonin-enriched rat or human blood (i.e., rat blood enriched with synthetic melatonin or blood collected from human volunteers during the night) (Blask et al. 2005, Blask et al. 2009, Blask et al. 2014). In contrast, MCF-7 xenografts or rat hepatomas perfused with melatonin-depleted blood (i.e., blood collected from human volunteers either during the daytime or after exposure to LAN) exhibited high tumor-proliferative activity. Other studies showed that administration of exogenous melatonin in drinking water reversed LAN-promoted growth of MCF-7 xenografts in nude rats (Dauchy et al. 2014) and murine 4T1 mammary cancer cells in female BALB/c mice (Schwimmer et al. 2014). The tumor suppressive effects of exogenous melatonin in LAN-exposed animals were completely blocked when a nonselective melatonin receptor antagonist was added to the blood perfusate (Blask et al. 2005, Dauchy et al. 2014). However, one study reported that melatonin administered in drinking water had no effect on LAN promotion of murine B16 melanoma cells inoculated into male C57BL6 mice (Otálora et al. 2008).

Other studies investigated the effects of the daytime light exposure on melatonin and tumor growth (Dauchy et al. 2015, Dauchy et al. 2018). These studies reported that exposure to blue-enriched light during the daytime amplified the nocturnal melatonin signal and inhibited the growth of human PC3 prostate cancer xenografts in male nude rats and Morris 7288CTC rat hepatoma implants in male Buffalo rats. These studies provide further support that the total daily light exposure (light during the day and electric light at night) is important for circadian regulation.

Non-LAN studies: Several studies, including a few studies reviewed in the previous section, also investigated the effects of melatonin on tumor growth independent from LAN exposure. Melatonin administered in tap water inhibited growth of chemically induced mammary and colon tumors in rodents (Shah et al. 1984, Kothari 1987, Anisimov et al. 1997, Anisimov et al. 2000, Lenoir et al. 2005) and inhibited growth of human leiomyosarcoma xenografts in nude rats (Dauchy et al. 2009b), murine TRAMP-C2 prostate cancer cells implanted into male C57BL/6 mice (Haim et al. 2010), rat hepatoma implants in male Buffalo rats (Blask et al. 2004), and murine B16 melanoma cells in male mice (Otálora et al. 2008). Growth of hepatoma implants in male Buffalo rats was also inhibited by perfusion with melatonin-enriched rat blood (Blask et al. 1999). In vitro studies of several MCF-7 human breast cancer cell lines (ERα+, steroid receptor negative, Her2-positive SKBR-3, Her2.1, and caSrc) demonstrated that melatonin added to the culture medium at physiological concentrations significantly reduced the invasive/metastatic phenotype either by promoting mesenchymal-to-epithelial transition or inhibiting key metastatic signaling pathways (Mao et al. 2012, Mao et al. 2016a). These studies also showed that exogenous melatonin suppressed metastasis of MCF-7 xenografts in nude mice and nude rats.

Studies using pinealectomized rodents also show enhanced growth of chemically induced or transplanted tumors that is the same as the response to LAN (Aubert et al. 1980, Tamarkin et al. 1981, Blask et al. 1999, Blask et al. 2004). In both cases, the effect has been attributed to suppressed melatonin production (Dauchy et al. 1999, Blask et al. 2005, IARC 2010) such that LAN exposure has been described as functional pinealectomy (Shah et al. 1984, Stevens et al. 2000, Anisimov et al. 2012). Mammary tumor incidence in pinealectomized rats administered exogenous melatonin during the tumor induction phase or after tumors were already present was decreased (Aubert et al. 1980, Tamarkin et al. 1981).

In addition, Hill et al. (2013) reported that the age-related decline in melatonin production in rats was directly related to the observed age-associated enhanced growth of NMU-induced mammary tumors and a reduced sensitivity to inhibition by exogenous melatonin. These data clearly show that melatonin has oncostatic activity and is discussed further in the following section.

#### Biological effects of melatonin related to cancer

Melatonin is known to exert multiple effects that are directly relevant to cancer development and progression. These effects include multiple tumor defense mechanisms that offer some protection against all the biological effects that are recognized as hallmarks of cancer (Erren 2005, Hill et al. 2015, Talib 2018). These oncostatic properties of melatonin have been demonstrated in numerous human cancers and cell lines including breast, prostate, sarcomas, colorectal, liver, skin, ovarian, cervical, neural, and larynx as well as in murine tumor models (Mediavilla et al. 2010). The anti-initiating and oncostatic effects of melatonin and supporting mechanistic data have been extensively reviewed (Blask et al. 2002a, Mirick and Davis 2008, Mediavilla et al. 2010, Srinivasan et al. 2011, Hardeland 2014, Gurer-Orhan and Suzen 2015, Haim and Zubidat 2015) and include anti-estrogenic properties, modulation of the cell cycle, anti-mitotic activity, differentiation and apoptosis, inhibition of telomerase activity, antioxidant effects, inhibition of angiogenesis, inhibition of metastasis, enhancing immune response, inhibiting fatty acid transport and metabolism, and modulating gene expression through interaction with clock genes and epigenetic events. In addition, several lines of evidence suggest that the oncostatic properties of melatonin involve epigenetic mechanisms relevant to cancer, and particularly breast cancer (Korkmaz et al. 2009, Hardeland 2014, Schwimmer et al. 2014). These epigenetic processes include the following: (1) influence on the transcriptional activity of nuclear receptors involved in the regulation of breast cancer cell growth (e.g., ERα, glucocorticoid receptor, retinoic acid receptor), (2) down-regulation of genes involved in the synthesis or activation of estrogens (e.g., aromatase), (3) inhibition of telomerase activity or expression induced by estrogens, (4) modulation of the cell cycle through inhibition of cyclin D1 expression, and (5) influence on circadian rhythm disturbances dependent on the light/dark cycle and deregulation of PER2 tumor suppressor gene activity (reviewed by Korkmaz et al. 2009). Studies of epigenetic effects in animal models of chronic jet lag or LAN and in shift workers are reviewed in Section 6.3.2.

Many of melatonin’s oncostatic actions are mediated via the MT1 receptor and modulation of downstream cell proliferative and survival signaling pathways including aerobic glycolysis (Warburg effect), cAMP, linoleic acid uptake and metabolism to 13-hydroxyoctadecadienoic acid (13-HODE), tumor kinase signaling, and transcriptional activity of mitogenic nuclear receptors (e.g., ERα, retinoic acid receptor-related orphan receptor alpha (RORα), and glucocorticoid receptors) (Blask et al. 2002b, Dauchy et al. 2003, Dauchy et al. 2007, Blask et al. 2011, Wu et al. 2011, Blask et al. 2014, Dauchy et al. 2014). Melatonin suppressed metastasis in human breast cancer cells by inhibiting epithelial to mesenchymal cell transition (Mao et al. 2012, Mao et al. 2016b). The molecular pathways involved included activating glycogen synthase kinase 3ß (GSK3ß) activity by inhibiting serine-threonine kinase Akt phosphorylation and inhibiting ribsomal S6 kinase 2 (RSK2) activity. GSK3ß and RSK2 are protein kinases that are key regulators in the signaling networks that modulate epithelial to mesenchymal cell transition and metastasis. Both human epithelial (MCF-7) and mesenchymal (leiomyosarcoma) cancer xenografts perfused in situ with human or rat blood with or without physiological nocturnal levels of melatonin exhibited dose-dependent suppression of tumor cAMP production, linoleic acid uptake, 13-HODE release, mitogen-activated protein kinase (MAPK) activation, and [^3^H]-thymidine incorporation into DNA (Blask et al. 2005, Blask et al. 2009, Dauchy et al. 2009b, Mao et al. 2016a). The suppressive effects of melatonin were prevented by treatment with a melatonin receptor antagonist. These studies provide mechanistic evidence that melatonin, at nocturnal physiological concentrations, suppresses tumor growth via a melatonin-receptor mediated signal transduction pathway involving linoleic acid uptake and metabolism. In vitro studies with a variety of human and murine cancer cell lines (including breast and prostate) also show that physiological concentrations of melatonin generally inhibit cell proliferation and invasiveness while higher concentrations are cytostatic or cytotoxic (Cos et al. 1998, Blask et al. 2002b). However, the dose-response of tumor cells to melatonin varies from a bell-shaped to a linear pattern depending on the cell line and cell culture conditions (Blask et al. 2002b).

The oncostatic actions of melatonin are especially relevant for hormone-dependent neoplasms such as mammary and prostate cancer (Mediavilla et al. 2010). In particular, melatonin’s anti-estrogenic properties are important for its oncostatic effects on hormone-dependent mammary tumors. Melatonin inhibits growth of MCF-7 breast cancer cells, in part, by modulating the estrogen response pathway (Hill et al. 1992, Kiefer et al. 2002). Melatonin treatment, via its MT1 G protein coupled receptor, significantly diminished 17ß-estradiol (E2)-induced ERα transactivation, altered ERα DNA binding activity, suppressed E2’s induction of cAMP, and reduced E2-induced cell proliferation. Melatonin’s anti-estrogenic effects are unique and involve a double mechanism of action: (1) interaction with enzymes involved in the formation and biotransformation of androgens and estrogens (i.e., Selective Estrogen Enzyme Modulator [SEEM], and (2) interaction with estrogenic receptors (i.e., Selective Estrogen Receptor Modulator [SERM]) (Mediavilla et al. 2010).

In addition, there is an increasing body of evidence that estrogens, estrogen receptors, and estrogen signaling mechanisms are required for prostate cancer initiation and progression (Yeh et al. 2014, Bonkhoff 2018). Sainz et al. (2005) reported that pharmacological concentrations of melatonin significantly reduced prostate cancer cell growth in vitro and stopped cell-cycle progression of human androgen-dependent (LNCaP) and -independent (PC3) cell lines. The various pathways and key events associated with melatonin’s oncostatic effects are shown in Table 6-1.

Table 6-1 Oncostatic mechanisms of melatonin

Mechanism | Pathway | Key events: Cellular/molecular effects | Outcome
Selective Estrogen Receptor Modulator (SERM) | Estrogen signaling | ↓ ERá expression; ↓ ERα activation; ↓ Transcription of ERα-dependent genes | ↓ Estrogen response; ↑ Oncostatic activity – estrogen-dependent tumors
Selective Estrogen Enzyme Modulator (SEEM) | Estrogen biosynthesis | ↓ Aromatase; ↓ 17ß-hydroxy steroid dehydrogenases; ↓ Estrogen sulfatase; ↑ Estrogen sulfotransferases | ↑ Weak estrogens (i.e., estrone); ↓ Active estrogens (i.e., estradiol); ↑ Oncostatic activity – estrogen-dependent tumors
Cell proliferation, differentiation, apoptosis | Cell cycle, cell death | ↑ GO-G1 phase, cell-cycle length; ↑ p53, p21, Bax; ↑ Caspases 3, 8, 9; ↑ Cytochrome c; ↓ Cyclin D1 | ↓ Cell proliferation; ↑ Cell differentiation; ↑ Apoptosis (cancer cells); ↑ DNA damage repair; ↑ Oncostatic activity – multiple tumor types
Inhibition of telomerase | Telomere maintenance | ↓ Telomerase reverse transcriptase (hTERT); ↓ Estradiol-induced telomerase activity response | ↓ Number of cell replication cycles; ↑ Oncostatic activity – estrogen-dependent tumors
Antioxidant activity | Oxidative stress response | ↓ Reactive oxygen species (ROS); ↓ Nitric oxide synthase (NOS); ↑ GSH, superoxide dismutase (SOD), catalase; ↑ Cytokines | ↓ DNA damage; ↓ Side effects of chemo- and radiotherapy; ↑ Oncostatic activity – multiple tumor types
Anti-angiogenesis | Neovascularization | ↓ Vascular endothelial growth factor (VEGF); ↓ Hypoxia inducible factor-1α (HIF-1α); ↓ ROS | ↓ Neovascularization; ↑ Oncostatic activity – multiple tumor types
Inhibition of metastasis | Cell surface adhesion molecules and plaques | ↑ E-cadherin; ↑ ß_1_-integrin; ↑ MT1 receptor; ↓ Stimulatory effects of 17ß-estradiol | ↓ Cell invasiveness/metastasis; ↑ Oncostatic activity – multiple tumor types
Immunomodulation | Cellular and humoral immunity | ↑ Natural killer (NK) cells, monocytes, leukocytes; ↑ Cytokines; ↑ Interferon-γ; ↑ TNF-α | ↑ Immunosurveillance; ↑ Oncostatic activity – multiple tumor types
Fatty acid transport and metabolism | Epidermal growth factor/mitogen activated protein kinase (EGFR/MAPK) | ↓ Linoleic acid uptake; ↓ 13-HODE | ↓ Activation of EGFR/MAPK; ↑ Oncostatic activity – multiple tumor types
Prevention of circadian disruption | Clock genes and epigenetic pathways | ↓ Abnormal epigenetic modifications; ↓ Dysfunctional clock genes (SCN and peripheral) | ↑ Internal clock synchronization; ↑ Oncostatic activity – multiple tumor types

Sources: Mediavilla et al. 2010, Srinivasan et al. 2011, Zubidat and Haim 2017.

↓ = decreases, ↑ = increases.

### 6.2.3 Other mechanisms of circadian disruption

Circadian disruption can affect cell-cycle homeostasis and alter the transcription level of clock and clock-controlled genes associated with cell-cycle progression, immune response, cell proliferation, chromatin remodeling, DNA damage repair, metabolism, and apoptosis, all of which could contribute to cancer development and progression (Fu and Kettner 2013, Ben-Shlomo 2014, Soták et al. 2014, Stevens and Zhu 2015). In addition to melatonin suppression, other mechanisms related to circadian disruption include altered clock gene function and expression and desynchronization of the master clock from the peripheral clocks. Filipski et al. (2002) provided the first experimental evidence that circadian disruption (i.e., SCN ablation by bilateral electrolytic lesions) was associated with accelerated growth of implanted Glasgow osteosarcoma or pancreatic adenocarcinoma in B6D2F1 mice that was independent of melatonin as these nocturnal mice have low levels of melatonin secretion and an atypical melatonin rhythm with production and secretion peaking during the day (Li et al. 2000, Filipski et al. 2004).

Overall, the evidence suggests that circadian disruption/desynchronization is an independent risk factor for cancer and that tumor suppression in vivo is, in part, a clock-controlled function (Lee et al. 2010, Kettner et al. 2014). This section reviews the evidence supporting this conclusion including genetic models of clock gene mutations in rodents, polymorphism studies in humans, and in vivo and in vitro gene expression studies.

#### Genetic models in experimental animals

Although circadian disruption in humans does not require mutations in clock genes, a number of clock gene mutant mouse models have been used to investigate the biological effects of circadian disruption and the specific role of the core clock genes. However, with the exception of Bmal1, other core clock genes have at least two functionally redundant isoforms such that clear phenotypic changes may be observed only in mouse models with multiple loss-of-function alleles (Schibler et al. 2015). In general, clock gene suppression (i.e., downregulation of specific genes) or knockouts and mutations in mice are associated with a cancer-prone phenotype and accelerated growth of tumors (Table 6-2) (Wood et al. 2008, Yang et al. 2009b, Lee et al. 2010, Zeng et al. 2010, Mteyrek et al. 2016, Papagiannakopoulos et al. 2016, Mteyrek et al. 2017). Some studies evaluated the effects of exposure to radiation or chemical carcinogens in clock gene mutant or deficient experimental animals.

Table 6-2 Cancer studies of genetic models of clock gene mutations or downregulation in mice

Reference | Animal model | Clock genes | Tumor site | Comments
Wood et al. 2008 | Inactivation | Per2 | Intestine; Colon polyps | Downregulation enhanced proliferation of colon cells in vitro
Yang et al. 2009b | Downregulation | Per2 | Breast | Accelerated tumor cell growth in vivo and in vitro and doubled the daily amplitude of the tumor growth rhythm
Lee et al. 2010 | Mutant; Spontaneous or radiation induced | Bmal1, Per1 and/or Per2; Cry1 and/or Cry2 | Lymphoma; Liver; Ovarian | Uncoupling of p53 and Myc signaling promotes tumor development
Zeng et al. 2010 | Downregulation; Inoculated with C26 mouse colon cancer cells | Bmal1 | Colon | BALB/c mice inoculated with C26 mouse colon cancer cells; increased proliferation in vitro
Papagiannakopoulos et al. 2016 | Germline mutations | Per2, Bmal1 | Lung | Enhanced cell proliferation in lung tumors associated with increased c-Myc levels
Mteyrek et al. 2016, Mteyrek et al. 2017 | Mutant | Cry1, Cry2, and Per2 | Liver; Bile duct | Co-exposure to DEN

#### Clock gene effects

The circadian timing system controls the expression of up to 40% to 50% of transcripts in mammalian genomes in a tissue- and time-specific manner, thus it is important in regulating many biological processes and has broad physiological and pharmacological implications (Huisman et al. 2016, Mure et al. 2018, Ruben et al. 2018). Many of these biological processes and pathways are associated with carcinogenesis (e.g., immune function, chronic inflammation, DNA repair, metabolic disorders and obesity, and premature aging (Fu et al. 2002, Fu et al. 2005, Antoch et al. 2008, Wood et al. 2008, Yang et al. 2009a, Lee et al. 2010, Geyfman et al. 2012, Kettner et al. 2014). Rodent studies have shown that the responses to both gamma and UV radiation damage follow a robust rhythm in vivo and that ablation of the core circadian genes Per2 and Bmal1 in mice was sufficient to abolish circadian rhythms of DNA damage response (Fu et al. 2002, Panda et al. 2002, Geyfman et al. 2012). Thus, one of the expected consequences of circadian disruption is altered DNA repair.

As discussed in Section 1.1, the central clock in the SCN regulates cell proliferation and apoptosis in peripheral tissues at the systemic level through the SNS and the neuroendocrine system (Fu and Lee 2003). Deregulated SNS signaling induces oncogenic activation and suppresses clock genes and ATM-p53 signaling, thus leading to uncontrolled cell proliferation and contributing to tumor initiation (Fu et al. 2005, Lee et al. 2010, Kettner et al. 2016). Estrogens and glucocorticoids also regulate cell proliferation and apoptosis in peripheral tissues (Fu and Lee 2003). Post-translational modifications of clock proteins are also important for proper clock function and regulatory fine-tuning of the circadian molecular clockworks (Mehra et al. 2009, Hirano et al. 2016). Thus, circadian disruption can result in abnormal modifications and turnover of clock proteins. These data indicate that the circadian system plays an important role in suppressing the hallmarks of cancer (Greene 2012).

At the cellular and molecular level, the circadian clocks in peripheral tissues operate as interlocked feedback loops and are coupled to the cell cycle (Gérard and Goldbeter 2012, Fu and Kettner 2013, Ballesta et al. 2017). Therefore, disruption of either the positive or negative loop leads to loss of control in the circadian homeostasis of cell-cycle progression. Several molecular components of the cell cycle network exhibit circadian rhythms and, as such, can be entrained by the circadian clock (Gérard and Goldbeter 2012). Examples of genes involved in cell-cycle regulation, DNA damage checkpoints and apoptosis that are under circadian control include proto-oncogenes (e.g., AP1, Creb, Ras, c-Myc, Mdm2, ß-catenin), tumor suppressor genes (e.g., Atm, p53, p21, Wee1, AMP-kinase, Gadd45α), and genes that encode the caspases, cyclins, cyclin-dependent kinases (CDKs), transcription factors, and ubiquitin-associated factors (Fu and Lee 2003, Chen-Goodspeed and Lee 2007, Fu and Kettner 2013, Kelleher et al. 2014, Uth and Sleigh 2014, Altman 2016). The expression patterns of cell-cycle genes and p53 are synchronized with the expression patterns of the core circadian genes in human and rodent somatic tissues (Bjarnason et al. 1999, Bjarnason et al. 2001, Fu et al. 2002, Lee et al. 2010, Fu and Kettner 2013, Kettner et al. 2015). Per2 binding modulates the stability of p53 by preventing ubiquitination in unstressed cells while increasing p53 transcriptional activity in response to genotoxic stress (Gotoh et al. 2016). Both these processes are related and are mediated by Per2 regulation of p53 subcellular trafficking from the cytoplasm to the nucleus.

The CLOCK-BMAL1 heterodimer also directly regulates genes that play an essential role in cell-cycle control, including blocking c-Myc overexpression (Fu et al. 2002, Fu et al. 2005, Sahar and Sassone-Corsi 2007, Lee et al. 2010). CLOCK also possesses intrinsic histone acetyltransferase (HAT) activity that can affect cell proliferation and differentiation in multiple ways including chromatin remodeling and interaction with key cell-cycle proteins (e.g., p53 and c-MYC) and transcription factors (e.g., ERα, NF-κB, c-JUN) (Doi et al. 2006, Sahar and Sassone-Corsi 2007). PER1 and PER2 tumor-suppressor activity involves regulation of the ATM-Chk1/Chk2 DNA damage-response pathway (Gery et al. 2006, Chen-Goodspeed and Lee 2007, Takahashi et al. 2008, Lee et al. 2010). PER1 also exerts tumor-suppressor activity by regulating the cyclin-CDK-cyclin-dependent kinase (cyclin-CDK-CK1) inhibitory regulatory network in human oral squamous cell-carcinoma cells (Fu et al. 2016). CRY2 interacts with ATR and CHK1 to regulate intra-S checkpoint function in UV-induced DNA damage response via Timeless (TIM), a natural partner of PER in Drosophila (Ünsal-Kaçmaz et al. 2005), while BMAL1 is involved in p53-dependent p21WAF1/CIP1 induction in human colorectal carcinoma cells (Mullenders et al. 2009). In addition, Per2 expression was upregulated in murine NIH 3T3 fibroblasts and human hematopoietic leukemia cell lines by CCAAT/enhancer-binding proteins (C/EBPs) which include a family of transcription factors that regulate cell growth and differentiation (Gery et al. 2005). These data highlight the role of the circadian clock in regulating oncogenic mechanisms. A simplified model of circadian clock control of cell-growth regulation is shown in Figure 6-2.

Some studies have evaluated the role of clock genes specifically for breast cancer development (reviewed by Zubidat and Haim 2017). Studies that silenced CLOCK and CRY2 genes in MCF-7 breast cancer cells and reported altered expression of a network of genes that are relevant for breast cancer including those involved in cellular growth and proliferation, cell signaling and interaction, tumor suppression, and DNA repair. In these same studies, CLOCK gene expression was lower in women without breast cancer while CRY2 showed lower expression in breast cancer cells compared to normal cells. Another study also reported a link between TIMELESS overexpression and breast cancer risk. There was a significant positive association between breast cancer stage and TIMELESS promoter hypomethylation in peripheral blood lymphocytes taken from breast cancer patients compared to age-matched controls. In addition to breast cancer, Per2, Cry1, and Cry2 were independently found as liver tumor suppressors (Lee et al. 2010, Kettner et al. 2016, Mteyrek et al. 2016, Mteyrek et al. 2017), and Per2 and Bmal1 had important roles as tumor suppressors in mouse models of lung adenocarcinoma (Papagiannakopoulos et al. 2016).

Figure 6-2 Circadian regulation of cell-cycle checkpoints and cell growth

The figure depicts the signaling pathways stimulated by the protein complex of the CLOCK protein bound to the BMAL 1 protein. At the top of the figure, the CLOCK/BMAL 1 complex stimulates 2 different proteins, WEE1 and cyclins, and suppresses one protein, MYC. Suppression of MYC leads to cell proliferation and differentiation. Stimulation of either WEE1 or cyclins lead to cell cycle progression. The CLOCK/BMAL1 complex also initiates transcription of the PER and CRY genes. The Per and Cry proteins then bind together and suppress their own transcription by inhibiting the CLOCK/BMAL 1 complex. DNA damage-repair pathways and/or apoptosis are stimulated by either the Cry protein binding to the Timeless protein and CHK1 protein or by PER1 protein binding to the cell-cycle check point proteins ATM and CHK2.

Sources: Adapted from Takahashi et al. (2008) and Chen-Goodspeed and Lee (2007). The circadian clock controls cell growth by regulating expression of cell-cycle-related genes (e.g., c-Myc, Wee1, Cyclin D1) and interacting with cell-cycle checkpoint proteins (ATM, CHK1, CHK2). Transcription of these cell-cycle genes shows circadian rhythms, and they are direct targets of the CLOCK/BMAL1 complex. CLOCK/BMAl1 also initiates transcription of Per and Cry whose proteins combine to form a heterodimer that translocates to the nucleus and suppresses their own transcription by inhibiting CLOCK/BMAL1. In addition, the PER1 protein interacts with cell-cycle check-point proteins (ATM and CHK2) while CRY and TIMELESS (TIM) interact with CHK1 which can activate DNA damage-repair pathways and/or apoptosis and reset the phase of the circadian clock.

#### Cancer studies of simulated shift work, chronic jet lag, or LAN, and clock genes

Cancer studies of chronic jet lag in experimental animals have found similar effects of the role of clock genes in tumorigenesis as those observed in genetic models. A study in melatonin-deficient mice also demonstrated that simulation of chronic jet lag (8-hour advances in the light/dark cycle every 2 days) resulted in severe circadian disruption (i.e., ablated the rest-activity cycle, altered rhythms of body temperature, serum corticosterone, mPER1 protein expression in the SCN, suppressed mPer2 and mRev-erbα mRNA in the liver and the tumor, and promoted growth of Glasgow osteosarcoma implants (Filipski et al. 2004). Filipski et al. (2005) reported that mice subjected to a chronic jet lag protocol showed altered rhythms and reduced expression of clock genes in the liver of healthy mice and accelerated tumor growth in mice implanted with Glasgow osteosarcoma. The livers of otherwise healthy jet lagged mice showed increased c-Myc oncogene expression and amplified its rhythm while reducing expression of the tumor suppressor p53 by about 50%.

#### Polymorphisms in clock genes

Results from studies that investigated the association of clock gene single nucleotide polymorphisms (SNPs) in shift workers and breast cancer were mixed but reported some evidence that a few clock gene variants were associated with a greater risk of breast cancer (Monsees et al. 2012, Grundy et al. 2013b, Zienolddiny et al. 2013, Rabstein et al. 2014, Truong et al. 2014). A significant association with breast cancer risk was identified for 10 SNPs in five clock genes (Clock, RorA, RorB, Per3, and Npas2) in a recent comprehensive review that included 27 eligible studies, 38,231 cases, 96,756 subjects, and 687 SNPs in 14 clock genes (Benna et al. 2017). Reszka et al. (2017) reviewed results from 15 epidemiological studies (including 5 studies on shift work) that investigated the possible link between clock gene variants and breast cancer. These studies identified BMAL1, BMAL2, CLOCK, NPAS2, CRY1, CRY2, PER1, PER3, and TIMELESS as candidate breast cancer risk variants. SNPs in CLOCK and NPAS2 were the most commonly reported variants modifying breast cancer risk.

Zhu et al. (2009) found that at least one SNP in nine core circadian genes was significantly associated with the risk of developing prostate cancer. Furthermore, risk estimates for four SNPs in three genes (CLOCK, PER1, and PER3) varied by disease aggressiveness. Markt et al. (2015) reported that a CRY1 variant was nominally associated with fatal prostate cancer but did not find a strong and consistent association between clock gene variants and prostate cancer risk. Overall, the data suggest that polymorphisms in clock genes could affect susceptibility to shift work or LAN exposure.

## 6.3 Shift work and LAN studies: Key characteristics of carcinogens

This section presents evidence from human, animal, and/or relevant in vitro studies that shift work and LAN are associated with several biological effects that are commonly exhibited by established human carcinogens and/or other key events with a known connection to cancer. These effects have been shown to (1) alter DNA repair or cause genomic instability, (2) induce epigenetic alterations, (3) induce oxidative stress, (4), induce chronic inflammation and immunosuppression, (5) alter metabolism, and (6) alter hormone rhythms and signaling pathways, and are reviewed below.

### 6.3.1 DNA repair and genomic instability

There are limited data on the genotoxic effects of shift work or LAN in humans or experimental animals; however, the available data show that these exposures can contribute to DNA damage by altering DNA repair and promoting genomic instability. As discussed in Section 6.2, melatonin and the core clock genes have important roles in regulating cell-cycle control and DNA-damage repair.

#### Animal studies of simulated shift work/jet lag or LAN

Experimental animal studies support a link between exposure to simulated jet lag or LAN and inhibition of DNA repair, genomic instability, and mammary, liver, and colon cancer development. Rats exposed to shifting light schedules showed differential expression of 51 genes with a known link to breast cancer (Kochan et al. 2016) and downregulation of genes associated with DNA repair and p53 pathways that promote genomic instability in mammary tissues. Another study reported that simulated jet lag disrupted circadian expression of DNA damage response and repair genes in rats and accelerated mammary tumorigenesis (Fang et al. 2017). Chronic jet lag induced spontaneous hepatocellular carcinoma in wild type C57BL/6J mice by inducing persistent and genome-wide gene deregulation in the liver including genes involved in DNA repair, oxidative stress response, innate and adaptive inflammatory responses, and liver metabolism (see Sections 6.3.3, 6.3.4, and 6.3.5) (Kettner et al. 2016). The finding that p53-null mice developed tumors (e.g., lymphoma, osteosarcoma, liver, ovarian, kidney, and intestinal) under simulated chronic jet lag conditions provided genetic evidence, which supports a role for the p53 pathway in suppressing chronic circadian disruption-induced genomic instability caused by LAN (Lee et al. 2010).

In an initiation-promotion study, rats exposed to 1,2-dimethylhydrazine and held in constant light also had higher rates of DNA damage in colonic epithelial and enteric glial cells and increased development of colon preneoplasia compared to animals exposed to 1,2-dimethylhydrazine and maintained on a standard 12-hour light/dark cycle (Frajacomo et al. 2015).

#### Studies in shift workers

Two studies in humans provide evidence that night shift work is associated with decreased DNA repair and one study suggested that the effects may be related to melatonin. A study of 223 night shift workers and 217 day shift workers found that urinary clearance of 8-OH-dG was significantly lower among night shift workers during their day sleep periods compared to their night sleep periods on their first day off from work and were non-significantly lower than dayworkers suggesting that night work was associated with a reduced capacity to repair oxidative DNA damage. Among night shift workers, urinary levels of 6-sulfatoxymelatonin were positively correlated with clearance of 8-OH-dG (i.e., higher 6-sulfatoxymelatonin levels were associated with higher urinary 8-OH-dG levels) (Bhatti et al. 2016, 2017) An analysis of 50 night shift workers with the highest melatonin suppression (e.g., difference in melatonin level between night work and night sleep) had very reduced levels (20%) of urinary 8-OH-dG after night work compared to night sleep. Decreased sleep quality may also have contributed (see Section 6.4.2). Manzella et al. (2015) reported a 3-fold decrease in 8-oxoguanine DNA glycosylase (OGG1) gene expression in 60 rotating shift workers (with deregulation of clock genes) compared to 54 day shift workers in samples taken in the morning after a day off. OGG1 is the primary gene in the DNA base excision repair pathway responsible for removal of oxidative damage. These authors also conducted in vitro studies with human dermal fibroblasts and reported that OGG1 expression modulation depended on a correctly functioning molecular circadian clock that could be disrupted in shift workers.

Three studies reported some association between shift work and telomere length (Liang et al. 2011, Parks et al. 2011, Samulin Erdem et al. 2017a). A nested case-control study (699 cases, 895 controls) from the Norwegian Nurses cohort reported that persistent night work schedules (e.g., working 4, 5, or 6 consecutive nights for > 5 years) was associated with decreased telomere length independent of case-control status and among breast cancer cases. Combined analysis of night shift work and telomere length found a decreased risk of breast cancer per one unit increase in telomere length among persistent night workers (high frequency and > 5 year duration) compared to dayworkers whereas no significant association was found with telomere length independent of shift work status (Samulin Erdem et al. 2017a). Liang et al. (2011) reported that among > 4,000 participants in the NHS, women with a longer history of rotating night shift work tended to have shorter telomeres; however, the trend between telomere length and duration of rotating shift work was not statistically significant although it appeared to be more pronounced for women younger than 50 years. Sleep duration was positively associated with telomere length among women younger than 50 years (see Section 6.4.2). Parks et al. (2011) reported that long-term work in multiple jobs, shift work, or work at night was associated with shorter relative telomere length in postmenopausal women; however, the effect was attenuated by covariate adjustment. Telomere shortening is generally associated with genomic instability and increased cancer risk.

Regulation of long interspersed element-1 (LINE1) activity is a potential mechanism for genomic instability associated with LAN or shift-work induced melatonin suppression (deHaro et al. 2014, Belancio 2015). LINE1 is an endogenous agent that can induce genomic instability via insertional mutagenesis and DNA double-strand breaks and is upregulated in many human tumors. Mobilization of LINE1 in cultured HeLa cells was inhibited by overexpression of the MT1 receptor (deHaro et al. 2014). This effect was abolished by addition of a melatonin receptor antagonist. This study also reported that in situ perfusion of PC3 human prostate cancer xenografts in nude rats with melatonin-rich human blood (but not melatonin-poor blood) also suppressed endogenous LINE1 mRNA. A receptor-mediated action of melatonin on LINE1 expression was further demonstrated when PC3 xenografts were perfused with human blood supplemented with exogenous melatonin or melatonin antagonist.

### 6.3.2 Epigenetic effects and gene expression

Almost all human cancers are characterized by vast genomic reprogramming and aberrant epigenetic modifications including DNA methylation and histone modifications that affect gene expression, and disrupted regulation of these epigenetic modifications actively contribute to cancer initiation and progression (Korkmaz and Reiter 2008, Korkmaz et al. 2009, Chi et al. 2010, Hardeland 2014, Masri et al. 2015, Salavaty 2015). The circadian clock is regulated at the epigenetic level and aberrant DNA methylation patterns have been detected in all core clock genes in many types of cancer (Joska et al. 2014, Masri et al. 2015). In addition to DNA methylation, chromatin remodeling has an important role in circadian regulation of gene expression (Doi et al. 2006, Masri et al. 2015). Chromatin remodeling involves a number of histone modifying enzymes (e.g., HATs, histone deacetylases, methyltransferases, demethylases and others) and occurs through post-translational modifications of the core histone proteins (Nakahata et al. 2008). The finding that CLOCK has intrinsic HAT activity confirms that chromatin remodeling is linked to circadian physiology (Doi et al. 2006, Masri et al. 2015). The activity of NAD^±^-dependent deacetylases, sirtuin 1 (SIRT1) and sirtuin 6 (SIRT6), is regulated in a circadian manner and SIRT1 activity correlates with the rhythmic CLOCK-induced acetylation of BMAL1 (Nakahata et al. 2008, Masri et al. 2015). The data indicate that CLOCK and SIRT1 are associated during all times of the circadian cycle and contribute to histone acetylation rhythms, regulate acetylation patterns as the promoters of clock-controlled genes, and regulate the deacetylation and degradation of PER2, a clock gene with tumor-suppressor activity (Asher et al. 2008, Nakahata et al. 2008, Zubidat and Haim 2017). SIRT1 appears to act as a tumor suppressor or a tumor promoter, depending on the biological system studied, while SIRT6 acts as a tumor suppressor and is an important regulator of aerobic glycolysis in cancer cells (Masri et al. 2015). These data suggest that chromatin remodeling is crucial for maintaining the core clock transcription/translation machinery and that the carcinogenic effects of circadian disruption may have an epigenetic basis (Doi et al. 2006, Salavaty 2015).

Rodent studies show that circadian transcription is coupled with rhythmic chromatin modifications including histone and non-histone protein acetylation, SIRT1 and SIRT6 deacetylation, and histone methylation (Masri et al. 2015). Mice entrained to a 12-hour light/dark cycle and sacrificed at various times show that transcriptional regulation of the core clock mechanism in mouse liver or vasculature is accompanied by rhythms in histone H3 acetylation and that the rhythmic conversion of transcriptionally permissive chromatin to facultative heterochromatin is dependent on the presence of functional BMAL1-CLOCK binding sites (Etchegaray et al. 2003, Curtis et al. 2004, Ripperger and Schibler 2006).

#### Animal studies of simulated jet lag or LAN

Rodents exposed to jet lag or LAN also showed evidence of epigenetic changes that are associated with cancer growth and development. Female rats exposed to simulated jet lag showed differential expression of 19 miRNAs in mammary tissue (Kochan et al. 2015). All but one of the 19 differentially expressed miRNAs play a role in breast cancer development and most had predicted circadian-relevant targets linked to breast cancer development. Another study reported that mice injected (subcutaneous in the left flank) with murine breast cancer cells and exposed to LAN (450 lux) for 30 minutes each night showed global DNA hypomethylation in tumors, reduced melatonin levels, and increased tumor growth compared to controls (Schwimmer et al. 2014). Treatment with exogenous melatonin reduced hypomethylation and tumor growth.

#### Studies in shift workers

There is some evidence that shift work is associated with epigenetic changes, with most studies reporting significant epigenetic effects. Importantly, the effects of methylation were observed in genes involved in inflammation and carcinogenicity, suggesting that epigenetic mechanisms are a potential link between shift work, circadian disruption, and cancer. However, the database is limited because only a few studies were conducted in independent populations or evaluated the same endpoints. Details of the scope of the database and study findings are reported below and in Table 6-3.

Ten studies conducted in six different study populations examined various epigenetic mechanisms in night shift and day workers. One study was a breast cancer case-control study and the remaining studies were cross-sectional analyses. Study populations were from Denmark (a general population cohort: Zhu et al. 2011, Jacobs et al. 2013, Shi et al. 2013, Liu et al. 2015), Norway (nurses: Samulin Erdem et al. 2017b), Italy (male chemical workers: Bollati et al. 2010), Poland (nurses and midwives: Peplonska et al. 2017, Reszka et al. 2018), and (presumably) from two different populations of health care providers in Seattle, Washington U.S.A. (Bhatti et al. 2015, Adams et al. 2017). The studies also varied in the molecular methods; some studies looked at genome-wide methylation patterns, while others looked at methylation in miRNA, or specific circadian, immune, or other genes.

Four studies, all conducted within the Danish Diet, Cancer and Health prospective cohort, investigated different aspects of epigenetic modifications in the same small subset of long-term shift workers. Long-term shift work was found to be associated (1) with altered epigenetic methylation patterns for CLOCK (decreased) and CRY2 (increased) that were consistent with epigenetic changes in breast cancer patients as well as changes in global methylation (Zhu et al. 2011) and (2) with altered methylation patterns of imprinted genes which may increase cancer risk by inducing expression of normally silent alleles or repressing normally expressed alleles (Jacobs et al. 2013). Shi et al. (2013) and Liu et al. (2015) found that the promoter regions of several miRNAs were differentially methylated in shift workers including hypermethylation of miR-219 and miR-34b. The effect of miR-219 is to dampen cancer cell sensitivity to apoptosis; it affects many of the same immunological pathways as miR-34b. Inhibition of miR-34b reduces downstream p53 signaling and immunomediated tumor suppression, thus increasing cancer risk.

Two other studies specifically evaluated clock genes. Reszka et al. (2018) reported that PER1, PER2, and BMAL1 showed decreased methylation attributable to rotating-shift work among nurses and midwives but no effects were observed for other clock genes. Samulin Erdem et al. (2017b) found that among breast cancer cases, shift work was associated with changes in 5mC methylation levels at various CpG sites of the promoter region in BMAL1 (increased), PER1 (decreased), and CRY1 (increased) but no effects were observed for other clock genes. In analyses of cases matched to controls with similar night shift work exposure, increases in the methylation index were observed for all three of these genes in cases compared to controls suggesting that epigenetic regulation of core clock genes may contribute to breast cancer in shift workers. However, it is unclear whether the patterns are due to night shift work, cancer progression, or a combination of these factors.

Additional findings regarding the effect of shift work on genes involved in immune function were reported by Bhatti et al. (2015). This study of Seattle health care workers looked at genome methylation and found that shift work was related to DNA methylation changes in a wide variety of genes, noting the largest changes were for clock genes and genes involved in immune function. In a presumably different population of health care workers in Seattle, Adams et al. (2017), using different molecular genome methylation techniques and types of analyses, reported non-statistically significant associations in BACH2 (immunosuppression in tumors), JRK (overexpressed in breast, colorectal, and ovarian cancers), and RPS6KA2 (downstream signaler of MAPK and putative tumor suppressor for ovarian cancer), but no association with other genes.

Bollati et al. (2010) found long-term shift work (but not ever-worked shift work) was inversely related to Alu, TNF-α, and IFN-γ methylation (hypomethylation). They also reported significant differences in TNF-α methylation between morning and evening type persons with morningness related to hypomethylation. Finally, Peplonska et al. (2017) limited their analysis to BRCA1 and BRCA2, and found no association between rotating night shift work and promoter methylation.

In summary, three of the four studies that evaluated genome-wide methylation found that methylation patterns significantly differ between night and day shift workers; the one study that did not report a significant association found non-statistically significant associations for two genes involved in carcinogenicity. All three studies that evaluated promoter methylation in specific circadian clock genes reported that methylation patterns differed by shift work status. A study evaluating genome methylation also found evidence of an association between shift work and hypomethylation of genes involved in immune function. However, the type of methylation and the specific genes involved were not consistent across studies. Importantly, one of the studies evaluated clock gene expression in breast cancer cases, whereas the other two studies analyzed cancer-free subjects. Three studies provide evidence that night shift work is related to methylation in immune function-related genes. In general, methylation of other specific genes was only reported in a single study for each gene.

An experimental study reported that four days of simulated night shift work in healthy volunteers resulted in circadian disruption characterized by reduced amplitudes and overall misalignment of rhythmic transcripts with the shifted sleep/wake cycle (Kervezee et al. 2018). Approximately 3% of the transcriptome was either up-regulated or down-regulated in peripheral blood mononuclear cells. Functional analysis revealed that the key biological processes affected included suppression of natural killer (NK) cell-mediated immune response, down-regulation of JUN/AP1 pathway (an important regulator of cell proliferation, differentiation, and apoptosis), and up-regulation of several members of the signal transducer and activator of transcription (STAT) family (STAT1, STAT2, and STAT5A) that is involved in regulating defense mechanisms against viruses and tumors.

Table 6-3 Epigenetic effects of circadian disruption in shift workers

Reference; Location | Population/exposure | DNA methylation | Results | Comments and gene effects
Bollati et al. 2010; Northern Italy | Chemical workers; 100 backward rotating shift workers; 50 dayworkers; Shift work duration (assessed by job seniority); Shift work subpopulations; Chronotype: 35 morning; 25 evening; Tolerance to shift work: 40 good; 35 poor | Global methylation: Alu and LINE-1 elements (repetitive elements); Specific genes: promoter of GCR, TNF-α, and IFN-γ | Night shift work vs. day shift work; - Ever shift work: no effect for global or specific genes; - Increasing shift work duration (trend): ↓ methylation (hypomethylation) of Alu and IFN-γ- and ↑ of GCR; Chronotype (evening and morning); - Significant differences in TNF-α methylation; Good vs. poor tolerance shift work; No differences | Selection of population restricted day and night workers to same production departments with same exposure to chemicals.; Only one blood sample per subject instead of 24-hr pattern which might better assess if methylation changes are due to phase shifts vs. total increase or decrease.; Genes: inflammatory and cancer-relevant pathways
Zhu et al. 2011; Denmark | Diet, Cancer and Health Cohort; Long term shift workers ages 50–64 yr; Analyses; Specific genes: 19 shift workers; 98 day workers; Genome-wide association study (GWAS): 10 age- and folate-intake matched night and day workers | Specific genes; - CLOCK promoter hypomethylation; - CRY2 promoter hypermethylation; Genome wide methylation changes; Pathway analysis of genes with altered methylation patterns | Night shift work vs. dayworkers; Specific genes; - ↓ CLOCK methylation; - ↑ CRY2 methylation; GWAS; - Significant changes across 4,752 genes; - 66.4% hypermethylated; - 33.6% hypomethylated | CLOCK and CRY2 patterns are consistent with epigenetic changes in breast cancer patients.; Pathway analysis; Prominent role for DNA replication, recombination, repair, gene expression, behavior with ESR1
Jacobs et al. 2013; Denmark | Same 10 night and day shift worker pair from Diet, Cancer and Health Cohort | 397 CpG sites in promoter regions of 56 imprinted genes | Night shift work vs. dayworkers; Significant changes in 26 imprinted genes; - ↑ methylation: 5.04% CpG sites; - ↓ methylation: 7.56% CpG sites; - Hypermethylation: DLX5 and IGF2AS Hypomethylation of TP73
Shi et al. 2013; Denmark | Same 10 pairs of subjects as the subset from Zhu et al. 2011, Diet, Cancer and Health Cohort | Promoter regions of specific miRNA precursors, including circadian-relevant miR-219 promoter | Night vs. day workers; miRNA methylation; - 50 CpG loci of 31 miRNAs, including miR-219.; - Hypermethylated: 48 CpG loci of 29 miRNAs; - Hypomethylated: 2 loci of 2 miRNAs; miR-219 over-expressed MCF-7 breast adenocarcinoma cell model; - 319 mRNAs differentially expressed transcripts | Hypermethylation of miR-219 may dampen cancer cell proliferation and sensitivity to apoptosis; miR-219 affects many of the same immunological pathways as miR-34b; Pathway analysis; Immunomediated antitumor activity (antimicrobial response, inflammatory response, infectious disease, cell growth, and apoptosis)
Liu et al. 2015; Denmark | Same 10 pairs of subjects as the subset from Zhu et al. 2011, Diet, Cancer and Health Cohort | miR-34b promoter hypermethylation | Night shift work vs. dayworkers; - ↑ miR-34b promoter methylation at a CpG site; Transfection of the miR-34b mimic in an MCF-7 breast cancer cell line; - Differential expression of 230 mRNA transcripts | Pathway analysis; Interferon-mediated antiviral response and apoptotic and antiproliferative gene networks including inflammatory response, immunological disease, gene expression, cell signaling and cellular development, cell cycle, cell death, and cancer
Bhatti et al. 2015; Seattle, USA | Seattle metro healthcare workers; Cross sectional study; Men and women aged 20–40 yr; 65 day workers and 59 night shift workers | Genome wide methylation patterns | Night shift work vs. dayworkers; - ↓ average methylation in each significant locus, gene, CpG island, or gene region; - Statistically significant differences at 16,135 loci, 3,769 genes, 7,173 CpG islands, and 5,508 gene regions; - Hypomethylated patterns: 21 loci in the core circadian genes; largest differences in PER3 and CSNK1ε | Genes include clock genes and genes involved in immune function and host defense; Limited cumulative years of night shift work and type of rotations
Adams et al. 2017; Seattle, USA | Seattle metro healthcare workers; Cross-sectional study; Types of shift; 86 day workers and 111 night shift workers, premenopausal women 20–49 yr of age; Chronotype; 110 female night shift workers and 131 male night workers | Genome-wide DNA methylation | Night shift work vs. dayworkers; - No statistically significant associations; - Suggestive associations in some genes with links to cancer: BACH2, JRK; Chronotype among night shift workers; No statistically significant associations; Suggestive associations in some genes with links to cancer: RPS6KA2 | Genes:; - BACH2 (immunosuppression in tumors); - JRK (overexpressed in breast, colorectal, and ovarian cancers); - RPS6KA2 (downstream signaler of MAPK pathway and putative tumor suppressor for ovarian cancer); Underpowered to detect low to moderate effects; This study used different molecular methods and statistical analyses than Bhatti et al. 2015 study
Samulin Erdem et al. 2017b; Norway | Norwegian Nurses; Nested case-control study; 278 breast cancer cases; 280 matched controls matched on type of night shift work exposure; Night shift work categories: none, low, medium, high | 5mC methylation levels at CpG sites of the promoter region in five circadian genes CLOCK, BMAL1, CRY1, PER1 and PER2 | Breast cancer cases vs. controls matched for shift category; - ↑ methylation index in CLOCK, BMAL1, CRY1, and PER1 for medium exposure to shift work; - No significant effects for other night work exposure categories; Case-case analysis: Referent day workers; ↓ CRY1: ever, low, and high exposure; ↑ BMAL1 and PER1: medium exposure; Control analyses; No differences | Study limitations include sample collection time, and DNA source (saliva vs. blood); 0/19 polymorphisms in the 5 circadian genes had an effect on the methylation levels of the respective genes; No association between methylation levels of 5 core circadian genes and estrogen and progesterone receptors status of the tumor in cases
Peplonska et al. 2017; Lodz, Poland, | Nurses and midwives; Cross-section study; Fast forward rotating shift workers ages 40–60 yr; 347 night shift workers; 363 day workers | BRCA1 and BRCA2 promoter methylation- methylated vs. unmethylated | OR (95% CI) for methylation status; > 20 yr night work; - BRCA1: 1.04 (0.66–1.64); - BRCA2: 1.02 (0.64–1.64) | Limited to analysis of two genes; Used only one blood sample; Positive association found between methylation status of BRCA1 and current smoking, which is inconsistent with two other similar studies
Reszka et al. 2018; Poland. | Nurses and midwives working; 347 rotating night shift workers and 363 day workers; Current and lifetime rotating shift work; Same population as Peplonska et al. 2017 | CpG promoter methylation in circadian genes PER1, PER2, PER3, CRY1, CRY2, BMAL1, CLOCK, NPAS2 | Night shift work vs. day shift work; ↓ PER2; - Current night shift work; - More frequent vs. less frequent; - Longer vs. shorter lifetime duration (non-significant); ↓ PER1; - Longer vs. shorter lifetime duration; ↓ BMAL1 hypomethylation; - > 10 years shift work | Isolation of genomic DNA from whole blood with various proportions of leukocytes could have an impact on DNA-based epigenetic status, as authors did not analyze the mix of leukocytes, nor control for it

### 6.3.3 Oxidative stress

Levels of pro- and antioxidant markers show circadian rhythms in humans and experimental animals, thus disruption of these daily rhythms could affect sensitivity to oxidative stress and increase oxidative damage (Faraut et al. 2013). Simulated jet lag and LAN exposure studies in mice, as well as studies of shift workers, report evidence of a direct association of diminished melatonin and oxidative stress.

#### Animal studies of simulated jet lag or LAN

Two simulated jet lag studies and three LAN exposure studies reported evidence of oxidative stress in rodents. Kishi and Sunagawa (2011) reported that experimental jet lag in wild type and hypertensive rats increased blood pressure and SNS activity via oxidative stress. Kettner et al. (2016) reported that simulated chronic jet lag induced SNS dysfunction and global gene deregulation in livers of C57BL6J mice including global overexpression of prooxidant stress genes and suppression of antioxidant genes. 8-OH-dG levels were significantly higher in lung tissues but not the liver of nude mice injected with HeLa or PC3 cells and exposed to constant light compared to mice held in a normal 12-hour light/dark cycle (Yasuniwa et al. 2010). Oxidative stress was associated with enhanced expression of WNT10A signaling, hypervascularization in tumors, and increased tumor growth. In the other two studies, LAN exposure induced a clear increase in pulmonary superoxide dismutase (SOD) expression and significantly reduced serum total antioxidant status in rats (Benot et al. 1998, Temneanu et al. 2012). Serum total antioxidant status paralleled the 24-hour melatonin cycle and administration of exogenous melatonin increased the total antioxidant status (Benot et al. 1998).

#### Studies in shift workers

Over 9 studies provide moderate evidence of oxidative stress in shift workers. These include studies that measured 8-OH-dG levels in urine samples (Ishihara et al. 2008, Bhatti et al. 2016, 2017); oxidative stress indices in blood (ratio of total oxidant status to total anti-oxidant status) (Buyukhatipoglu et al. 2010, Ulas et al. 2012), malondialdehyde and SOD levels in red blood cells (Casado et al. 2008, Casado et al. 2011), malondialdehyde and/or glutathione reductase activity in blood serum (Kulikov et al. 2007, Muhammad and Qadir 2017), 8-isoprostane in urine (Nagata et al. 2017); and total plasma antioxidant capacity (Sharifian et al. 2005). Melatonin suppression, as measured by urinary excretion of 6-sulfatoxymelatonin, was directly associated with increased markers of oxidative damage in shift workers (Bhatti et al. 2016, 2017). Melatonin is a known antioxidant (see Section 6.2) that acts as a potent free radical scavenger, antioxidant enzyme promotor (e.g., SOD, glutathione peroxidase, glutathione reductase), and prooxidant enzyme inhibitor (e.g., lipoxygenases and nitric oxide synthase) (Reiter 2001, Reiter et al. 2001, Colín-González et al. 2015). Gromadzinska et al. (2013) reported clear evidence of oxidative stress in premenopausal nurses working night shifts but not for postmenopausal night shift nurses based on red blood cell glutathione peroxidase (GSH-Px) activity compared to day shift nurses. Significantly lower levels of vitamins A and E were found in premenopausal women working night shifts but, overall, no associations were reported between shift work and SOD, thiobarbituric acid reactive substances (TBARs), or plasma selenium levels.

### 6.3.4 Chronic inflammation and immunosuppression

The immune system and the circadian system are interconnected at multiple levels (i.e., neural, humoral, and systemic) (Habbal and Al-Jabri 2009, Cermakian et al. 2014). Many immune cell types (e.g., T and B lymphocytes, monocytes, macrophages, natural killer (NK) cells, neutrophils, eosinophils), cytokines, and other immune and inflammatory biomarkers show circadian rhythms in cell number or expression level (Haus and Smolensky 1999, Faraut et al. 2013, Scheiermann et al. 2013, Cermakian et al. 2014, Geiger et al. 2015). Thus, it is not surprising that studies of experimental animals exposed to simulated jet lag or LAN and studies of shift workers have reported evidence of altered immune and inflammatory responses. These studies are reviewed below. Other factors that may affect immune and inflammatory responses include sunlight exposure and vitamin D, sleep deprivation, and meal timing and are discussed in Section 6.4.

#### Animal studies of simulated jet lag or LAN

Rodents subjected to various chronic jet lag protocols showed evidence of circadian disruption and altered immune and inflammatory responses in 5 studies (Castanon-Cervantes et al. 2010, Wu et al. 2010, Logan et al. 2012, Guerrero-Vargas et al. 2015, Kettner et al. 2016). Logan et al. (2012) reported that suppressed circadian expression of NK cell cytolytic activity was associated with increased growth of tumors following i.v. injection of MADB106 mammary adenocarcinoma cells in phase-shifted rats. Two studies reported an increased release of pro-inflammatory cytokines following lipopolysaccharide (LPS) challenge (Castanon-Cervantes et al. 2010, Guerrero-Vargas et al. 2015). Furthermore, the altered innate immune response was not due to sleep loss or stress in phase-shifted mice; however, the effects of simulated shift work on the inflammatory response was prevented when food was not available during the working schedule suggesting that mistimed food consumption contributes to the inflammatory response (Guerrero-Vargas et al. 2015). Kettner et al. (2016) reported that chronic jet lag induced deregulation of both innate and adaptive inflammatory responses in C57BL6J mice and dramatically accelerated pathophysiological progression in the liver. Another study found that simulated jet lag changed the rhythmic profiles of peripheral lymphocytes and T helper cells in the spleen and increased plasma IL-6 levels in mice (Wu et al. 2010).

Three studies in Siberian hamsters reported that continuous dim LAN (5 lux) or a light pulse at night impaired cell-mediated immunity, as evidenced by suppressed delayed type hypersensitivity following dermal application of 2,4-dinitro-1-fluorobenzene (Bedrosian et al. 2011, Prendergast et al. 2013, Aubrecht et al. 2014). Bedrosian et al. (2011) also reported a reduced bactericidal activity in blood after LPS treatment and Prendergast et al. (2013) reported that a functional central clock was required to generate circadian rhythms in leukocyte trafficking and for driving peripheral clocks in secondary lymphoid organs. Although pinealectomy did not affect circadian rhythms in leukocyte trafficking, melatonin was necessary to convey circadian time information to the spleen clock genes. These studies demonstrate that a functional circadian system is critical for maintaining optimal immunosurveillance and T-cell-dependent immune responses.

#### Studies in shift workers

Human studies are generally consistent with the studies in rodents, which also show evidence that circadian disruption can affect the immune system and inflammatory response. Six studies reported that night shift, or rotating shift work, is associated with altered cytokine (e.g., Il-2, IL-6, TNF-α, IFN-γ) rhythms or levels and inflammatory responses in the blood compared to day shift workers (Zheng et al. 2006, Burgueño et al. 2010, Khosro et al. 2011, Puttonen et al. 2011, Cuesta et al. 2016, Muhammad and Qadir 2017). In contrast, three studies did not report evidence of altered cytokine levels in shift workers (Copertaro et al. 2010, van Mark et al. 2010, Copertaro et al. 2011). Four studies also reported evidence that shift work increased C-reactive protein levels (a marker of inflammation that is associated with increased risk of cancer, cardiovascular disease, and other inflammation-related disorders) (Zheng et al. 2006, Khosro et al. 2011, Puttonen et al. 2011, Kim et al. 2016).

Two studies reported evidence of lower NK cell activity in nurses or emergency room physicians performing shift work (Okamoto et al. 2008, Nagai et al. 2011). The effects on NK cell activity in both these studies were related to the degree of fatigue. NK cells are part of the innate immune system and low NK activity has been associated with increased tumor growth in humans and laboratory animals (Logan et al. 2012). However, two studies of nurses did not report evidence of suppressed NK cell function in shift workers compared to day workers at baseline or after one year of follow-up (Copertaro et al. 2010, Copertaro et al. 2011). Some epigenetic studies reported an association between night shift work and altered methylation of genes involved in immune function (see Section 6.3.2)

Nine studies reported that shift workers had elevated counts of various immune cells (e.g., white blood cells, lymphocytes, leukocytes, neutrophils, monocytes) (Nakano et al. 1982, Nishitani and Sakakibara 2007, Sookoian et al. 2007, Khosro et al. 2011, Nagai et al. 2011, Puttonen et al. 2011, Kim et al. 2016, Lu et al. 2016, Wirth et al. 2017). In contrast, a recent study that included almost 8,500 participants, including 1,779 shift workers, in the National Health and Nutrition Examination Survey (2005 to 2010) found no association between self-reported current shift work and leukocyte counts (Buss et al. 2018).

Overall, the data show that shift work may contribute to inflammation and an altered immune response; however, as evidenced by some negative studies, these exposures may not always trigger an immune or inflammatory response. The circadian phase alterations in immune cell and cytokine levels are potential confounding factors in most of these studies because the day workers and shift workers often have different circadian patterns when measured at the same time point and must be interpreted with caution (Faraut et al. 2013).

### 6.3.5 Metabolic alterations

Experimental animal studies provide evidence that LAN induces metabolic disturbances via circadian disruption and promotes the formation and growth of spontaneous tumors, xenografts, or chemically induced tumors (Blask et al. 2005, Vinogradova et al. 2009, Blask et al. 2014, Dauchy et al. 2014, Guerrero-Vargas et al. 2017). The underlying mechanisms associated with enhanced tumor growth in experimental studies include LAN-induced melatonin suppression and circadian disruption leading to hyperglycemia, hyperinsulinemia, runaway aerobic glycolysis (Warburg effect), altered lipid signaling, and increased proliferative activity (Blask et al. 2005, Dauchy et al. 2009a, Blask et al. 2014, Dauchy et al. 2014, Mao et al. 2016a, Guerrero-Vargas et al. 2017). Impaired glucose and lipid metabolism, metabolic syndrome, weight gain, altered food intake and activity rhythms, disrupted liver transcriptome rhythms, and altered rhythms of metabolically active hormones have been reported in rodents exposed to continuous light, non-24-hour light schedules, dim LAN, and simulated shift work or jet lag (Vinogradova et al. 2009, Arble et al. 2010, Fonken et al. 2013a, Fonken et al. 2013b, Fonken and Nelson 2014). In addition, studies of rats exposed to blue-enriched light during the daytime reported that tumor cAMP levels, linoleic acid uptake and metabolism, growth signaling pathways, and aerobic glycolysis (Warburg effect) were markedly downregulated compared to rats exposed to broad-spectrum cool white fluorescent lighting during the day, thus suggesting that exposure to daytime blue light also affects tumor metabolic signaling and proliferative activities (Dauchy et al. 2015, Dauchy et al. 2018). Kettner et al. (2016) also reported that chronic jet lag is an independent risk factor for spontaneous hepatocellular carcinoma in wild-type C57BL6J mice. The reported mechanism involved jet lag-induced global dysregulation of liver metabolic function leading to non-alcoholic fatty liver disease and promotion of the Warburg effect. Together with chronic jet lag-induced oncogenic activation, immune suppression, and loss of control in DNA surveillance and cell proliferation, the persistent liver metabolic circadian dysfunction provides one of the key pathophysiological mechanisms that drives progression from non-alcoholic fatty liver disease to steatohepatitis, fibrosis, and eventually hepatocellular carcinoma. The importance of the circadian system in maintaining metabolic homeostasis is further supported by clock gene mutant mouse models (Rudic et al. 2004, Turek et al. 2005, Fonken and Nelson 2014, Kettner et al. 2015, Kettner et al. 2016). These studies show that clock gene mutants are susceptible to obesity, metabolic syndrome, impaired glucose tolerance and regulation, diabetic-like phenotype, defective insulin production, altered endocrine signaling, and an altered feeding rhythm (Fonken and Nelson 2014).

Obesity, metabolic syndrome, and other metabolic disorders such as type 2 diabetes are recognized risk factors for some cancers and are often associated with long-term shift work and circadian disruption in humans (De Bacquer et al. 2009, Pan et al. 2011, Wang et al. 2011, Guo et al. 2013, Ika et al. 2013, Renehan et al. 2015, Arnold et al. 2016, Zubidat and Haim 2017). Guo et al. (2013) reported evidence that shift work was an independent risk factor for diabetes and that the risk significantly increased with a duration of shift work of at least 10 years. Thus, the evidence suggests that circadian disruption in humans may contribute to cancer by altering metabolism and increasing risk of metabolic disease and obesity.

### 6.3.6 Sex hormone rhythms and signaling pathways

LAN-induced melatonin suppression and circadian disruption also affects sex hormone rhythms by influencing the hypothalamic-pituitary-gonadal axis (Mirick and Davis 2008). Evidence from animal and clinical studies show that melatonin inhibits the release of gonadotropins (luteinizing hormone [LH] and follicle-stimulating hormone [FSH]), testosterone, and estrogen. Studies in nocturnal rodents or rodent cells also show that melatonin inhibits prolactin secretion (Dubocovich et al. 2003, Dubocovich and Markowska 2005, Ogura-Ochi et al. 2017); however, in humans the melatonin and prolactin rhythms are in phase (Goel et al. 2009). A study using cultured primary pituitary cells from female baboons reported that melatonin increased prolactin release in a dose- and time-dependent fashion (Ibáñez-Costa et al. 2015).

#### Animal studies of exposure to LAN

Various LAN protocols induced or promoted tumor growth in rodents (see Section 5). Several of these studies reported that constant dim light or LAN also affects hormone levels and rhythms. Rats exposed to constant dim light or LAN had lower nocturnal excretion of 6-sulfatoxymelatonin and higher levels of serum estradiol compared to animals maintained on a 12:12 light-dark cycle (Cos et al. 2006). As mentioned in Section 6.1.2, the increased sensitivity to DMBA-induced mammary tumors in female mice exposed to LAN from birth was attributed in part to increased circulating levels of prolactin (Mhatre et al. 1984, Shah et al. 1984). Other studies show that rodents exposed to LAN had significantly accelerated age-related disturbances in estrous function and rhythm (Anisimov et al. 2004, Prata Lima et al. 2004, Vinogradova and Chernova 2006, Popovich et al. 2013). These disturbances in estrous function were followed by hyperplastic processes in the mammary gland, ovaries, and uterus and support the hypothesis that circadian and endocrine disruption induced by LAN is involved in development and growth of hormone-responsive tumors.

#### Studies in shift workers

Epidemiological studies of LAN and shift work (Section 3) indicate the strongest statistically significant associations of night work with hormone receptor-positive (ER+, PR+, and/or HER+) breast cancer (Grundy et al. 2013b, Lie et al. 2013, Papantoniou et al. 2015a, Wang et al. 2015a, Cordina-Duverger et al. 2016, Vistisen et al. 2017, Wegrzyn et al. 2017). LAN and/or shift work exposure studies in humans and experimental animals (discussed below) also show effects on sex hormones (i.e., estrogens, progesterone, prolactin, testosterone), some of which are known risk factors for breast and prostate cancer and are summarized in Table 6-4a,b,c,d. Some of these effects could be mediated by melatonin-induced changes in hormone levels (see Section 6.2).

Overall, the available studies provide consistent evidence that night shift work is associated with elevated estrogen levels. Six published studies of independent populations reported higher levels of various estrogen metabolites in night shift workers compared to day workers (Schernhammer et al. 2004, for postmenopausal women in NHS, Nagata et al. 2008, Bracci et al. 2013, Bracci et al. 2014, Gómez-Acebo et al. 2015, Papantoniou et al. 2015c, Peplonska et al. 2016) although findings were not statistically significant in the Spanish study of permanent workers (Papantoniou et al. 2015a). Positive findings were found in both reports of the study of workers from Northern Italy (Bracci et al. 2013, Bracci et al. 2014; however, it is not clear if these populations overlap.) Although a study of Seattle health care workers found similar estrone conjugates in night shift workers as in day workers, in an analysis within night shift workers, estrone conjugates were higher after night work or day time sleep compared to night sleep on a day off (Davis et al. 2012) (see Table 6-4a). No clear patterns were observed between estrogens and the number of night shifts worked in the two weeks before sample collection among premenopausal women in the NH2 study; however, only 14 women worked greater than 1 night (Schernhammer et al. 2004). Three studies suggested a relationship between estradiol levels and persistent night shift work. The highest estradiol levels were reported among women working night shifts for the longest number of years (Schernhammer et al. 2004 [estradiol in all fractions in postmenopausal women], Langley et al. 2012 and Peplonska et al. 2012) although findings were no longer significant in the study by Langley et al. (2012) in the adjusted analysis (P = 0.11). Comparability of these studies, however, is limited by differences across studies in shift schedules, control of confounders, sample size, specific estrogen metabolite measured, and sampling protocols, including timing of sampling after shifts and during the menstrual cycle.

There is little evidence that estrogens levels are related to urinary melatonin levels. The NHS II study found a significant inverse association of urinary melatonin levels with estradiol among a sample of 80 premenopausal women using the average of 3 urinary measurements (Schernhammer et al. 2004); however, the evidence was weaker in a later study of a larger sample of premenopausal women (including the 80 from the 2004 study) based on 1 urinary measurement performed on the follicular phase sample (P = 0.07) (Schernhammer et al. 2006a). No association was found between melatonin levels in studies from Italy, Spain, Canada, and Japan (See Table 6-4a).

Table 6-4a Studies of estrogens in night shift workers

Reference; Location | Population/exposure | Hormone, methods, and timing | Results
Bracci et al. 2013; Northern Italy | National Health Service: nurses with ≥ 2 yr shift work; Premenopausal women; 31 rotating NSW; 31 DSW | Serum 17β-estradiol from fasting blood; End of night or beginning of morning shift | ⬆17β-estradiol levels; - NSW vs. DSW (ns); - NSW without nap vs. NSW with nap; - NSW without nap vs. DSW; Similar 17β-estradiol levels; - NSW with nap vs. DSW; No significant association of 17β-estradiol levels with clock gene expression or aMT6s
Bracci et al. 2014; Northern Italy | National Health Service; nurses with ≥ 2 yr of shift work; 60 rotating NSW; 56 DSW | Serum 17β-estradiol from fasting blood; Start of morning shift after a regular night’s sleep on a day off | ⬆17β-estradiol levels; - NSW vs. DSW; - Morning chronotype; Correlations; - Chronotype score: positive (P = 0.011); - Clock gene expression: negative; Urinary aMT6s: null
Davis et al. 2012; Seattle, WA | Seattle female health care workers, ages 20–49; ≥ 20 hr/week at night or days; 172 NSW; 151 DSW | Urinary estrone conjugates (E1C); NSW: Nighttime sleep on day off, daytime sleep after 1 shift, and night work after ≥ 2 consecutive night shifts, DSW: Night time sleep after ≥ 1-day shift | ⬆ E1C within NSW; - Night work vs. night sleep; - Day sleep vs. night sleep; Similar level: NSW vs. DSW; - Night sleep, night work, or day sleep (NSW)
Gómez-Acebo et al. 2015; Spain | Female health care workers or teachers ages 20–65 yr; 63 rotating NSW; 73 DSW | Serum estradiol; Start of morning day shift or end of night shift; Urinary aMT6s over 24 hours | ⬆ Estradiol levels; - NSW vs. DSW, both pre- and post-menopausal combined; pre-menopausal in adjusted analyses for menstrual cycle phase, and for women in follicular phase; No association of plasma sex hormones with urinary aMT6s (data not shown)
Langley et al. 2012; Canada | 82 premenopausal nurses; rotating NSW (DD, NN, 5 days off ) | Serum estradiol and estrone, and urinary aMT6s; Start of a day shift in summer and in winter | ⬆ Estrone levels; - Greater than 20 years NSW: but non-significant after adjustment (P = 0.11); Estradiol levels; - No significant association with NSW in adjusted analysis; Significant association between urinary aMT6s and estradiol in the winter but no longer significant in adjusted analysis
Nagata et al. 2008; Japan | 206 postmenopausal women in general breast cancer screening population; Ever or never worked grave yard shift assessed by questionnaire 3 years; 7 NSW; 170 DSW | Serum estradiol and estrone; Urinary aMT6s; Blood sampled at 2:00 PM on day of interview; first-void urine collected next day | ⬆ Estrone; - Ever NSW vs. DSW (P = 0.006); - Years working NSW (P = 0.03); - Worked NSW within past 3 years; ⬆ Estradiol; - Ever NW vs. DSW (P = 0.11); - Worked NSW within past 3 years; No correlation of estrogen levels with urinary aMT6s levels (only 7 NSW)
Papantoniou et al. 2015c; Spain | Male and female workers from hospitals (56, mainly women), car and train companies (61, mainly men), ages 22–64 yr; 75 permanent NSW; 42 DSW | Urinary estradiol, estrone, and estriol; Sampled from all voids in 24-hr working day or night; Cosinor analysis used to evaluate hormone rhythms | NSW vs. DSW (ns); - ⬆ Total estrogens: premenopausal; - ⬆ Estrone: full population; - ⬆ Estradiol: full population; No correlation of estrogen with urinary aMT6s levels
Peplonska et al. 2016; Poland | Polish nurses and midwives, 40–60 years of age; Pre- and post-menopausal; 263 fast rotating NSW; 269 DSW | Plasma estradiol (E2); Start of morning shift or at end of night shift | ⬆ Estradiol (E2) postmenopausal women; NSW duration:; - 15–25 yr or > 25 yr vs. ≤ 5 NSW ⬆ with increasing years of night work in postmenopausal women (P_trend_ = 0.051); ⬆ Estradiol in morning chronotype: NSW vs. DSW; - Ever NSW (P < 0.05); - Higher frequency NSW (P_trend_ = 0.082); - Longer duration NSW (P_trend_ < 0.001)
Schernhammer et al. 2004, Schernhammer et al. 2006a; U.S.A. | Nurses’ Health Study (NHS) and Nurses’ Health Study II (NHS II); 2004: 663 postmenopausal nurses from NHS and 80 NHS II primarily pre-menopausal nurses (ages from NHS II; 18% reported night work in the two weeks prior to urine collection; 2006: 459 rotating NSW from NHS II, primarily pre-menopausal nurses (ages 33–50), includes 80 nurses from 2004 study | Estrogens; 2004: Plasma estradiol as three fractions (total, free, bioavailable) and estrone, and estrone sulfate; 2006: Plasma estradiol, estrone sulfate, and estrone collected in follicular and luteal phase; Urinary aMT6s (premenopausal women); 2004: Luteal phase first spot morning urine; 3 samples); 2006: Luteal or follicular phase; 1 sample | 663 postmenopausal women (2004); - ⬆ Estradiol (total, free, and bioavailable); - Longer NW durations (≥ 15 yr) vs. never night work; - Significant trend with increasing duration all 3 estradiol fractions; No association with estrone or estrone sulfate; 80 premenopausal women (2004) and number of nights worked in last 2 weeks; - No clear or significant trends with estradiol, estrone, or estrone sulfate levels; analyses limited by small numbers of nurses who worked > 1 night.; - Significant inverse association of urinary melatonin levels with bioavailable estradiol but not other fractions, estrone, or estrone sulfate; attenuated with adjustment for age and BMI; 459 premenopausal women (2006); - Estradiol inversely related to urinary aMT6s for follicular phase (P = 0.07); - No clear association of urinary aMT6s with estrone or estrone sulfate

aMT6s = 6-sulfatoxymelatonin; D = day; DSW = day worker; E1C = estrone conjugate; N = night; ns = not significant; NSW = night worker.

There is some evidence that progestogens are associated with night shift work. Two studies reported higher progesterone levels or total progestogens in night in shift workers compared to day workers (Gómez-Acebo et al. 2015, Papantoniou et al. 2015c). However, no clear association was found between night shift work and progestogen levels for pre-menopausal or post-menopausal women in the Nurse Health Studies (Schernhammer et al. 2004) (see Table 6-4b). In an analysis restricted to rotating night shift workers, Langley et al. (2012) found higher progesterone levels among women with long-term night shift work; however, the findings were no longer significant in adjusted analysis.

The NHS II study found a significant positive association of urinary melatonin levels with progesterone among premenopausal women in the 2004 publication (Schernhammer et al) but not in the 2006 publication. None of the three remaining studies found a correlation with urinary melatonin levels.

Table 6-4b Studies of progestogens in night shift workers

Reference; Location | Population/exposure | Hormone, methods, and timing | Results
Gómez-Acebo et al. 2015; Spain | Female health care workers or teachers ages 20–65 yr; 63 rotating NSW; 73 DSW | Serum progesterone; Start of a day shift in summer and in winter; Urinary aMT6s over 24 hours | ⬆ Progesterone; - NSW vs. DSW in adjusted analysis; estimate attenuated somewhat (P = 0.059) when other hormones were added to the model.; - No association of plasma sex hormones with 24-hr urinary aMT6s (data not shown)
Langley et al. 2012; Canada | 82 premenopausal nurses; rotating NSW (DD, NN, 5 days off) | Serum progesterone; Start of a day shift in summer and in winter | ⬆ progesterone; - ≥ 20 yr NSW in unadjusted analysis but no association as observed in adjusted analysis (P = 0.79); No correlation with urinary aMT6s levels
Papantoniou et al. 2015c; Spain | Male and female workers from hospitals (56, mainly women), car and train companies (61, mainly men), ages 22–64 yr; 75 permanent NSW; 42 DSW | Urinary progestogens (pregnanediol, pregnanetriol, and 16-androstenol); Sampled from all voids in 24-hr working day or night; Cosinor analysis used to evaluate hormone rhythms | NSW vs. DSW (significant findings in adjusted analysis); - ⬆ Total progestogens: Overall and pre-menopausal; - ⬆ Pregnanediol: Overall and pre-menopausal; - ⬆ 16-androstenol: Pre-menopausal; - ⬆ Pregnanetriol: Overall; No correlation of progestogens with urinary aMT6s levels
Schernhammer et al. 2004, Schernhammer et al. 2006a; U.S.A. | Nurses’ Health Study (NHS) and Nurses’ Health Study II (NHS II); 2004: 663 postmenopausal nurses from NHS and 80 NHS II primarily pre-menopausal nurses (ages from NHS II; 18% reported night work in the two weeks prior to urine collection; 2006: 459 rotating NSW from NHS II, primarily pre-menopausal nurses (ages 33–50), includes 80 nurses from 2004 study | Plasma progesterone; follicular and luteal phase (2006); Urinary aMT6s (premenopausal women); 2004: Luteal phase first spot morning urine; 3 samples); 2006: Luteal or follicular phase; 1 sample | 663 postmenopausal women (2004); - No association with NSW duration; 80 premenopausal women (2004); - ⬆ progesterone level in NSW > 1 night in the last 2 weeks higher than those working 0 nights but no clear trend with # of nights worked (P = 0.14); - Significant positive correlation between urinary aMT6s and progesterone, attenuated with adjustment for age and current BMI; 459 premenopausal women (2006); - No clear correlation between progesterone measured in the luteal samples

aMT6s = 6-sulfatoxymelatonin; DSW = day shift worker; ns = not significant; NSW = night shift worker.

Overall, there is no evidence of an association with prolactin levels and night shift work. Three studies comparing prolactin levels in night shift workers and day workers reported no relationship between night work and prolactin levels (Schernhammer et al. 2004, Korompeli et al. 2009, Bukowska et al. 2015). Two studies of only night shift workers reported either no difference in prolactin levels after a normal night sleep compared to levels taken after sleep preceded by a night shift (Aktan et al. 1997), nor differences by duration of night work (Langley et al. 2012) (see Table 6-4c). In addition, a few small field or experimental studies measuring prolactin levels in night shift workers only, or in night and day shift workers at multiple time points found (1) decreased prolactin levels during or after night work compared to levels measured during day shifts in the same workers (Aulitzky et al. 1984, Touitou et al. 1990, Costa et al. 1997), or (2) increased (Weibel and Brandenberger 1998) or decreased (Touitou et al. 1990) prolactin levels in night shift workers compared to controls or day shift workers. One study found that prolactin patterns were similar in day sleep after night work as day workers subjected to an abrupt sleep delay (Spiegel et al. 1996).

Table 6-4c Studies of prolactin in night shift workers

Reference; Location | Population/exposure | Hormone, methods, and timing | Results
Aktan et al. 1997; Turkey | 20 pre-menopausal NSW nurses | Serum prolactin in follicular phase; Two samples: morning after a typical night’s sleep and after a typical night shift | Night sleep vs. night work; No difference in prolactin levels
Bukowska et al. 2015; Poland | Polish nurses and midwives, 40–60 years of age; Pre- and post-menopausal; 327 NSW; 330 DSW | Serum prolactin; Morning: start of morning shift or at end of night shift | NSW vs. DSW; ⬆ Prolactin (crude) in both pre- (P = 0.001) and post-menopausal (P = 0.02); attenuated in adjusted analysis and not significant; No association between prolactin and NSW duration, frequency, total number of nights worked or current night work status
Korompeli et al. 2009; Greece | 32 intensive care nurses; 25 NSW; 7 DSW | Plasma prolactin; Sampled at start and end of each type of shift (morning, evening, and night shifts for NSW and morning shift for DSW) | NSW vs. DSW; No significant difference in samples from morning shift; analysis for night shift of NSW vs. DSW not reported
Langley et al. 2012; Canada | 82 premenopausal nurses; rotating NSW (DD, NN, 5 days off) | Serum prolactin; Start of a day shift in summer and in winter | No association of prolactin with NSW duration (continuous or working long durations); No relationship of prolactin with urinary aMT6s levels
Schernhammer et al. 2004; U.S.A. | Nurses’ Health Study (NHS) and; 663 postmenopausal nurses from NHS; (Prolactin only measured in NHS postmenopausal women) | Serum prolactin | NSW vs. DSW; No association of prolactin by # years worked

aMT6s = 6-sulfatoxymelatonin; DD = 2 day shifts; DSW = day shift worker; D = day shift; NN = 2 night shifts; ns = not significant; NSW = night shift worker; N = night shift.

Findings for studies of androgens and night shift work are unclear. Five independent studies compared levels of androgens in shift workers and day workers, with study populations varying by gender, occupational status, androgen metabolites, and biological tissue (Schernhammer et al. 2004, Nagata et al. 2008, Gómez-Acebo et al. 2015, Papantoniou et al. 2015c, Peplonska et al. 2016); only one of the studies included men (Papantoniou et al. 2015c) (see Table 6-4d). The Spanish study (Papantoniou et al. 2015c) found evidence of an association of shift work and an increase in several androgens in men (although not statistically significant), pre-menopausal women, and the total population. However, Gómez-Acebo et al. (2015) found lower serum levels of testosterone in pre-menopausal women whose samples were drawn during their luteal phase. In general, no association or only non-significant associations were found in the other 3 studies.

No association was found between urinary melatonin levels and androgens in most studies reporting this association (Schernhammer et al. 2004, Gómez-Acebo et al. 2015, Papantoniou et al. 2015c). Schernhammer et al. (2006a) reported modest positive correlations of dehydroepiandrosterone (DHEA) and dehydroepiandrosterone sulfate (DHEAS) with urinary melatonin levels among pre-menopausal women in unadjusted, but not adjusted analyses.

Table 6-4d Studies of androgens in night shift workers

Reference; Location | Population/exposure | Hormone, methods, and timing | Results
Gómez-Acebo et al. 2015; Spain | Female health care workers or teachers ages 20–65 yr; 63 rotating NSW; 73 DSW | Serum testosterone, DHEA, DHEAS; Start of a day shift in summer and in winter; Urinary aMT6s over 24 hr | NSW vs. DSW; - ⬇ Testosterone: Pre- and post-menopausal women, and pre-menopausal women adjusted for menstrual cycle phase in all models; pre-menopausal women in the luteal phase when hormones were not added to the model; - ⬆ DHEA: pre-menopausal women in the follicular phase, no longer significant in models including other hormones; post-menopausal women in models including other hormones (ns, P =0.067); No association of plasma sex hormones with 24-hr urinary aMT6s (data not shown)
Nagata et al. 2008; Japan | 206 postmenopausal women in general breast cancer screening population; Ever or never worked grave yard shift assessed by questionnaire 3 yr; 7 NSW; 170 DSW | Serum testosterone, DHEA; Blood sampled at 2:00 PM on day of interview; Urinary aMT6s; First-void urine collected next day after interview | NSW vs. DSW; - No association: Testosterone and DHEA:; Testosterone and DHEAS levels not significantly correlated with urinary aMT6s; Not informative study due to small numbers of NSW
Papantoniou et al. 2015c; Spain | Male and female workers from hospitals (56, mainly women), car and train companies (61, mainly men), ages 22–64 yr; 75 permanent NSW; 42 DSW | Urinary androgens: testosterone, epitestosterone, DHEA, androsterone, etiocholanolone, 11β-OH-androsterone, androstenedione, 6α-OH-androstenedione, 3α,5α-androstanediol, and 3α,5β-androstanediol; 24-hr urine sample; Cosinor analysis used to evaluate rhythm of aMT6s and androgens | NSW vs. DSW; - ⬆ Total population (significant or borderline significant): Total androgens, all androgens and their metabolites except epitestosterone, etiocholanolone, and 3α,5β-androstanediol; - ⬆ Males (ns): Most androgens and metabolites; - ⬆ Premenopausal women (significant): Testosterone and 3α,5α-androstanediol; - Later peak time of all androgen metabolites; No correlation between androgens and urinary aMT6s
Peplonska et al. 2016; Poland | Polish nurses and midwives, 40–60 yr of age; Pre- and post-menopausal; 263 fast rotating NSW; 269 DSW | Plasma testosterone, DHEAS; Start of morning shift or at end of night shift | NSW vs. DSW; - Testosterone: no association with ever, frequency or duration of NSW in pre- or postmenopausal women; - DHEAS: ⬆ (borderline) levels in postmenopausal women with longer duration of night work, (P = 0.082).; No heterogeneity of effect by chronotype.
Schernhammer et al. 2004, Schernhammer et al. 2006a; U.S.A. | Nurses’ Health Study (NHS) and Nurses’ Health Study II (NHS II); 2004: 663 postmenopausal nurses from NHS and 80 NHS II primarily pre-menopausal nurses (ages from NHS II; 18% reported night work in the two weeks prior to urine collection; 2006: 459 rotating NSW from NHS II, primarily pre-menopausal nurses (ages 33–50), includes 80 nurses from 2004 study | Plasma testosterone and androstenedione, DHEA; Urinary aMT6s (premenopausal women); 2004: Luteal phase first spot morning urine; 3 samples); 2006: Luteal or follicular phase; 1 sample | 663 postmenopausal women (2004); - No clear patterns with NSW history; 80 premenopausal women (2004); ⬆ DHEA (P = 0.09) with ⬆ nights worked in 2 wk prior to sampled collection; 2004 & 2006: No correlation with urinary aMT6s except for DHEA and DHEAS unadjusted analysis, but not in multivariate analysis (2006).

aMT6s = 6-sulfatoxymelatonin; DHEA = dehydroepiandrosterone; DHEAS = dehydroepiandrosterone sulfate; DSW = day shift worker; ns = not significant; NSW = night shift worker.

## 6.4 Other exposures associated with shift work or LAN

Circadian disruption is a complex process involving interactions of multiple factors. In addition to LAN-induced melatonin suppression and desynchronization of central and peripheral clock and clock-controlled gene expression, other exposures commonly associated with shift work may contribute to circadian disruption including: vitamin D deficiency related to reduced sunlight, sleep deprivation, and meal timing (Costa et al. 2010, Asher and Sassone-Corsi 2015, Smolensky et al. 2015, Figueiro 2017, Zubidat and Haim 2017). Interactions with various lifestyle factors (e.g., physical activity, alcohol, drugs, chronic disease, exposure to environmental chemicals and pollutants, etc.) may also be important. However, current data cannot disentangle the relative roles of LAN, melatonin suppression, clock gene disruption, sleep disruption, and other factors in shift-work carcinogenicity (Stevens et al. 2014).

### 6.4.1 Sunlight and vitamin D

Modern electric lighting practices not only increase exposure to LAN but also possibly contribute to decreased exposure to sunlight, resulting in weaker circadian entrainment and vitamin D deficiency (Smolensky et al. 2015). Vitamin D includes a group of fat-soluble compounds that are produced in two forms (D_2_ and D_3_). Vitamin D_2_ comes from plant sources; however, up to 90% of vitamin D comes from endogenous production of D_3_ from skin exposure to UV-B radiation in sunlight (Atoum and Alzoughool 2017). Vitamin D and melatonin are intimately linked to the circadian system and regulate, in a complimentary fashion, many of the same biological processes in cells, tissues, and organ systems. Although there is no evidence to date that suggests that vitamin D affects core clock gene expression, vitamin D directly or indirectly regulates more than 2,000 genes in many pathways that are associated with malignancy including metabolism, DNA repair, antioxidant activity, anti-inflammatory activity, angiogenesis, immune function, cell proliferation, cell differentiation, and apoptosis (Holick 2016).

Overall, the available evidence that vitamin D deficiency plays a role in shift work carcinogenicity is inconclusive. Two studies did not find that night shift work was associated with a decreased level of sunlight exposures (Hansen and Lassen 2012, Gómez-Acebo et al. 2015), which would argue against the vitamin D hypothesis. Studies that have examined the effects of shift work on vitamin D status have reported mixed results (Maeda et al. 2007, Itoh et al. 2011, Alefishat and Abu Farha 2016). A recent systematic review of vitamin D and various occupations (Sowah et al. 2017) found that shift workers (may include evening and night shift workers together) had the lowest average levels of serum 25-hydroxyvitamin D (33.8 ± 10.1 nmol/L) among all occupations, with ~80% having serum vitamin D levels ≤ 50 nmol/L, indicating vitamin D deficiency.

Although vitamin D deficiency has been associated with increased risk of various cancers, including breast cancer in some studies (Chen et al. 2010, Gandini et al. 2011, Touvier et al. 2011, Holick 2016, Reichrath et al. 2016, Atoum and Alzoughool 2017, O’Brien et al. 2017), a recent report by the World Cancer Research Fund (WCRF 2018) concluded that the evidence linking vitamin D and breast cancer risk was limited and that a firm conclusion could not be made. Vitamin D exerts its effects via the vitamin D receptor (VDR). Some VDR polymorphisms in humans have been associated with increased breast cancer risk while VDR knockout mice have higher rates of preneoplastic mammary lesions (reviewed by Atoum and Alzoughool 2017). However, in addition to vitamin D deficiency, poor sunlight exposure could contribute to other pathways (i.e., insulin resistance, estrogen deficiency, thyroxin deficiency, immune system modulation, degradation of folic acid, and circadian disruption) that increase cancer risk (Suba 2012).

### 6.4.2 Sleep

Night shift work misaligns the sleep/wake cycle with the daily and seasonal light-dark cycle. A common consequence of this misalignment is sleep deprivation derived from both sleep loss and poor sleep quality (Ackermann et al. 2013, Korsiak et al. 2017). The sleep-wake cycle is strongly and bidirectionally associated with the circadian system such that changes in one affects the other. Moreover, sleep is critical for maintaining optimal immune, cellular, metabolic, and endocrine functioning. Dysfunction in each of these physiological systems has been linked to carcinogenesis (Samuelsson et al. 2018). Overall, the database is inadequate to evaluate the contribution of sleep disturbances in shift work-mediated carcinogenicity as few studies have evaluated the interaction between shift work and sleep and cancer risk.

Studies that have examined the effects of shift work on sleep have reported that shift workers more frequently experience disturbed sleep, poor sleep quality, excessive sleepiness, and a significantly higher prevalence of short sleep duration (< 7 hours per day) compared with day workers (Drake et al. 2004, Luckhaupt and Sestito 2013). Yong et al. (2017), using NHANES data, reported that several sleep problems were significantly higher among night shift workers than a representative sample of U.S. workers. Self-reported short sleep duration (61.8%), poor sleep quality (30.7%), sleep-related activities of daily living (ADL) (36%), and insomnia (18.5%) were all highest for night shift workers in the United States, with night shift workers having the highest likelihood of these sleep problems in a multivariate analysis. Even in retirement, persons who worked shifts during their pre-retirement years had significantly worse scores on the Pittsburgh Sleep Quality Index by 0.96 units (1 to 15 years) and 0.61 units (> 15 years) relative to retired day workers independent of gender, former occupation, morningness, or current health (Monk et al. 2013). Guo et al. (2013) also investigated the effects of shift work on sleep quality in a cohort of retired workers (> 26,000 workers including > 9,000 shift workers) from a motor corporation in China. This study reported poorer sleep quality in retired shift workers that gradually improved to baseline quality levels after 20 years. Rahman et al. (2013) reported that both daytime and nighttime sleep are adversely affected in rotating-shift workers and suggested that filtering short wavelengths may reduce sleep disruption.

Overall, the epidemiological evidence that sleep duration is related to breast cancer risk is unclear (reviewed by Samuelsson et al. 2018), with some studies finding no association and others finding an increased risk with long sleep durations, short durations, or both short and long sleep durations. A recent meta-analysis (Lu et al. 2017) modeled the estimates from 10 studies of breast cancer and sleep duration and reported a significant excess risk of breast cancer among women sleeping for longer durations, especially of ER+ breast cancer. Other studies found that short sleep duration (≤ 6 hours) was associated with ER− and PR− breast cancer in all women (Xiao et al. 2016), black women (Xiao et al. 2016), or never shift workers (Wang et al. 2015a). An earlier meta-analysis (Yang et al. 2014) reported no relationship between sleep duration and breast cancer risk. The small excess risks associated with long sleep duration reported in each study may be an “epiphenomenon” of comorbidity as suggested by Stranges et al. (2008) who found that several sociodemographic, lifestyle, and comorbidity factors could confound or mediate U-shaped associations between sleep duration and health (e.g., longer and shorter sleep durations related to breast cancer risk).

Four studies, including the Million Women Study (Travis et al. 2016) contributed information about sleep duration among night shift workers. McElroy et al. (2006) and Pinheiro et al. (2006) investigated the impact of night work history on the relationship between sleep duration and breast cancer risk and found no differences. Wang et al. (2015a) reported a statistically significant 83% increased risk among women who had ever worked nights and reported sleep durations of ≤ 6 hours. In the Million Women Study, consideration of sleep duration made no difference in the relationship between shift work and breast cancer risk.

Fritschi et al. (2013) reported on a composite variable of self-reported “sleep disturbances” including short (< 6 hours) or long (≥ 9 hours) sleep duration, poor sleep quality, and frequent difficulty falling or staying asleep. A non-significantly elevated risk of breast cancer was found among those reporting ever having any sleep disturbance (OR = 1.21, 95% CI = 0.95 to 1.55). Girschik et al. (2013) reported on sleep duration in this same case-control population and found no relationship between short or long sleep duration and breast cancer.

Possible mechanisms and other factors contributing to adverse effects of sleep deprivation include interactions with melatonin, oxidative stress, immune suppression, DNA damage repair, timing and quality of food intake, alcohol intake, tobacco use, and physical inactivity (Anjum et al. 2012, Bhatti et al. 2016, Nagata et al. 2017). Acute sleep deprivation affects the melatonin rhythm and core clock gene expression in peripheral tissues (Ackermann et al. 2013, Archer and Oster 2015). Independent of melatonin suppression, sleep deprivation is associated with many of the chronic diseases (e.g., obesity, type II diabetes, hypertension, and cancer) that are associated with circadian disruption, and can lead to immune suppression and a shift to a cancer-stimulatory cytokine secretion pattern (Balachandran 2011, Nagai et al. 2011, Faraut et al. 2012, Gamaldo et al. 2012). Mistimed sleep significantly reduced the number of rhythmic transcripts in the human blood transcriptome and altered the expression of key regulators of gene expression (including methylases and acetylases involved in chromatin modifications, RNA polymerase, ribosomal proteins involved in translation, and some core clock genes) (Archer et al. 2014). In addition, sleep deprivation affects the appetite hormones leptin and ghrelin, resulting in increased hunger and possibly contributing to increased prevalence of obesity among shift workers (Taheri et al. 2004, Figueiro et al. 2012, Zubidat and Haim 2017). Figueiro et al. (2017) also showed that exposure to high levels of circadian-effective light during the morning or during the entire day was associated with higher sleep quality, reduced depression, and improved circadian entrainment. Taking a short nap during nighttime shift work may also have some benefits. Female nurses who took a short nap during night shift work had significantly lower 17ß-estradiol levels compared to night-shift nurses who did not take a nap (Bracci et al. 2013).

### 6.4.3 Meal timing

The feeding-fasting cycle is recognized as an important nonphotic zeitgeber for peripheral clocks, and meal timing is particularly important for glucose homeostasis (Asher and Sassone-Corsi 2015, Wehrens et al. 2017). Fonken et al. (2010) reported that mice exposed to constant bright light or dim LAN had significantly increased body mass and reduced glucose tolerance compared to mice exposed to a standard LD cycle, even though the total caloric intake and daily activity were similar among the groups. The primary difference was that exposure to LAN shifted the time of food intake and disrupted metabolic signals. The effects of simulated shift work on the pro-inflammatory response to a LPS challenge in rats was eliminated by food restriction during their forced activity schedule and indicates that mistimed food consumption was a major factor contributing to the inflammatory response (Guerrero-Vargas et al. 2015). Time-restricted feeding studies in rodents show that meal timing can reset circadian clocks in peripheral tissues (Wu et al. 2004, Filipski and Levi 2009). Filipski and Levi (2009) reported that meal timing (12 hours on and 12 hours off) counterbalanced circadian disruption produced by simulated chronic jet lag in mice by restoring near-normal circadian patterns in the liver and slowed tumor growth. Wu et al. (2004) examined the effects of meal timing on growth of transplanted Glasgow osteosarcoma in male mice. Tumors grew more slowly in mice on a restricted feeding schedule (i.e., restricted to 4 or 6 hours during the light or dark phase) compared to mice given food ad libitum. Overall survival was longer and tumor growth was slower in mice fed during the light phase, suggesting that meal timing during the light phase reduced tumor growth by modifying circadian clock function or signaling pathways within peripheral tissues and tumor cells.

The effects of time-restricted feeding have not been thoroughly investigated in humans (Asher and Sassone-Corsi 2015). One study reported that eating after 10:00 PM was significantly associated with breast cancer (OR = 1.5, 95% CI = 1.06 to 2.12; P = 0.02). Those with ≥ 20 years duration of eating after 10:00 PM had an OR of 2.28 (95% CI = 1.13 to 4.61); those who ate between midnight and 2:00 AM had an OR of 2.73 (1.01 to 6.99) (Li et al. 2017). The effect was strongest among women who ate staple foods such as noodles (OR = 2.79, 95% CI = 1.58 to 4.94; P < 0.001) or rice (OR = 2.58, 95% CI = 1.42 to 4.69; P = 0.002); however, there was no evidence of a relationship between breast cancer risk among women eating fruits and vegetables at these times. Simulated shift work in healthy volunteers (i.e., mistimed food intake and sleep) altered the circadian patterns of 127 plasma proteins (including 30 proteins showing strong circadian regulation) compared to volunteers with sleep and food intake patterns in phase with the endogenous circadian clock (Depner et al. 2018). The biological pathways associated with the altered proteins included immune function, glucose homeostasis and/or energy metabolism, and cancer (e.g., tyrosine kinase signaling, receptor tyrosine-protein kinase erbB-2, DNA damage checkpoints). There is some evidence that meal timing and eating frequency are associated with metabolic and inflammatory biomarkers that are putatively associated with breast cancer risk (Marinac et al. 2015a, Marinac et al. 2015b, Marinac et al. 2016). C-reactive protein concentrations increased 3% for every 10% increase in the proportion of calories consumed in the evening. There was also a significant association between calories consumed during the evening and fasting duration with C-reactive protein levels and glucose metabolism. A nightly fasting duration of < 13 hours was associated with an increased risk of breast cancer recurrence but not with a higher risk of breast cancer mortality compared with fasting ≥ 13 hours per night (Marinac et al. 2016). Shift workers, and especially rotating shift workers, had significantly higher dietary inflammatory index scores compared to day workers (Wirth et al. 2014a, Wirth et al. 2014b). Some of the most likely factors contributing to poorer dietary habits among shift workers include nighttime consumption of food, increased snacking compared to day workers, stress, fatigue, and sleep loss. Although it is uncertain whether or not the differences in inflammatory potential are biologically significant, it is known that chronic inflammation is a risk factor for several chronic diseases including cancer. Nagata et al. (2017) reported that women shift workers who ate nighttime snacks at irregular hours had higher levels of oxidative stress compared to those who did not eat snacks or who ate snacks on a regular schedule.

### 6.4.4 Co-exposure to carcinogens or toxicants

Night shift workers can also be exposed to other carcinogens in the work place. Studies have shown that absorption, distribution, metabolism, and excretion of xenobiotic agents can vary by circadian stage of exposure raising the possibility that risk from co-exposure to other carcinogens may differ depending on the time of exposure in the 24-hour day. A review by Smolensky et al. (2017) found evidence suggesting that circadian timing of exposure to xenobiotics affects tolerance and adverse outcomes (although cancer was not reviewed specifically). Clinical studies have demonstrated that timing of medication administration also affects efficacy of treatment.

Some initiation-promotion studies found that time of day of carcinogen application affected tumor burden (Clausen et al. 1984, Iversen and Iversen 1995, Wille 2003, Gaddameedhi et al. 2011) with one study finding that tumor multiplicity was correlated with timing of peak activity of a DNA repair protein (Gaddameedhi et al. 2011). Finally, the initiation-promotion studies of simulated shift work or LAN in animals also support a potential interaction between circadian disruption (induced by shift work or LAN) and cancer growth (see Section 5).

## 6.5 Synthesis

Human and animal studies show that exposure to shift work, jet lag, and/or LAN can induce circadian disruption as evidenced by desynchronization of the central clock-SNS-peripheral clock axis, melatonin suppression, alterations of physiological or hormonal circadian biomarkers, and/or altered clock gene expression. Shift work is the best studied LAN-associated exposure in humans and represents extensive LAN exposure conditions. Epidemiological studies of night shift workers suggest an increased risk of breast cancer in women, and to a lesser degree, an increased risk of prostate cancer in men (see Sections 3 and 4). LAN, shift work, and jet lag studies in humans and experimental animals also show direct evidence of several biological effects with a known connection to cancer (i.e., hallmarks of cancer and/or characteristics of carcinogens). These include reduced DNA repair and genomic instability, epigenetic modifications and altered gene expression, oxidative stress, chronic inflammation and immunosuppression, metabolic disturbances, and altered hormone rhythms. Several of these studies also reported a connection of these effects with accelerated tumor growth.

The proposed mechanisms linking shift work and LAN, circadian disruption, and cancer focus on the biological properties of melatonin and the broader role of the circadian system, autonomic and neuroendocrine signaling, and clock genes (circadian disruption theory) in tumor suppression and maintaining cellular and tissue homeostasis. There is substantial experimental evidence that both melatonin and the circadian timing system can protect against tumor development and progression and affect mechanisms and pathways that are relevant to all the hallmarks of cancer. Although interconnected, both factors can also protect against tumor development independently. Studies in experimental animals demonstrate that LAN-induced melatonin suppression accelerates tumor growth while melatonin treatment inhibits tumor growth via several oncostatic pathways. Experimental studies also strongly support the role of clock genes in maintaining cell and tissue homeostasis and in tumor suppression. Genetic models in rodents show that knockouts or mutations in the core clock genes are associated with circadian disruption and a cancer-prone phenotype. Disrupted clock gene expression is characteristic of many human cancers. Consequently, melatonin suppression and other types of circadian disruption may promote neoplastic transformation via multiple pathways involving disrupted circadian homeostatic controls that affect energy balance, DNA repair, immune function, hormone levels and signaling pathways, angiogenesis, cell cycle, and apoptosis.

Although the detailed mechanisms are not fully understood, it is clear that shift work and LAN represent complex exposure scenarios that contribute to circadian disruption and other biological effects that are directly relevant to cancer initiation, promotion, and progression. In addition to the complex interactions among melatonin, other hormones, the central clock, peripheral clocks, and clock-controlled genes, interactions also occur with other factors that are associated with shift work and LAN that may mitigate or exacerbate circadian disruption. These include sleep and sleep deprivation, vitamin D, meal timing, chronic disease, and various lifestyle factors (e.g., smoking, drinking, drugs, exposure to environmental chemicals and pollutants, social factors, and physical activity). Because of the complex interactions and overlapping effects of LAN-induced melatonin suppression, circadian disruption, sleep deprivation, and other factors, it is currently impossible to separate their relative individual contributions to cancer development and progression. All of the proposed mechanisms or modes of action have experimental support from studies in humans, human cell lines, and experimental animals and are relevant to humans.