# 4 Other Human Cancer Studies

## Introduction

The objective of this section is to evaluate the level of evidence (sufficient, limited, or inadequate) of the carcinogenicity of night work for cancers other than breast cancer. The major cancers of interest include prostate (Section 4.1), colorectal cancer (Section 4.2), female hormonal cancers (i.e., ovarian and endometrial cancers, Section 4.3), and lung cancer (Section 4.4). The database was inadequate to conduct formal cancer hazard assessments for other cancer sites (e.g., malignant melanoma, other skin cancers, leukemia, non-Hodgkin lymphoma [NHL], stomach and pancreatic cancers) (Section 4.5) or other exposure scenarios (e.g., light at night [LAN], transmeridian travel, geographical coordinates) (Section 4.6).

Twenty-five studies of night work and hormonal, prostate, colorectal, or lung cancers satisfied the inclusion criteria, including twelve cohorts and seven population-based case-control studies of independent populations from the United States, Europe, the United Kingdom, Canada, China, and Australia. Although most studies examined exposure to night work and risk of one cancer type, a few cohort studies (Taylor and Pocock 1972, Schwartzbaum et al. 2007, Yong et al. 2014a, Jørgensen et al. 2017) and two case-control studies (Parent et al. 2012, studies on the Spanish multi-center case-control study by Papantoniou and colleagues) reported on night work and multiple primary cancer sites of interest. Nurses, workers in specific occupational settings, and general populations are represented in the studies; with one exception (Taylor and Pocock 1972), all were published since 2003. A Japanese cohort study by Fujino (2007) examined shift work and mortality from multiple incident cancer types, but was excluded due to insufficient information on population and methods. Studies of workers that provided job title alone and no further specification of shifts worked, e.g., radio and telegraph operators (Tynes et al. 1996), were not included.

Each cancer hazard assessment includes an evaluation of study quality followed by a synthesis of the evidence across cancer sites. Similar to the assessment of studies on breast cancer, the evaluation of potential selection and exposure misclassification bias and sensitivity played a major role in identifying the most informative studies. Methods for evaluating study quality and synthesizing the evidence across studies are described in Section 3 and the Shift Work at Night, Light at Night, and Circadian Disruption Protocol (NTP 2018).

Circadian disruption is not directly measured; thus, persistent practices of night shift work may be a surrogate for night shift work related to chronic circadian disruption (e.g., long duration, high frequency, or intensity of night work schedules). Other key issues that may modify the relationship of circadian disruption and cancer include participant’s chronotype. Issues specific to particular cancers are prostate cancer severity, ovarian and lung cancer subtypes, smoking, and specific cancer subtypes and gender for colorectal cancer.

## 4.1 Prostate cancer

Prostate cancer is the most common non-skin cancer in men living in the United States, representing almost 10% of all incident cancers. Approximately 161,360 incident prostate cancer cases and 26,730 prostate cancer deaths were predicted for 2017 in the United States (Howlader et al. 2017). Prostate cancer has a high survival rate, with 98.2% of men living past five years from diagnosis. Prostate cancer aggressiveness, however, is a critical component of disease progression and cancer severity. Evidence shows that tumor severity, classified as Gleason grade, is generally established early in tumor pathogenesis (VanderWeele et al. 2014) and that lower grade prostate cancer does not always progress to more severe grades (Penney et al. 2013), suggesting prostate cancer aggressiveness is an important factor to consider. Further, risk factors associated with aggressive prostate cancer, such as obesity, should be taken into consideration (Allott et al. 2013). As non-aggressive prostate cancer is not immediately fatal, the use of mortality data in studies may represent both new and prevalent cases of disease, and most of the incident cases in a given year would not be captured by mortality for that year, as deaths for any given year represent cases diagnosed years earlier.

### 4.1.1 Overview of study methods and characteristics

Eight cohort studies (Kubo et al. 2006, Schwartzbaum et al. 2007, Kubo et al. 2011, Gapstur et al. 2014, Hammer et al. 2015, Dickerman et al. 2016, Åkerstedt et al. 2017, Behrens et al. 2017) and five population-based case-control studies (Conlon et al. 2007, Parent et al. 2012, Papantoniou et al. 2015b, Tse et al. 2017, Wendeu-Foyet et al. 2018) of incident prostate cancer were eligible for review (Table 4-1). Studies by Yong et al. (2014a) and Yong et al. (Yong et al. 2014b) used the same study population of male chemical workers as Hammer et al. (2015) to examine multiple cancers, including prostate cancer; however, Hammer et al. (2015) provided a more in-depth analysis of prostate cancer incidence, and therefore, will be included. Tables include details only from the latest update of a study population or the most comprehensive report on a population. Detailed data on study design, methods, and findings were systematically extracted as described in the study protocol.

Table 4-1 Studies of prostate cancer and night work

Reference | Population | Outcome and source(s) | Exposure assessment and information
Cohort studies
Kubo et al. 2006 | Japan Collaborative Cohort Study; 1988–1990 (enrollment); 14,052 working men (population based) | Incident prostate cancer; Death certificates and linkage with cancer registries | Self-administered questionnaire; Night work: fixed and rotating shift not defined; Metrics: type of shift at longest job
Schwartzbaum et al. 2007 | Swedish workers, registry-based cohort; Registered in 1960 and 1970 census (enrollment); 1971–1989 (follow-up); 2,102,126 workers (population based) | Incident cancer using prostate and other cancers; Swedish Cancer Registry or Cause of Death Register (SIR study) | Job exposure matrix (JEM); Night work: workplace had rotating schedule or work between 1:00 AM & 4:00 AM; Metrics: ever worked in occupation–industry combinations
Kubo et al. 2011 | Japanese industry-based retrospective cohort; Records from 2006–2008; 4,995 working men (specific manufacturing corporation) | Incident prostate cancer; Health insurance records | Company records; Night work: continuous counter-clockwise 3-shift rotation system; Metrics: ever worked a rotating shift for > 80% of career
Gapstur et al. 2014 | U.S. Cancer Prevention Study II cohort study; 1982–2010 (enrollment and follow-up); 305,057 employed men (population based) | Fatal prostate cancer; Underlying cause of death; Personal inquiries and verification using death certificates/national registry | Self-administered questionnaire; Night work: not defined for rotating shifts, fixed night started work from 9:00 PM–midnight; Metric: current type of shift work (fixed night or rotating shifts)
Hammer et al. 2015 | German Rhineland-Palatinate chemical workers; 1995–2005 (employment records); 2000–2009 (follow-up); 27,828 male production workers (specific chemical company) | Incident prostate cancer; type of cancer; Rhineland-Palatinate Cancer Registry | Company records; Night work: forward rotating system: one 12-hr shift (6:00 AM–6:00 PM), 24 hr off, 12-hr (6:00 PM–6:00 AM), and another 48 hr off); Metric: ever worked
Dickerman et al. 2016 | Older Finnish Twin Cohort; 1981–2012 (follow up period); 11,370 men who were twins born before 1958 | Histologically confirmed incident and fatal prostate cancer; National registries | Self-administered questionnaire; Rotating shifts: rotated through morning, evening, or night shifts in a 2- or 3-shift pattern; Night work: fixed or night shift not defined; Metrics: type of shift, work at current or latest job, chronotype
Åkerstedt et al. 2017 | Swedish Twins Registry cohort study; 1998–2010 (enrollment and follow-up period); 12,322 men who were twins born before 1959 | Incident prostate cancer; Swedish cancer or death registries | Telephone-based questionnaire; Night work: not defined; Metrics: ever (1+ year), duration of night work
Behrens et al. 2017 | German Heinz-Noxdorf Recall cohort study; 2000–2011 (enrollment and follow-up period); 1,757 men residing in highly industrialized Ruhr area (population based) | Incident prostate cancer; Medical or death records | Computerized baseline questionnaire (not known who administered it). Follow-up questionnaire by mail; Night work: 12:00 AM–5:00 AM (night work), any hours from 6:00 PM–7:00 AM (shift work); Metrics: ever worked (1+ year), duration of night or shift work, preferred midpoint of sleep
Case-control studies
Conlon et al. 2007 | Northeastern Ontario case-control study; 1995–1998 (enrolled); 760 cases; 1,632 population-based controls | Incident prostate cancer; Ontario cancer registry 1995–1998 | Self-administered questionnaire; Night work: rotating full-time (not defined); Metrics: ever worked, duration, age at first shift work, and years since full-time rotating shiftwork
Parent et al. 2012 | Montreal multisite case-control cancer study; 18 hospitals; 1979–1985 (enrolled); 400 male cases; 512 male population-based controls | Incident, histologically confirmed prostate, colon, rectal, lung, and other cancers; Cases from pathology departments in Montreal hospitals | In-person questionnaire; Night work: included work between 1:00 AM–2:00 AM for ≥ 6 mo; Metrics: Ever, cumulative duration, and night work ≤ 20 yr or ≥ 20 yr in the past
Papantoniou et al. 2015b | MCC-Spain population-based case-control study; 11 hospitals, 7 regions; 2008–2013 (enrolled); 1,095 cases; 1,388 population-based controls | Histologically confirmed prostate cancer, including anatomical, pathological, and clinical stage, prostate-specific antigen (PSA) levels and Gleason score for most cases; Medical records | In-person interviews with questionnaire; Night work: any time between midnight & 6:00 AM for ≥ 3 nights/mo; Metrics: Ever worked shifts (≥ 1 yr), type of shift (permanent and rotating), cumulative duration, cumulative frequency, duration, and frequency by chronotype
Tse et al. 2017 | Chinese hospital-based case-control study; 2011–2016 (enrollment period); 431 male cases; 402 male hospital controls without cancer | Newly confirmed prostate cancer by histology; Hospital-based cases and controls | In-person questionnaire; Night work: 1+ hour between midnight & 5:00 AM; Metric: ever worked (more than once a month for > 1 yr)
Wendeu-Foyet et al. 2018 | France EPICAP population-based case-control study; 2012–2013 (enrolled); 819 male cases; 879 male population-based controls | Newly confirmed prostate cancer by histology, including Gleason score, PSA levels, and stage; Medical records and cancer registry | In-person questionnaire; Night work: 270 hr or 3 nights/mo for > 1 yr; Metrics: ever worked, shift type (permanent or rotating), duration, number of consecutive nights worked, night shift length, cumulative frequency, shift timing, rotation type, shift rotation speed, sleep duration, chronotype

hr = hour(s); JEM = job-exposure matrix; mo = month(s); PSA = prostate-specific antigen; yr = year(s).

Studies were from a broad geographic range, including populations from the United States, Canada, Spain, Germany, Sweden, Finland, France, and Japan. Cohort studies comprised occupational chemical and manufacturing workers, as well as the general population, including a cohort of twins. Cancer incidence was determined through registry linkages, death certificates or registries, and company records. A cross-sectional study showing men ages 40 to 65 years old in the National Health and Nutritional Examination Survey (NHANES) who reported working shifts had significantly elevated prostate-specific antigen (PSA) levels at or above 4.00 ng/mL (Flynn-Evans et al. 2013). This study, however, was excluded because only the PSA screening test, but no incident cancer, was reported.

### 4.1.2 Evaluation of study quality

A detailed evaluation of study quality for all potential biases is available in Appendix D, Table D-1; an overview of the assessment is provided in Table 4-2. It should be noted that studies by Schwartzbaum et al. (2007) and the study design of Papantoniou et al. (2015b) have also been evaluated and described in detail in the breast cancer section (see Section 3 for details on study quality metrics), and thus, will not be discussed in detail in this section except for an overall study utility assessment; additional study findings are provided in Appendix D, Table D-2. Similar to the breast cancer evaluation, Schwartzbaum et al. (2007) was ultimately excluded from the hazard evaluation due to poor exposure assessment.

Table 4-2 Summary of study quality: Shift work and prostate cancer

Citation | Selection^a^ | Exposure | Outcome | Confounding methods | Adequacy of analysis | Selective reporting | Sensitivity | Utility^b^
Cohort studies
Kubo et al. 2006 | ++ | + | ++ | +++ | +++ | +++ | + | +
Schwartzbaum et al. 2007 | ++ | 0 | +++ | +++ | ++ | +++ | + | 0
Kubo et al. 2011 | + | ++ | + | +++ | + | ++ | + | +
Gapstur et al. 2014 | +++ | 0 | ++ | ++ | +++ | +++ | + | 0
Hammer et al. 2015 | ++ | + | ++ | +++ | +++ | +++ | + | +
Dickerman et al. 2016 | +++ | 0 | +++ | +++ | +++ | +++ | + | 0
Åkerstedt et al. 2017 | ++ | + | +++ | +++ | +++ | +++ | + | +
Behrens et al. 2017 | ++ | +++ | ++ | +++ | +++ | +++ | ++ | +++
Case-control studies
Conlon et al. 2007 | ++ | ++ | ++ | +++ | ++ | +++ | ++ | ++
Parent et al. 2012 | +++ | ++ | +++ | ++ | +++ | +++ | ++ | ++
Papantoniou et al. 2015b | ++ | ++ | +++ | +++ | +++ | +++ | ++ | +++
Tse et al. 2017 | ++ | + | +++ | +++ | +++ | +++ | + | +
Wendeu-Foyet et al. 2018 | +++ | +++ | +++ | +++ | +++ | +++ | +++ | +++

a Levels of concern for bias and for study sensitivity (columns for Selection through Sensitivity). Key: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

b Utility of the study to inform the hazard evaluation. Key: +++ = high utility; ++ = moderate utility; + = low utility; 0 = inadequate utility.

#### Selection bias

Potential selection bias is a major concern for one study. The Japanese manufacturing study by Kubo et al. (2011) included a small, highly selected surviving sub-cohort of participants (ages 49 to 65) from a larger cohort. If persons not able to tolerate shift work left the cohort, died, or changed to day work, they would not have been identified in this sub-cohort of survivors. This suggests that the estimate of effect in this study might be biased towards the null.

Some studies were determined to have minimal (Parent et al. 2012, Gapstur et al. 2014, Dickerman et al. 2016, Wendeu-Foyet et al. 2018) or some concern (Kubo et al. 2006, Conlon et al. 2007, Kubo et al. 2011, Hammer et al. 2015, Papantoniou et al. 2015b, Åkerstedt et al. 2017, Behrens et al. 2017, Tse et al. 2017) for selection bias. For Behrens et al. (2017), eligible subjects who did not participate in follow-up had higher rates of prostate cancer which may attenuate the risk estimates if those participants were more likely to have engaged in shift work.

Concerns of selection bias are present in the German chemical industry (Yong et al. 2014a, Hammer et al. 2015), as employees of the chemical company were required to have a medical examination both prior to work and subsequently every three years. The authors considered that healthy worker survival bias may be induced through ongoing selection out of the shift-worker group based on health-related criteria, so a term for employment duration was included in regression models as a proxy for work-related effects. Both day and shift workers had a higher incidence of prostate carcinoma than the general population (standardized incidence rate [SIR] = 1.44, 95% confidence interval [CI] = 1.22 to 1.70 for daytime workers; SIR = 1.51, 95% CI = 1.30 to 1.74 for shift workers), indicating potential detection bias in this industry population with access to prostate screening. The study by Åkerstedt et al. (2017) may be subject to potential healthy-worker survivor effect (HWSE) as it did not have adequate information on lifetime history of shift work in a primarily older study population (41–60 years old) at baseline.

Attrition bias was possible in two case-control studies (Conlon et al. 2007, Papantoniou et al. 2015b) where non-participants differed from participants and fewer than 50% of the controls responded to the questionnaire, substantially fewer than among cases (74%). The use of hospital controls in Tse et al. (2017), which included patients with pancreatic and colorectal diseases, may not have been an ideal comparator group considering the potential impact of night work on pancreatic and colorectal cancers. It should be noted that the case-control studies by Parent et al. (2012) and Papantoniou et al. (2015b) used the same control population for multiple cancer case examinations. If the control population was not selected to be appropriate for all cancer cases, then the results may be subject to selection bias.

#### Exposure misclassification

Similar to studies on breast cancer, the ranking of the exposure assessment is determined by the integration of three factors: (1) how night work was initially defined, (2) the quality of the measurements, and (3) whether the study includes one or more metrics that can differentiate those with the most persistent night shift work practices from those with less extensive night shift work practices.

Definitions of night work exposure varied among prostate cancer studies, making for complex comparisons. Only six studies considered individuals exposed if they worked nights at least six months (Parent et al. 2012) or one year (Papantoniou et al. 2015b, Åkerstedt et al. 2017, Behrens et al. 2017, Tse et al. 2017, Wendeu-Foyet et al. 2018). As mentioned in Section 3.2.1, studies characterizing night work as either a narrow range of nighttime hours or minimum number of night hours worked are subject to less exposure misclassification (Garde et al. 2016). Five studies defined exposure as working anytime between a range of night hours (Schwartzbaum et al. 2007, Gapstur et al. 2014, Papantoniou et al. 2015b, Behrens et al. 2017, Tse et al. 2017). Parent et al. (2012) defined night work that included working between 1:00 AM and 2:00 AM. Hammer et al. (2015) defined rotating shift work as working a 12-hour shift from 6:00 PM to 6:00 AM. Wendeu-Foyet et al. (2018) used the French definition of night shift work which involves night work for 270 hours/year or 3 nights/month. Other available studies are subject to exposure misclassification as explicit timings of night or rotating shift work were not captured.

Exposure information was assessed using questionnaire data, occupational records, or a job exposure matrix (JEM). Two cohort studies (Gapstur et al. 2014, Dickerman et al. 2016) based their exposure assessments on current employment at baseline only, with no data on lifetime exposure, and therefore were considered to be of critical concern. All other studies except for Behrens et al. (2017) and Wendeu-Foyet et al. (2018) were considered to have high or moderate concern for exposure misclassification. Most studies did not adequately assess lifetime history of shift work. Based on this limited information, if unexposed participants had actually engaged in shift work at a prior time period, exposure status will have been misclassified and therefore effect estimates may be biased toward the null.

In both cohorts described in Hammer et al. (2015) and Yong et al. (2014a), occupational exposure records were not available for the entire period of a worker’s employment. To assess the extent of misclassification bias, the authors examined a random sample of workers and found that 5% of the day workers transferred at least once to shift work and 18% of the shift workers had transferred to day work. Regarding duration, the authors calculated an error rate of exposure duration of 2.2% for day workers and 11.6% for shift workers. For ever exposure to shift work, misclassification in individuals known to be shift workers after 1995 would be low, but day workers after 1995 may not be truly unexposed, leading to a bias away from the null.

The most common metrics in the studies were type of shift and duration of working night shift. Night work type was not consistently categorized across studies, with five studies differentiating fixed and a rotating night shift schedule (Kubo et al. 2006, Gapstur et al. 2014, Papantoniou et al. 2015b, Dickerman et al. 2016, Wendeu-Foyet et al. 2018), and four studies examining a rotating shift schedule only (Conlon et al. 2007, Schwartzbaum et al. 2007, Kubo et al. 2011, Hammer et al. 2015). Rotating shift patterns were detailed in few studies, including a three-shift counter-clockwise pattern (Kubo et al. 2011), a two- or three-shift pattern (Dickerman et al. 2016), a forward rotating pattern (Hammer et al. 2015), or only forward, only backward, or both pattern types (Wendeu-Foyet et al. 2018). A few studies may have defined rotating night work to include both night and evening shifts (Conlon et al. 2007, Hammer et al. 2015, Dickerman et al. 2016). Wendeu-Foyet et al. (2018) also examined differences by shift timings, as either early morning, late evening, or overnight shifts.

Three studies (Kubo et al. 2006, Åkerstedt et al. 2017, Tse et al. 2017) relied on an overall question on prior shift work history to attempt to characterize exposure but without further capturing total work history, and thus may be subject to misclassification.

##### Sensitivity

All of the cohort studies lacked sensitivity for a variety of reasons: small numbers of exposed cases (Kubo et al. 2011, Behrens et al. 2017), young cohort (Hammer et al. 2015), or very little information on exposure variability (Schwartzbaum et al. 2007, Gapstur et al. 2014, Dickerman et al. 2016).

##### Overall study utility

Four case-control studies (Conlon et al. 2007, Parent et al. 2012, Papantoniou et al. 2015b, Wendeu-Foyet et al. 2018) and one cohort study (Behrens et al. 2017) were considered to be of high or moderate utility, and therefore, were the most informative studies (Table 4-2). In general, these studies captured lifetime history of shift work, at least a moderate number of exposed prostate cancer cases, and, for the cohort study, an internal comparator analysis. Five studies were categorized as having low or moderate utility (Table 4-2). Lastly, three cohort studies (Schwartzbaum et al. 2007, Gapstur et al. 2014, Dickerman et al. 2016) were deemed as inadequate study utility either for measuring current shift work exposure only or very poorly characterizing shift work.

### 4.1.3 Prostate cancer hazard assessment

Findings for all the individual studies included in the analysis are available in Appendix D, Table D-2, and selected findings are graphed in the forest plots below.

As stated in Section 3.2.5, NTP did not consider the meta-analysis approach informative and thus did not include its own meta-analysis nor did it include the published meta-analyses in the cancer hazard assessment. Three meta-analyses (Rao et al. 2015, Gan et al. 2018, Mancio et al. 2018), published since 2013, found significant aggregate risk estimates greater than 1.00 with ever working shifts, but only for rotating shift types. Two of three analyses found an exposure-response trend with increasing duration of shift work exposure. One meta-analysis found elevated estimates for studies of Asian populations compared to Western populations. Limitations that weakened the utility of these meta-analyses for the purposes of this assessment were the inclusion of studies with poorly characterized shift work, including only concurrent shift work exposure and not including the most recent large case-control study of prostate cancer (Wendeu-Foyet et al. 2018)

#### Consistency of the evidence across studies

Overall, the identified prostate cancer studies provide consistent evidence of an association with prostate cancer risk. Moreover, prostate risk was associated with persistent night shift work (e.g., long duration, high cumulative frequency of night shifts over a lifetime, or combinations of frequency and duration).

Seven of the ten studies provided evidence that night shift work increases prostate cancer risk (Table 4-3 shows the studies grouped by level of evidence and study utility). As described in Section 3, the level of evidence for each study was reached by considering the findings across all metrics or analyses reported in the study as well as study quality, and the direction (if known) for any potential biases. Studies providing moderate to strong evidence found significant positive relationships, increased risk of prostate cancer in those working nights for the longer duration of exposure, and/or a significant positive trend of prostate cancer with night work duration (Parent et al. 2012, Papantoniou et al. 2015b, Behrens et al. 2017). Studies providing some evidence found a significant association with night work and prostate cancer; however, the positive findings were restricted to limited analyses. Some studies did not have adequate information on duration of night work (Kubo et al. 2006, Tse et al. 2017). Wendeu-Foyet et al. (2018) saw evidence of a relationship only when persistent permanent shift work was performed, and Conlon et al. (2007) saw significantly increased prostate cancer risk only in certain younger age groups and durations of shift work but no clear exposure-duration patterns were observed.

Two studies (Hammer et al. 2015, Åkerstedt et al. 2017) did not find associations with prostate cancer risk and the evidence from the remaining study by Kubo et al. (2011) was considered inconclusive due to a small number of exposed cases and inadequate information on night work exposure.

The major predictor of heterogeneity across studies was study quality. All of the most informative studies (high or moderate quality) found an association between night work and prostate cancer risk. Of the lower quality studies, two were considered to offer some evidence of an effect (Kubo et al. 2006, Tse et al. 2017) and three were null or inconclusive (Kubo et al. 2011, Hammer et al. 2015, Åkerstedt et al. 2017).

The summary of the key metrics measured, study utility, and level of evidence of all studies is listed in Table 4-3. Details on the metrics of exposure and effect modifiers are discussed below.

Table 4-3 Evidence summary table and key metrics assessed for studies of night work and prostate cancer

Reference | Study utility | Study design | Key metrics measured in study
Reference | Study utility | Study design | Ever worked | Years worked | Cumulative frequency | Cancer severity
Strong evidence or some evidence of prostate cancer risk
Behrens | +++/++ | Cohort | *** | ***
Papantoniou | +++/++ | Case-control | ** | *** | ** | ***
Wendeu-Foyet | +++/++ | Case-control | Null | *** | ** | **
Conlon | +++/++ | Case-control | *** | **
Parent | +++/++ | Case-control | *** | ***
Kubo 2006 | + | Cohort | **
Tse | + | Case-control | *
Null or inconclusive evidence
Kubo 2011 | + | Cohort | *
Hammer | + | Cohort | Null | | | Null
Åkerstedt | + | Cohort | Null | Null

+++/++ = informative (dark yellow); + = low utility (light yellow); strength of association increases with number of * and darker shade of blue for key metrics.

#### Metrics of exposure

Most studies reported on ever exposure, five studies reported on exposure duration (Conlon et al. 2007, Parent et al. 2012, Åkerstedt et al. 2017, Behrens et al. 2017, Wendeu-Foyet et al. 2018), and two studies reported on lifetime cumulative shifts (Papantoniou et al. 2015b, Wendeu-Foyet et al. 2018).

##### Ever night work

The evaluated studies differed in their approaches to classifying exposure to shift and/or night work, which may add to the heterogeneity in results (see Figure 4-1). Overall, four of the five moderate- and high-utility studies reported an elevated risk of prostate cancer in individuals who had ever worked night shifts (Conlon et al. 2007, Parent et al. 2012, Papantoniou et al. 2015b, Behrens et al. 2017), two of which were statistically significant (Parent et al. 2012, Behrens et al. 2017). Wendeu-Foyet et al. (2018) reported a null association with ever working night shifts.

Figure 4-1 Forest plot of human studies on the risk of prostate cancer from ever exposure to night work; stratified by study utility

The figure depicts a forest plot of the risk of prostate cancer and ever exposure to night shift work by study utility. Of the 5 high utility studies, 3 reported statistically significant elevated risk estimates ranging from 1.19 to 2.77. Of the 5 low utility studies, 3 reported excess risks, ranging from 1.77 to 3.00, with two of these being statistically significant,

Note: Plotted confidence intervals (CI) are standardized and estimated based on software package, and therefore may differ slightly from study confidence intervals.

All remaining studies were determined to have low study utility. Hammer et al. (2015) reported a null association between night work in an occupational setting in Germany and risk of prostate cancer. Two studies (Kubo et al. 2006, Tse et al. 2017) reported elevated risks based on very small numbers of rotating shift worker cases. Another study reported a positive but non-significant relationship between night work and prostate cancer (Kubo et al. 2011). Although Åkerstedt et al. (2017) found a null association of night work and prostate cancer, a duration-stratified model showed a slight increased risk compared to unadjusted estimates for certain durations of night work exposure.

##### Exposure metrics

Although the definitions of duration and cumulative frequency of exposure differed across studies, long duration and greater cumulative frequency of night work suggest an overall increased risk of prostate cancer incidence, but with inconsistent dose-response patterns across studies. Five high-and moderate-utility studies and one low-utility study examined cumulative duration of shift or night work and risk of prostate cancer; the longest duration of night shift work reported by each study is presented in Figure 4-2. The studies varied in their categorization of shift work duration, with four studies involving subjects engaged in 20 or more years of night work. Five high- and moderate-utility studies reported increased risk of prostate cancer for the highest duration category, though only the estimates reported by Parent et al. (2012), Behrens et al. (2017), and Papantoniou et al. (2015b) were statistically significant. Two studies (Papantoniou et al. 2015b, Behrens et al. 2017) reported a significant exposure-response trend of prostate cancer incidence by duration of night work whereas no clear exposure-duration response patterns were observed with the other studies (Conlon et al. 2007, Parent et al. 2012, Wendeu-Foyet et al. 2018). The low-utility prospective study reported null associations across all durations (Åkerstedt et al. 2017). Although Hammer et al. (2015) did not evaluate lifetime duration of shift work per se, the study found an increased risk of prostate cancer in chemical workers with increasing duration of employment who worked 30 years or more at the company (unreported hazard ratios).

Two studies provide evidence that other measures of persistent night shift work are related to increased prostate cancer risk. Papantoniou et al. (2015b) observed an increased risk of prostate cancer among those working rotating nights with the highest cumulative exposure (≥ 2,857 rotating night shifts; odds ratio [OR] = 1.32, 95% CI = 0.99 to 1.77). Wendeu-Foyet et al. (2018) did not see an association with prostate cancer and cumulative frequency of lifetime night shifts for overall, permanent, or rotating night shift work; however, a positive association was observed with combined exposure metrics. A significantly elevated risk of prostate cancer was seen, however, in all participants working ≥ 30 years and either ≥ 6 consecutive nights (OR = 1.71, 95% CI = 1.06 to 2.76), or greater than 10 hours shift length (OR = 2.49, 95% CI = 1.11 to 5.61), and in participants working greater than 10 hours shift length and either at least 1,314 cumulative nights (OR = 1.76, 95% CI = 1.03 to 3.03) or ≥ 6 consecutive nights (OR = 1.86, 95% CI = 1.05 to 3.27). These associations generally strengthened and remained significant when examining permanent night shift workers only. Wendeu-Foyet et al. (2018) found a significantly decreased risk of prostate cancer for shift lengths less than 8 hours (OR = 0.32, 95% CI = 0.16 to 0.34) and a significantly increased risk with greater than 10 hours shift length (OR = 1.88, 95% CI = 1.08 to 3.26). No relationship was found when examining direction or speed of shift rotation, or timing of night shift (i.e., early morning, late evening, and overnight shifts).

Although most studies examined rotating night shift work, three studies (Kubo et al. 2006, Papantoniou et al. 2015b, Wendeu-Foyet et al. 2018) examined rotating and fixed (permanent) night shift work separately. Generally, there were no major differences in risk of prostate cancer between rotating and permanent night shift work in the three studies. Wendeu-Foyet et al. (2018) also did not find an increased risk when examining direction and speed of shift rotation.

Figure 4-2 Forest plot of human studies on the risk of prostate cancer by longest cumulative duration of night work

The figure depicts a forest plot of the risk of prostate cancer and the longest cumulative duration of night shift work. Five of the 6 studies reported elevated risks ranging from 1.22 to 3.06, with 3 being statistically significant.

Note: Plotted confidence intervals (CI) are standardized and estimated based on software package, and therefore may differ slightly from study confidence intervals.

#### Effect modification or outcome subtype

##### Prostate cancer severity

There is some evidence that night shift work is associated with more severe prostate cancer; however, this is limited to only three studies that examined prostate cancer severity and night work. Papantoniou et al. (2015b) found a statistically significant positive association between night work and high-risk prostate tumors (according to the D’Amico classification) (relative risk ratio [RR] = 1.40, 95% CI = 1.05 to 1.86), particularly among men working rotating nights for the longest duration (≥ 28 years; RR = 1.63, 95% CI = 1.08 to 2.45; P_trend_ = 0.027), and for those working the highest cumulative frequency of night shifts (≥ 2,857 shifts; RR = 1.78, 95% CI = 1.17 to 2.69; P_trend_ = 0.007). Men with a history of night work and Gleason score > 7 at diagnosis had a higher risk (RR = 1.43, 95% CI = 0.99 to 2.07), compared to those with a lower Gleason score (< 7; RR = 1.09, 95% CI = 0.85 to 1.38). Wendeu-Foyet et al. (2018) also found a borderline significant positive association between permanent, but not rotating, night work and aggressive prostate cancer (with Gleason scores 7+) (OR = 1.41, 95% CI = 0.98 to 2.04). Elevated risk of aggressive prostate cancer was significantly associated with working ≥ 20 years of permanent shifts (OR = 1.76, 95% CI = 1.13 to 2.75; P_trend_ = 0.003), ≥ 6 consecutive permanent nights (OR = 1.87, 95% CI = 1.13 to 3.11), > 10 hours permanent shift length (OR = 2.63, 95% CI = 1.23 to 5.63; P_trend_ = 0.04), and combined metrics of persistent permanent shift work.

In contrast, Hammer et al. (2015) found little evidence that the risk of prostate cancer differs by severity; however, risk estimates were imprecise, there were few exposed cases with advanced prostate cancer (T4), and this was a null study for all metrics. This study was conducted in a relatively young cohort of German chemical workers, and the detection of prostate cancer may be higher in this particular cohort considering screening was more frequent.

##### Chronotype, preferred midpoint of sleep

Although both chronotype and diurnal preference (measured by preferred midpoint of sleep) were examined in three studies, they do not substantially modify the association between shift work and risk of prostate cancer. The effect of chronotype on the risk of prostate cancer in night workers was evaluated in the Papantoniou et al. (2015b) and Wendeu-Foyet et al. (2018) studies, with all studies reporting elevated risks for evening chronotype. However, the Spanish study (Papantoniou et al. 2015b) also found that morning chronotype had an increasing risk with long-term exposure (≥ 28 years) (OR = 1.79, 95% CI = 1.16 to 2.76; P_trend_ = 0.017).

Behrens et al. (2017) reported that earlier sleep preference was associated with significantly higher risk of prostate cancer when compared to intermediate and late sleepers. Stratified analysis by vitamin D status did not reveal differences in risk of prostate cancer.

#### Chance, bias, and confounding

Study findings were unlikely to be explained by unmeasured confounding, although because there are no known causes of prostate cancer, there is always potential for unknown causes to confound results. However, positive associations were observed across different geographical locations or racial groups, populations, and study designs, which help to decrease concerns from unknown confounders. Potential confounders for prostate cancer and shift work studies included age and occupational exposures, which were generally controlled for in statistical analyses. NTP thought that body mass index (BMI) could be the causal pathway of shift work and cancer, and therefore, was not included as a key confounder in the study quality assessment (e.g., consider it as some concern); however, NTP did note that BMI was controlled for in a few studies (Kubo et al. 2006, Kubo et al. 2011, Parent et al. 2012, Åkerstedt et al. 2017). Results from Åkerstedt et al. (2017) and Kubo et al. (2006) remained null and positive, respectively, after controlling for BMI. Kubo et al. (2011) saw an increased relative risk after controlling for BMI, but results remained non-significant. Parent et al. (2012) did not report unadjusted estimates, but a significantly increased risk of prostate cancer was present after controlling for BMI. No studies evaluating aggressive prostate cancer controlled for BMI, a potential risk factor. A few studies found significant differences in levels of physical activity by shift work status, which may be a result of decreased access to outdoor activities and greater sedentary duties in night workers. Controlling for physical activity, a potential but not established risk factor associated with shift work but not prostate cancer, was only considered in two studies (Parent et al. 2012, Papantoniou et al. 2015b), both of which found a positive association with prostate cancer. There is a greater likelihood that findings were biased due to exposure misclassification (primarily non-differential). Lifetime exposure to nighttime shift work was not fully captured in many studies measuring ever versus never exposure, and thus, there is a possibility that unexposed comparator groups had worked nights. The potential for exposure misclassification of unexposed participants would therefore attenuate risk estimates toward the null.

None of the occupational cohort studies controlled for frequency of prostate cancer screening. As mentioned earlier, the use of regular prostate cancer screening in certain occupational studies, including the use of more sensitive tests such as PSA, may increase the likelihood of disease detection. If day shift workers are more likely to be screened than night shift workers due to availability, then differential outcome misclassification may bias results.

## 4.2 Colorectal cancer

In 2017, an estimated 135,430 new colon and rectum cancer cases were predicted in the United States. Colorectal cancer is the second leading cause of cancer-related death in the United States (Howlader et al. 2017). There is a moderate chance of surviving five years after colorectal cancer diagnosis (64.9%, 2007 to 2013 age-adjusted SEER data). Based on SEER age-adjusted data from 2009 to 2013, about three-quarters (74%) of cases are diagnosed at the localized (39%) or regional stage (35%). The remaining fourth of cases are diagnosed at the distant stage or are unstaged and have much lower survival rates (13.9%, and 35.4%, respectively). Studies that rely on mortality data to represent incident colorectal cancer may not be capturing most incident cancers unless latency is sufficiently long or the cancer stage is aggressive.

### 4.2.1 Overview of study methods and characteristics

Five independent cohort studies of colorectal cancer (Schwartzbaum et al. 2007, Yong et al. 2014a, Jørgensen et al. 2017, Papantoniou et al. 2018, [Nurses’ Health Study (NHS)]) were available for review, as well as three population-based studies (Parent et al. 2012, Papantoniou et al. 2017, Walasa et al. 2018). Study populations measuring shift work were from North America (United States, Canada), Europe (Sweden, Denmark, Germany, Spain), and Australia. Two cohort studies used the NHS cohort to examine shift work exposure and either colorectal cancer incidence (Papantoniou et al. 2018) or mortality (Gu et al. 2015; NHS cohort only), so the study populations were likely to have overlapped. In this current review, only Papantoniou et al. (2018) was included and Gu et al. (2015) served as supplementary information (Table 4-4). Another previous NHS study (Schernhammer et al. 2003) has been superseded by the combined NHS/NHS2 study by Papantoniou et al. (2018), which contains a longer follow-up period. Similarly, two retrospective cohort studies used the cohort of German chemical workers to examine colorectal cancer incidence (Yong et al. 2014a) or mortality (Yong et al. 2014b). In this current review, only incident colorectal cancer was included (Yong et al. 2014a), and mortality information from Yong et al. (2014b) served as supplementary information (Table 4-4). Most studies combined colon and rectal cancers, with Parent et al. (2012), Schwartzbaum et al. (2007), Walasa et al. (2018), Papantoniou et al. (2017) and Papantoniou et al. (2018) examining colon and rectal cancers together and/or separately. Studies of men, women, and both men and women were included.

Table 4-4 Studies of colorectal cancer and night work

Reference | Population | Outcome and source(s) | Exposure assessment and information
Cohort studies
Papantoniou et al. 2018; (Gu et al. 2015, supporting study) | Nurses’ Health Study (NHS) and NHS2 cohorts; NHS: 1976 (enrolled), 1988 (exposure collection), 1988–2012 (follow-up); NHS2: 1989 (enrolled), 1989–2013 (follow-up); NHS: 77,349 women; NHS2: 113,371 women | Incident colon and rectum cancers; Self-report, next of kin, postal service, death registry | Self-administered questionnaire; Night work: undefined time for ≥ 3 rotating night shift/mo; Metrics: Ever worked rotating night shifts (≥ 1 yr), duration of rotating night work; for NHS2, both baseline and follow-up cumulative duration
Schwartzbaum et al. 2007 | Swedish workers, registry-based cohort; See Table 4-1; 1,148,661 female shift workers | Incident colon and rectum and other cancers. (See Table 4-1) | See Table 4-1
Yong et al. 2014a; (Yong et al. 2014b, supporting study) | German Rhineland-Palatinate chemical workers retrospective cohort; 1995–2005 (employment records); 2000–2009 (follow-up); 27,828 male production workers (specific chemical company) | Incident cancers; colon and rectum and other cancers; Rhineland-Palatinate Cancer Registry | Company records; Night work: forward rotating system with: one 12-hr shift (6:00 AM–6:00 PM), 24 hr off, 12-hr shift (6:00 PM–6:00 AM), and another 48 hr off); Metric: ever worked
Jørgensen et al. 2017 | Danish Nurses Organization study; 1993 and 1999 (recruitment); 2012 (end of follow-up); 28,731 working nurses (population based) | Fatal colorectal and other cancers; Underlying cause of death; Danish Register of Causes of Death using underlying cause of death | Self-administered questionnaire; Night work: fixed nights (11:00 PM–7:00 AM); rotating shifts include day (7:00 AM–3:00 PM) and evening (3:00 PM–midnight); Metrics: current type of shift work (fixed nights or rotating shifts)
Case-control studies
Parent et al. 2012 | Montreal multisite case-control cancer study; See Table 4-1; 400 male cases; 512 male population controls | Incident, histologically confirmed colon, rectal, and other cancers (see Table 4-1) | See Table 4-1
Papantoniou et al. 2017 | MCC-Spain population-based case-control study; 23 hospitals in 12 regions; 2008–2013 (enrolled); 1,626 cases; 3,378 controls; men and women | Histologically confirmed colon and rectal cancers, including anatomical and histological stage; Medical records | In-person interviews with questionnaire; Night work: 1+ hour between midnight & 6:00 AM for ≥ 3 nights/mo; Exposed: Worked night shifts ≥ 1 yr (at least 1 hour from midnight–6:00 AM for ≥ 3 nights/mo); Metrics: Ever worked shifts (≥ 1 yr), type of shift, cumulative duration, age at first shift work, shift work ≤ 15 yr or ≥ 15 yr in the past
Walasa et al. 2018 | Western Australia population-based case-control study; 2005–2007 (enrolled); 350 cases; 410 controls; women only | Incident, histologically confirmed colorectal cancer; Western Australian Cancer Registry | Job exposure matrix (JEM); Night work: any work between midnight & 5:00 AM; Metrics: ever worked in occupation-industry combinations with ≥ 70% of participants as shift workers, cumulative duration, and exposure to LAN and phase shift

mo = month; yr = year.

### 4.2.2 Evaluation of study quality

A detailed evaluation of study quality for all potential biases is available in Appendix E, Table E-1 and an overview of the assessment is provided in Table 4-5. It should be noted that the breast cancer section (Section 3) evaluated Schwartzbaum et al. (2007), Jørgensen et al. (2017), and the study design of Papantoniou et al. (2017), and the prostate cancer section (Section 4.1) also evaluated Parent et al. (2012) and the study design of Yong et al. (2014a) (in Hammer et al. 2015); therefore, detailed discussions have been excluded in this section except for overall study utility and study findings in Appendix E, Table E-2. Similar to the breast cancer evaluation, Schwartzbaum et al. (2007) and Jørgensen et al. (2017) were ultimately excluded from the hazard evaluation due to poor exposure assessment.

Table 4-5 Summary of study quality: Shift work and colorectal cancer

Citation | Selection^a^ | Exposure | Outcome | Confounding | Analysis | Selective reporting | Sensitivity | Utility^b^
Cohort studies
Papantoniou et al. 2018 | ++ | ++ | +++ | +++ | +++ | +++ | +++ | +++
Schwartzbaum et al. 2007 | ++ | 0 | +++ | + | ++ | +++ | + | 0
Yong et al. 2014a | ++ | + | ++ | + | +++ | +++ | + | +
Jørgensen et al. 2017 | + | 0 | ++ | +++ | ++ | +++ | + | 0
Case-control studies
Parent et al. 2012 | +++ | ++ | +++ | ++ | +++ | +++ | ++ | ++
Papantoniou et al. 2017 | ++ | ++ | +++ | ++ | +++ | +++ | ++ | ++
Walasa et al. 2018 | ++ | + | +++ | ++ | +++ | +++ | ++ | +

a Levels of concern for bias and for study sensitivity (columns for Selection through Sensitivity). Key: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

b Utility of the study to inform the hazard evaluation. Key: +++ = high utility; ++ = moderate utility; + = low utility; 0 = inadequate utility.

#### Selection bias

Some (Schwartzbaum et al. 2007, Yong et al. 2014a, Papantoniou et al. 2017, Papantoniou et al. 2018, Walasa et al. 2018) or major concerns (Jørgensen et al. 2017) of selection bias are due to lack of accounting for healthy worker survivor effect and low response rates. Additionally, selection bias can be an issue for both younger and older populations. Younger cohorts with an inadequate latency period may not have been engaged in shift work long enough to see an effect. For the NHS/NHS2 combined study, NTP evaluated both the combined NHS and NHS2 cohorts to allow for the examination of how left truncation may operate (similar to Section 3). There was some concern of selection bias for the NHS cohort given the potential for left truncation, and minimal concern for the NHS2 cohort.

#### Exposure misclassification

There were serious or critical concerns regarding exposure misclassification in four studies. Jørgensen et al. (2017) limited their assessment of night and rotating shift work to current job and thus was assessed as having a critical concern for exposure misclassification. Critical concern due to exposure misclassification issues with the JEM in Schwartzbaum et al. (2007) is explained in greater detail in Section 4.1. Walasa et al. (2018) also used a JEM that characterized shift work at an aggregate level; however, the JEM was considered to be stronger than that of Schwartzbaum et al. (2007), given it was based on detailed information of lifetime occupational history. In the combined NHS/NHS2 study (Papantoniou et al. 2018), exposure misclassification is likely, given the survey question only asked for rotating, but not fixed, night shift work. The younger NHS2 cohort is less likely to be subject to exposure misclassification due to post-baseline follow-up questionnaires on shift-work status.

#### Outcome misclassification

The use of mortality data to approximate incidence of colorectal cancer in the supporting NHS study (Gu et al. 2015) and in Jørgensen et al. (2017) can result in a significant loss of cancer cases depending on survival and subsequent loss of power, and an underestimation of the risk estimate based on the high survival rate for this cancer.

#### Sensitivity

Schwartzbaum et al. (2007), Yong et al. (2014a), and Jørgensen et al. (2017) had low study sensitivity due to little or no information on duration or other metrics of shift work exposure. Other studies had moderate or high study sensitivity. Compared to the older NHS cohort, the younger NHS2 cohort had a lower number of exposed cases who worked shifts 15 or more years, and did not have information on tumor anatomical site.

#### Overall study utility

The study of the U.S.-based NHS and NHS2 cohorts (Papantoniou et al. 2018) and case-control studies in Canada (Parent et al. 2012) and Spain (Papantoniou et al. 2017) were considered to be informative for the evaluation (high or moderate utility). The NHS/NHS2 combined study (Papantoniou et al. 2018) was considered as one study in the overall utility because it allows NTP to evaluate how left truncation may operate (similar to Section 3) and any differences in risk based on age entering the cohort. A German-based occupational cohort study (Yong et al. 2014a) and an Australian case-control study (Walasa et al. 2018) both were considered to be of low study utility because they had poor classification of shift-work exposure, did not adequately account for smoking, and/or had poor sensitivity. A cohort of Danish nurses (Jørgensen et al. 2017) and a linkage study of the Swedish population (Schwartzbaum et al. 2007) were also determined to have inadequate utility based on critical concerns of exposure misclassification, and thus were not included in the hazard assessment.

### 4.2.3 Colorectal cancer hazard assessment

Findings for all the individual studies included in the analysis are available in Appendix E, Table E-2 and selected findings are graphed in the forest plots below.

As stated in Section 3.2.5, NTP did not consider the meta-analysis approach informative and thus did not include its own meta-analysis nor include the published meta-analyses in the cancer hazard assessment. One meta-analysis by Wang et al. (2015b) found significantly increased risk of colorectal cancer with ever exposure to night work, and a significant increase in risk for every 5 years duration of shift work. The utility of this analysis was limited by the inclusion of studies with insufficient or poorly characterized exposure to shift work or irrelevant outcomes of interest.

#### Consistency of the evidence across studies

Overall, the evidence for an association between rotating night shift work and colorectal cancer is unclear and is limited by a small number of informative studies (see Table 4-6). Two moderate-utility studies offer evidence (moderate to strong or some evidence) of an association based on significantly increased risks of colon, rectal, and colorectal cancers (Parent et al. 2012, Papantoniou et al. 2017). The Nurses’ Health Study, which was considered to be a high-utility study, found evidence of an association with rectal but not colon or combined colorectal cancer in the older but not the younger NHS cohort (Papantoniou et al. 2018). Moreover, a positive exposure-response relationship by increasing duration of shift work was found for colorectal and for rectal cancers (Papantoniou et al. 2017, Papantoniou et al. 2018). A low-utility study by Yong et al. (2014a) found a non-significantly increased association of colorectal cancer with having ever worked rotating night shift work in both internal and external analyses, suggesting that there is some evidence of an association. In the supporting mortality study by Yong et al. (2014b), shift work was not associated with colorectal cancer mortality. Lastly, a low-utility case-control study (Walasa et al. 2018) reported inconclusive results, with a null association of colon and colorectal cancers, and a non-significantly increased association with rectal cancer.

Table 4-6 Evidence summary table for studies of shift work and colon and rectal cancers

Reference | Study utility | Study design | Key metric measured in study
Reference | Study utility | Study design | Ever worked | Years worked | Cancer type | Gender
Strong evidence or some evidence of colorectal cancer risk
Parent et al. 2012 | +++/++ | Case-control | *** | ** | C, R | M, F
Papantoniou et al. 2017 | +++/++ | Case-control | *** | *** | CRC | F
Papantoniou et al. 2018 | +++/++ | Cohort | | ** | C, R, CRC | M, F
Yong et al. 2014a | + | Cohort | * | | CRC | M
Inconclusive evidence
Walasa et al. 2018 | + | Case-control | Null | * | C, R, CRC | F

+++/++ = informative (dark yellow); + = low utility (light yellow); strength of association increases with number of * and darker shade of blue for key metric measured in study; C = colon; CRC = colorectal cancer; F = female; M = male; R = rectum.

Issues relevant to the cancer hazard assessment include exposure metric, cancer sites (i.e., colon, rectum, or colon and rectum combined), and potential effect modifiers such as smoking status, body weight, and gender-specific differences.

#### Metrics of exposure

One study only examined ever exposure (Yong et al. 2014a), four studies reported on shift work duration (Parent et al. 2012, Papantoniou et al. 2017, Papantoniou et al. 2018, Walasa et al. 2018), and one study reported on type of shift (Papantoniou et al. 2017).

The main issues that may explain the observed heterogeneity across the studies include (a) the exposure metrics used and (b) the timing of night work.

##### Ever night work

Overall, the most informative studies suggest an increased risk of colorectal cancer associated with ever working night shifts (Figure 4-3). Papantoniou et al. (2017) reported statistically significant elevated risks for colorectal cancer among those working rotating shifts, but not fixed night shifts. Parent et al. (2012) saw a similar magnitude of risk of colon and rectal cancer in men who were ever employed in night work. Among the low-utility studies, internal analysis by Yong et al. (2014a) revealed an increased risk of incident colorectal cancer in rotating shift workers, although the association was not statistically significant. The study was limited by incomplete exposure history data. Walasa et al. (2018) reported null results in women for colorectal cancer and when stratifying by colon cancer, but did find a non-significantly increased risk of rectal cancer for ever having worked graveyard shifts (0.1+ months). The NHS/NHS2 study did not report on ever exposure.

Figure 4-3 Forest plot of human studies on the risk of colon, rectal, and colorectal (CRC) cancers from ever exposure to night work; stratified by study utility

The figure depicts a forest plot of the risk of colon, rectal, and colorectal cancers and ever exposure to night shift work by study utility. No high utility studies were reported; and of the 3 moderate utility studies, all reported statistically significant elevated risk estimates ranging from 1.22 to 2.10. One of the 2 low utility studies one reported a nonsignificant excess risk, while the other estimate was close to unity.

Note: Plotted confidence intervals (CI) are standardized and estimated based on software package, and therefore, may differ slightly from study confidence intervals. CRC = colorectal cancer.

##### Exposure duration

The three high- or moderate-utility studies also stratified by lifetime duration of night work exposure (Figure 4-4). In both the NHS and NHS2 cohorts, there were no significant exposure-response relationships with increasing exposure duration in women with colorectal or colon cancers. In the older NHS cohort, however, Papantoniou et al. (2018) found a significant positive trend with increasing duration in women with rectal cancer (P_trend_ = 0.02) and non-significant elevated risks for colorectal cancer for women working 20 to 29 years (RR = 1.26, 95% CI = 0.96 to 1.65) and 30+ years (RR = 1.17, 95% CI = 0.84 to 1.63). For the younger NHS2 cohort, only a moderate non-significant increase in colorectal cancer (CRC) risk was seen in nurses working 10 to 14 years (RR = 1.15, 95% CI = 0.73 to 1.81); however, this estimate was attenuated with the incorporation of an updated shift work history. In contrast, prior analysis of the same NHS cohort by Schernhammer et al. (2003) showed a significant positive trend of an elevated risk for colorectal cancer with increasing duration of rotating shift work; however, Schernhammer et al. (2003) analyzed the same cohort with 14 years less follow-up data. Considering the NHS cohort is an older population, the additional years of follow-up may have captured retirement years long after shift work was done, thereby diluting the effect with the added years of latency. The supporting NHS mortality study by Gu et al. (2015) found a borderline non-significant positive trend with increasing duration (P_trend_ = 0.07). For NHS2, only 15 CRC cases had 15+ years of shift-work history, and therefore, the study may have suffered from insufficient power.

Parent et al. (2012) did not report a positive exposure-response relationship; estimates exceeding 2.0 were reported for men working < 5 years for both colon and rectum cancer, as well as colon cancer among men working ≥ 10 years. Walasa et al. (2018) saw no increased risk of colorectal and colon cancers with increasing duration of graveyard shift or phase shift work; however, non-significantly elevated risk of rectal cancer was seen with both shorter (< 7.5 years) and longer durations (7.5+ years) of graveyard shifts. Similar results were seen with duration of phase shift exposure.

Figure 4-4 Forest plot of human studies on the risk of colon, rectal, and colorectal cancer and longest lifetime duration of shift work exposure; stratified by cancer type

The figure depicts a forest plot of the risk of colon, rectal, and colorectal cancers and the longest lifetime duration of shift work exposure by cancer site. Only one of the 3 colon cancer studies reported a statistically significant excess risk based on at least 10 years of exposure; all of the rectal cancer studies reported elevated risks, but only the estimate based on night work for at least 15 years was statistically significant. Finally, only the risk of colorectal cancer among individuals working nights at least 35 years was elevated and statistically significant.

Note: Plotted confidence intervals (CI) are standardized and estimated based on software package and, therefore, may differ slightly from study confidence intervals.

#### Type of cancer and effect modification

Differences in the magnitude of cancer risk were found after stratifying by cancer site (i.e., colon, rectum, colon and rectum), suggesting shift work may differentially impact rectal cancer. Walasa et al. (2018) did find elevated estimates for rectal but not colon cancer in women, but no estimates were significant. When stratifying by colon and rectal cancers, Papantoniou et al. (2018) found a significant risk and positive trend of rectal cancer in NHS cohort nurses working 15+ years of shift work (RR = 1.60, 95% CI = 1.09 to 2.34; P_trend_ = 0.02), but not in combined proximal and distal colon cancers. When examining colon cancer by tumor anatomical site, an increased non-significant risk of distal colon cancer, but not proximal colon cancer, was seen (RR = 1.27, 95% CI = 0.87 to 1.85).

Examining the association between shift work exposure and risk of colorectal cancer by gender (i.e., male, female, both) revealed conflicting results. The only study examining men and women (Papantoniou et al. 2017) showed significantly increased risk for colorectal cancer in men (OR = 1.32, 95% CI = 1.10 to 1.59), but not in women. Comparing studies of men and women, there were inconsistent results in the magnitude of effect, requiring a further evaluation into the potential for effect modification.

Walasa et al. (2018) did not find a significant increased risk of colorectal cancer with shift work involving phase shifts, LAN exposure, poor diet, insufficient vitamin D, sleep disturbance or physical inactivity. Those considered normal weight in the NHS mortality study (Gu et al. 2015) had a significant increasing trend in risk of colorectal cancer by years of shift work exposure (P_trend_ = 0.02); however, the trend did not remain in overweight and obese individuals. No significant trend was seen by duration of exposure when stratifying risk of colorectal cancer by never, former, and current smoker.

#### Chance, bias, and confounding

Alternative explanations for the evidence in these studies cannot be completely ruled out. Two studies did not control for BMI, red meat consumption, physical activity, and/or alcohol consumption (Yong et al. 2014a, Walasa et al. 2018), suggesting that these studies may suffer from bias. However, Yong et al. (2014a) conducted an internal analysis restricted to production employees to achieve maximum comparability with respect to occupational risk profiles, socioeconomic status, age distribution, and employment duration, which may further control for unmeasured confounding. Additionally, the supporting NHS mortality study by Gu et al. (2015) did not find effect modification by smoking and overweight status. All other studies of colorectal cancer included relevant risk factors in multivariate models, but also included covariates that were either not necessarily related to colorectal cancer or were in the etiologic pathway, potentially over-controlling for confounders and introducing bias towards the null.

## 4.3 Hormonal cancers (ovarian and endometrial)

Female hormonal cancers include ovarian and endometrial cancers. Overall, based on SEER age-adjusted data from 2009 to 2013 (Howlader et al. 2017), the five-year survival rate for ovarian cancer is 46.5%, but two-thirds of cases are diagnosed at the distant stage or are not staged. The 5-year survival rate for these women is much lower (~25% to 29%); for localized ovarian cancer (14.8% of all cases), the 5-year survival rate is 92.5%. Thus, although mortality data may provide useful information, the reliance on mortality data is likely to miss about one-third of cases with longer survival and later death, likely resulting in non-differential misclassification and loss of power. On the other hand, endometrial cancer has a relatively high 5-year survival rate (81.3%, age-adjusted SEER data from 2007 to 2013), and only studies of incidence are relevant.

### 4.3.1 Overview of study methods and characteristics

Four cohort studies (Schwartzbaum et al. 2007, Poole et al. 2011, Carter et al. 2014, Jørgensen et al. 2017) and one population-based study (Bhatti et al. 2013a) of ovarian cancer, and one cohort study of incident endometrial cancer (Viswanathan et al. 2007) were eligible for review (Table 4-7). Study populations were from Sweden, Denmark, and the United States. Four studies were from nurses, with three studies being from the U.S. Nurses’ Health Study. Mortality data from Gu et al. (2015) and incidence data from Poole et al. (2011) were taken from overlapping study populations. Jørgensen et al. (2017) also used ovarian cancer mortality data in Danish nurses. The remaining studies include a hospital-based case-control study, a prospective analysis using the American Cancer Prevention cohort, and a Swedish registry linkage study.

Table 4-7 Studies of hormonal cancer (ovarian cancer and endometrial cancer) and night work

Reference | Population | Outcome and source(s) | Exposure assessment and information
Ovarian cancer
Schwartzbaum et al. 2007 | Swedish workers, registry-based cohort; See Table 4-1 | Incident ovarian cancer and other cancer; See Table 4-1 | See Table 4-1
Poole et al. 2011; United States | U.S. Nurses’ Health Study cohorts (NHS/NHS2); Follow-up; NHS: 1988–2008; NHS2: 1989–2007; 181,548 female nurses | Incident ovarian cancer; Self-report, next of kin, postal service, death registry | Self-administered questionnaires; Night work: undefined time for ≥ 3 rotating nights/mo; Metrics: Ever worked rotating night shifts (≥ 1 yr), duration of rotating night work
Gu et al. 2015 (supporting study) | NHS (1988); Follow-up; 1988–2010; 74,862 female nurses | Fatal ovarian cancer, underlying causes; Next of kin, postal authorities, death registry | Self-administered questionnaires; Night work: undefined time for ≥ 3 rotating nights/mo; Metrics: Ever worked rotating night shifts (≥ 1 yr), duration of rotating night work
Carter et al. 2014 | American Cancer Prevention Study II (CPS) cohort; 1982 (enrollment) to 2010 (follow-up); 161,004 employed women (general population) | Fatal ovarian cancer; Biennial death certificate and automatic linkages with NDI | Self-administered questionnaire; Night work: 9:00 PM–midnight (fixed nights); Metrics: Current rotating shifts or fixed night shifts
Jørgensen et al. 2017 | Danish Nurses Organization study; See Table 4-4 | Fatal ovarian cancer; Underlying cause of death; Danish Register of Causes of Death using underlying cause of death | See Table 4-4
Bhatti et al. 2013a | Western Washington State population-based case-control study; 2002–2009 (enrolled); N = 1,101 invasive epithelial cases and 389 borderline epithelial tumors; 1,832 randomly selected controls | Histologically confirmed epithelial ovarian cancer, including histological, morphological, and tumor stage; Surveillance, Epidemiology, and End Results (SEER) | In-person interviews; Night work: Worked from midnight–4:00 AM; Metrics: Ever worked night shifts (≥ 4 continuous months), cumulative night shift work-years from age 25 to reference date; ever worked in a job with less than half of work days at night, age at diagnosis
Endometrial cancer
Viswanathan et al. 2007 | U.S. Nurses’ Health Study (NHS) cohort; 1976 (enrolled), 1988 (exposure collection), 1988–2010 (follow-up); 74,862 female nurses | Incident endometrial cancer; Self-report, next of kin, postal service, death registry | Self-administered questionnaire; Night work: undefined time for ≥ 3 rotating night shift/mo; Metrics: Ever worked rotating night shifts (≥ 1 yr), duration of rotating night work

mo = month; NDI = National Death Index; yr = year.

### 4.3.2 Evaluation of study quality

A detailed evaluation of study quality for all potential biases is available in Appendix F, Table F-1 and an overview of the assessment is provided in Table 4-8. It should be noted that the breast cancer section (Section 3) evaluated Schwartzbaum et al. (2007), Jørgensen et al. (2017), and the study designs in the NHS studies (Viswanathan et al. 2007, Poole et al. 2011); therefore, detailed discussions have been excluded in this section except for overall study utility and study findings in Appendix F. Similar to the other cancer endpoints evaluated, Schwartzbaum et al. (2007) and Jørgensen et al. (2017) were ultimately excluded from the hazard evaluation due to poor exposure assessment.

Table 4-8 Summary of study quality: Shift work and hormonal cancers

Citation | Selection^a^ | Exposure | Outcome | Confounding | Analysis | Selective reporting | Sensitivity | Utility^b^
Cohort studies
Schwartzbaum et al. 2007 | ++ | 0 | +++ | + | ++ | +++ | + | 0
Viswanathan et al. 2007 | ++ | ++ | +++ | +++ | +++ | +++ | ++ | ++
Poole et al. 2011 | +++ | ++ | +++ | +++ | +++ | +++ | ++ | +++
Carter et al. 2014 | +++ | 0 | ++ | +++ | +++ | +++ | + | 0
Jørgensen et al. 2017 | + | 0 | ++ | +++ | ++ | +++ | + | 0
Case-control study
Bhatti et al. 2013a | +++ | ++ | +++ | +++ | ++ | +++ | ++ | ++

a Levels of concern for bias and for study sensitivity (columns for Selection through Sensitivity). Key: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

b Utility of the study to inform the hazard evaluation. Key: +++ = high utility; ++ = moderate utility; + = low utility; 0 = inadequate utility.

#### Selection bias

Three analyses were conducted within the NHS cohort (Poole et al. 2011, Gu et al. 2015), with Viswanathan et al. (2007) and Gu et al. (2015) examining the original NHS cohort; Poole et al. (2011) included both the older and younger cohorts (NHS and NHS2, respectively). If ovarian and endometrial cancers are related to long-term exposures starting in early life, studies conducted in the older NHS cohort (Viswanathan et al. 2007, Gu et al. 2015) could be biased towards the null as women with cancer from early exposure are not present in the cohort (i.e. healthy-worker survival bias), and the timing of exposure in early adult life is not known. Alternatively, the study by Poole et al. (2011) may not be as susceptible to this bias, as younger women from the NHS2 cohort were included in the study population. Concern was minimal in the other studies evaluated.

#### Exposure misclassification

Some degree of exposure misclassification is likely for all of the ovarian cancer cohort studies (see Section 4.2 for a more detailed discussion of Jørgensen et al. 2017), the NHS cohort study (Poole et al. 2011), and Schwartzbaum et al. 2007). Two of the studies limited exposure assessment only to the current or last job (Carter et al. 2014, Jørgensen et al. 2017), and thus had critical concern for misclassification.

Other issues that may increase the likelihood of exposure misclassification include undefined definitions of night work, and relying on broad questions to determine ever exposure to night work. Explicit timings of night work were defined for three cohorts (Schwartzbaum et al. 2007, Carter et al. 2014, Jørgensen et al. 2017) and one case-control study (Bhatti et al. 2013a). Bhatti et al. (2013a) calculated cumulative work-years by dividing the total number of hours engaged in night work for a particular job by the total number of hours worked in a 40-hour workweek over a year (i.e., 2,080 hours). This method did not allow for distinguishing duration and frequency separately. Considering elevated risks were seen in only some ovarian cancer subtypes but not others, this case-control study is likely to be less susceptible to recall bias.

#### Sensitivity

Due to the limited ability to differentiate levels of exposure, and a potentially less relevant window of exposure, most studies had low to moderate study sensitivity.

#### Overall study utility

For ovarian cancer, the most informative study was the NHS/NHS2 incidence study (Poole et al. 2011) because lifetime shift work history was examined, the study had a varying age range and a large number of exposed cases, and there was minimal concern of potential bias. The analysis of ovarian cancer mortality by Gu et al. (2015) was not considered to be as informative because mortality data is an imprecise proxy for incident ovarian cancer. The Washington State population-based case-control study (Bhatti et al. 2013a) had detailed information on ovarian cancer and subtypes, comprehensive data on night shift schedules, and high participation rates, but lacked detailed exposure information and was considered to have moderate utility for the evaluation. The studies by Schwartzbaum et al. (2007), Jørgensen et al. (2017), and Carter et al. (2014) were excluded from the hazard assessment due to their inadequate exposure assessment and/or sensitivity to detect a true effect.

The NHS study by Viswanathan et al. (2007) was considered to be somewhat informative (moderate utility) for evaluating endometrial cancer, but it was the only study reporting on this outcome.

### 4.3.3 Hormonal cancer hazard assessment

Findings for all the individual studies included in the analysis are available in Appendix F, Table F-2.

The database is inadequate to evaluate the level of evidence from studies of night work and risk of endometrial cancer, as only one study (Viswanathan et al. 2007) is available. This study found a significant association between 20+ years of rotating shift work and endometrial cancer, with a significant exposure-response relationship for duration of shift work. When stratified by BMI, the relationship and trend remained only in women considered obese.

The available data are also inadequate to evaluate the relationship between ovarian cancer and night work because of few informative (moderate- or high-utility) studies of independent populations. The case-control study of ovarian cancer (Bhatti et al. 2013a) provided the strongest evidence of a relationship because of consistent, significantly increased risk for both invasive (OR = 1.24, 95% CI = 1.04 to 1.49) and borderline (OR = 1.48, 95% CI = 1.15 to 1.90) ovarian tumors, three ovarian tumor subtypes (high grade serous, low grade and borderline serous, and invasive/borderline mucinous), and increasing risk in certain durations of night work. The combined NHS and NHS2 cohort study (Poole et al. 2011, based on 718 cases) reported a non-statistically significant elevated risk among women working rotating shifts for 10 to 14 years and 15 to 19 years. No excess risk was found for those working ≥ 20 years. When examining ovarian cancer mortality in the NHS cohort, Gu et al. (2015) found no excess risk of ovarian cancer mortality for women working rotating shifts for any number of years; however, the study population was older than the NHS2 and the analysis was restricted to fatal cases.

## 4.4 Lung cancer

Lung cancer is the leading cause of cancer-related mortality in the United States, with approximately 222,500 incident cases expected to have occurred in 2017 (Howlader et al. 2017). Furthermore, five-year survival rate for lung cancer is 18.1%. Thus, using mortality data to approximate incidence of lung cancer is less likely to result in reduced power or bias than for other cancers.

### 4.4.1 Overview of study methods and characteristics

Three cohort studies of incident lung cancer (Schwartzbaum et al. 2007, Schernhammer et al. 2013, [NHS], Yong et al. 2014a), one nested case-cohort study (Kwon et al. 2015), and one population-based case-control study (Parent et al. 2012) were identified; three cohort studies of fatal lung cancer were also identified (Taylor and Pocock 1972, Gu et al. 2015, Jørgensen et al. 2017) (Table 4-9). Gu et al. (2015) conducted a mortality analysis within the NHS which overlaps with Schernhammer et al. (2013), and therefore will be used in support of the incident lung cancer study. Yong et al. (2014b) conducted a mortality analysis in the same study population as Yong et al. (2014a), and therefore, will be used in support of the incident lung cancer study. Of the five cohort and nested case-cohort studies, two were composed of nurses (Schernhammer et al. 2013, Jørgensen et al. 2017), and three were occupational cohort studies in the textile (Kwon et al. 2015), chemical (Yong et al. 2014a), and manufacturing populations (Taylor and Pocock 1972). The remaining two studies were general population studies of workers (Schwartzbaum et al. 2007, Parent et al. 2012).

Table 4-9 Studies of lung cancer and night work

Reference | Population | Outcome and source(s) | Exposure assessment and information
Cohort studies
Taylor and Pocock 1972 | United Kingdom retrospective cohort of manual workers; Enrolled 1956–1968; 8,603 men (industry-based) | Fatal lung and bronchial cancers; National Death Register (SMR study) | Company payroll records; Night work: 80% worked 3 rotating shifts (rapid and weekly); 20% worked alternate day/night or other shift schedules; Metric: Ever worked shift (≥ 10 years with ≤ 6 mo break)
Schwartzbaum et al. 2007 | Swedish workers, registry-based cohort; See Table 4-1 | Incident lung and other cancers (see Table 4-1) | See Table 4-1
Schernhammer et al. 2013 | US Nurses’ Health Study (NHS); 1976 (enrolled), 1988 (exposure collection); 1988–2008 (follow-up); N = 78,612 women | Incident lung cancer, including histology subtypes; Self-report, next of kin, postal service, death registry | Self-administered questionnaires; Night work: undefined time for ≥ 3 nights/mo in addition to days/evenings in that month; Metrics: Worked rotating night shifts (≥ 1 yr) by duration of rotating night work
Gu et al. 2015 (supporting study) | NHS (1988); Follow-up; 1988–2010; 74,862 female nurses | Fatal lung cancer, underlying causes; Next of kin, postal authorities, death registry
Yong et al. 2014a (Yong et al. 2014b supporting study) | German Rhineland-Palatinate chemical workers retrospective cohort; See Table 4-4 | Incident, lung/bronchial and other cancers (see Table 4-4) | See Table 4-4
Jørgensen et al. 2017 | Danish Nurses Organization study; See Table 4-4 | Fatal ovarian, lung, colorectal cancers; Underlying cause of death; Danish Register of Causes of Death using underlying cause of death | See Table 4-4
Case control and nested case-cohort studies
Parent et al. 2012 | Montreal multisite case-control cancer study; See Table 4-1; 761 male cases; 512 male population controls | Incident, histologically confirmed, lung and other cancers (see Table 4-1) | See Table 4-1
Kwon et al. 2015 | Shanghai Textile Industry Bureau (STIB) nested case-cohort study; Enrolled 1989–1991; 267,400 women textile workers; 1,451 cases;; 3,040 controls | Lung cancer incidence and mortality, ICD-9: 162; Shanghai Cancer Registry (SCR), the death registry of the Shanghai Textile Industry Bureau, medical records | JEM based on factory records; Night work: any continuous hours between midnight & 6:00 AM as part of a rotating shift pattern; Metrics: cumulative duration, cumulative frequency of night shifts

mo = month; SMR = standardized mortality ratio; yr = year.

### 4.4.2 Evaluation of study quality

A detailed evaluation of study quality for all potential bias is available in Appendix G, Table G-1 and an overview of the assessment is provided in Table 4-10.

It should be noted that the breast cancer section (Section 3) also evaluated Schwartzbaum et al. (2007), Jørgensen et al. (2017), Parent et al. (2012), and the older NHS cohort (Schernhammer et al. 2003, Gu et al. 2015); the prostate cancer section (Section 4.1) also evaluated the study population in Yong et al. (2014a). Therefore, detailed discussions have been excluded in this section except for overall study utility and study findings in Appendix G, Table G-2. Similar to the other cancer endpoints evaluated, Schwartzbaum et al. (2007) and Jørgensen et al. (2017) were ultimately excluded from the hazard evaluation due to poor exposure assessment.

#### Selection bias

None of the occupational cohort studies of prevalent surviving workers accounted for left truncation and the HWSE. Among these studies, HWSE was most clear in the Kwon et al. (2015) cohort study which reported that night work required a healthier physical profile for the completion of specific tasks, and the Taylor and Pocock (1972) study which only included men who had worked shifts at least ten years, likely selecting out those with shorter periods of work who may have left for illness related to lung cancer, or had low tolerance for night work.

#### Exposure misclassification

Critical concern for exposure misclassification in the Jørgensen et al. (2017) and Schwartzbaum et al. (2007) studies have been mentioned previously. There are major concerns (Yong et al. 2014a) and some concerns (Taylor and Pocock 1972, Parent et al. 2012, Schernhammer et al. 2013, Kwon et al. 2015) of exposure misclassification in lung cancer studies. This section will only review the studies unique to lung cancer (see Section 4.1 for Parent et al. 2012 and Schwartzbaum et al. 2007, and Section 4.2 for Jørgensen et al. 2017 and Yong et al. 2014a). Exposure assessments based on company records still raised concerns. Shift work exposure based on company records in Taylor and Pocock (1972) were adequately captured but insufficiently characterized. Exposure misclassification is also possible in a Chinese nested case-control study where shift work status was assessed at the factory level and not at the individual level (Kwon et al. 2015)

Definitions of night work varied among lung cancer studies. Among the lung-cancer-specific studies, only Kwon et al. (2015) specified night work as any hours completed between midnight and 6:00 AM. Taylor and Pocock (1972) categorized six rotating work schedules, including rotating and fixed night schedules, together to characterize shift work exposure.

#### Overall study utility

The most informative lung cancer studies were the NHS (Schernhammer et al. 2013, Gu et al. 2015), the Shanghai nested case-control study (Kwon et al. 2015), and the Canadian case-control study (Parent et al. 2012) (see Table 4-10). Two studies provided low study utility based on concerns for bias, primarily exposure misclassification and potential misclassification from smoking, a major risk factor for lung cancer which could be related to shift work status (Taylor and Pocock 1972, Yong et al. 2014a). Based on critical concerns for exposure misclassification, Jørgensen et al. (2017) and Schwartzbaum et al. (2007) were determined to have inadequate study utility and were not included in the hazard assessment.

Table 4-10 Summary of study quality: Shift work and lung cancer

Citation | Selection^a^ | Exposure | Outcome | Confounding | Analysis | Selective reporting | Sensitivity | Utility^b^
Cohort Studies
Taylor and Pocock 1972 | ++ | ++ | +++ | + | + | +++ | + | +
Schwartzbaum et al. 2007 | ++ | 0 | +++ | + | ++ | +++ | + | 0
Schernhammer et al. 2013 | ++ | ++ | +++ | +++ | +++ | +++ | ++ | ++
Yong et al. 2014a | ++ | + | ++ | ++ | +++ | +++ | + | +
Jørgensen et al. 2017 | + | 0 | ++ | +++ | ++ | +++ | + | 0
Case-control Studies
Parent et al. 2012 | +++ | ++ | +++ | +++ | +++ | +++ | ++ | ++
Kwon et al. 2015 | ++ | ++ | ++ | +++ | +++ | +++ | ++ | ++

a Levels of concern for bias and for study sensitivity (columns for Selection through Sensitivity). Key: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

b Utility of the study to inform the hazard evaluation. Key: +++ = high utility; ++ = moderate utility; + = low utility; 0 = inadequate utility.

### 4.4.3 Lung cancer hazard assessment

Findings for all the individual studies included in the analysis are available in Appendix G, Table G-1.

As stated in Section 3.2.5, NTP did not consider the meta-analyses approach informative and thus did not include its own meta-analyses.

#### Consistency of the evidence across studies

Of the literature reviewed, studies with high and moderate utility best informed the relationship between shift work exposure and risk of lung cancer (see Table 4-11). Of the three studies with high to moderate utility, a Canadian case-control study (Parent et al. 2012) and the NHS cohort (Schernhammer et al. 2013, Gu et al. 2015) provided evidence of an association between working night shifts and risk of lung cancer.

Table 4-11 Evidence summary table for studies of night work and lung cancer

Study utility or informativeness | Level of evidence | Cohort studies | Case-control, nested case-cohort studies
Moderate or high: 3 studies | Moderate to strong evidence: 2 studies | Schernhammer et al. 2003 (Gu et al. 2015) | Parent et al. 2012
| Null: 1 study | – | Kwon et al. 2015
Low: 2 studies | Null: 1 study | Yong et al. 2014a | –
| Inconclusive: 1 study | Taylor and Pocock 1972 | –

Issues relevant to the cancer assessment include exposure metrics and potential effect modifiers, such as cancer sites and gender-specific differences.

#### Exposure metrics

Ever night work: Findings for ever exposure and the risk of lung cancer were inconsistent across the four studies reported on this metric. The moderate-utility Canadian case-control study (Parent et al. 2012) reported significantly elevated risks of lung cancer associated with having ever worked night shifts. Among the studies with low utility, one study reported a nonsignificantly elevated risk of lung cancer (Taylor and Pocock 1972, Schwartzbaum et al. 2007); however, the study did not control for smoking and thus the evidence was considered inconclusive. Yong et al. (2014a) did not find an elevated risk of lung cancer in shift workers. Similarly, after adjustment for cigarette smoking, the supporting mortality study by Yong et al. (2014b) did not find an elevated risk of lung cancer in shift workers.

Longest duration: Four analyses of three study populations reported on shift work duration and lung cancer risk. Among the most informative studies, an excess risk of lung cancer incidence and mortality was found in the NHS/NHS2 studies. Gu et al. (2015) reported those working ≥ 15 years had a significantly increased risk of lung cancer mortality (HR = 1.25, 95% CI = 1.05 to 1.51). Schernhammer et al. (2013) reported an overall 28% excess risk of incident lung cancer among women working rotating shifts for ≥ 15 years compared to women with no shift work history (HR = 1.28, 95% CI = 1.07 to 1.53). Both NHS studies (Schernhammer et al. 2013, Gu et al. 2015) reported significant trends in exposure-response estimates for the risk of lung cancer among women working rotating shifts. However, there did not appear to be a consistent dose-response relationship across studies (Figure 4-6). Kwon et al. (2015) and Parent et al. (2012) did not find a significant trend with increasing duration of shift work, with Parent et al. (2012) finding the lowest shift work duration (6 months to < 5 years of shift work) had the highest risk of lung cancer incidence. Kwon et al. (2015) did not find an elevated risk of lung cancer when examining cumulative frequency of shift work (i.e., lifetime number of night shifts worked).

#### Effect modification and cancer subtype

Results from some of these studies suggest the risk of lung cancer due to shift work occurs primarily among smokers. In the NHS/NHS2 studies, shift workers who were smokers at the time of being interviewed had significantly elevated risks of lung cancer (Schernhammer et al. 2013, Gu et al. 2015). Furthermore, significant exposure-response trends were seen with increasing duration of shift-work years. Among never smokers, the risk was lower and did not reach statistical significance. There was no effect among former smokers. Based on NTP calculations of reported results by Kwon et al. (2015), there was a non-significant increased risk of lung cancer among ever smokers in the highest duration of night work (OR = 1.20, 95% CI = 0.60 to 2.39; 36 cases), whereas no association was found in the total population. There did not appear to be a consistent trend across duration of shift work by ever smokers.

Two studies examining subtypes of lung cancer suggest shift work increases one’s risk of squamous-cell and small-cell carcinoma of the lung (Parent et al. 2012, Schernhammer et al. 2013).

#### Chance, bias, and confounding

Alternative explanations for the evidence in these studies cannot be completely ruled out. Given the risk of lung cancer in shift workers was occurring primarily among smokers, there is a potential for residual confounding from smoking. While most studies had low concern of potential confounding bias given they accounted for likely confounders, one study (Taylor and Pocock 1972) did not control for smoking or potential confounding from co-exposures in the occupational cohort. Considering Parent et al. (2012) found elevated risks of multiple cancer types, including lung cancer, among night workers compared to study controls, there is a possibility of selection bias. To determine the representativeness of the sample, the study population was compared to the overall Canadian population, and both its occupational distribution and proportion of shift workers were similar.

## 4.5 Other types of cancers and night shift work

In addition to the five cancers (Sections 3 & 4.1 to 4.4), studies have examined the relationship between night shift work and other cancers. Although the database was deemed inadequate for a full evaluation, this section will briefly summarize the results from studies on night work exposure and skin tumors, lymphohematopoietic cancers, stomach cancer, and pancreatic cancer.

### 4.5.1 Skin tumors

Four studies, including three cohorts (Schernhammer et al. 2011, Yong et al. 2014a, Heckman et al. 2017) and one case-control study (Parent et al. 2012) reported on incident cases of malignant melanoma with exposure to shift work. Two studies reported a significantly decreased risk of malignant melanoma among rotating workers (Schernhammer et al. 2011, Yong et al. 2014a), while the other two studies found null or non-significantly increased associations in overall estimates (Parent et al. 2012, Heckman et al. 2017). Additionally, both NHS studies (Schernhammer et al. 2011, Heckman et al. 2017) also reported a significantly decreased risk of basal-cell carcinoma in relation to working shift rotations. Schernhammer et al. (2011) also found a significant downward trend of squamous-cell carcinoma among shift workers by increasing duration.

### 4.5.2 Lymphohematopoietic cancers

Three studies (two case-control and one cohort study) of incident leukemia in relation to shift work were available (Yong et al. 2014a, Costas et al. 2016, Talibov et al. 2018). Studies reported significantly increased risks of leukemia (Yong et al. 2014a) and chronic lymphocytic leukemia (Costas et al. 2016) among rotating shift workers. In addition, two studies of fatal leukemia in relation to shift work were examined (Taylor and Pocock 1972, Gu et al. 2015). In the population-based case-control study from Finland, Sweden, and Iceland (Talibov et al. 2018), a borderline non-significantly increased risk of leukemia (OR = 1.07, 95% CI = 0.99 to 1.16) and acute myeloid leukemia (OR = 1.15, 95% CI = 0.97 to 1.36) was seen in individuals with > 20 years of cumulative night work. Only the NHS mortality study (Taylor and Pocock 1972, Gu et al. 2015) found non-significantly increased risks of leukemia-related mortality among the longest rotating shift work durations.

The risk of non-Hodgkin lymphoma (NHL) in relation to shift work was reported in three cohort studies (Lahti et al. 2008, Carreón et al. 2014, Yong et al. 2014a) and two case-control studies (Parent et al. 2012, Talibov et al. 2018). Elevated risks of NHL were reported by Yong et al. (2014b) and Lahti et al. (2008). Lahti et al. (2008) found night-time work significantly increased the risk of NHL in men with the highest exposure (RR = 1.28, 95% CI = 1.03 to 1.59). In the chemical plant worker cohort study by Carreón et al. (2014), shift work did not increase risk of NHL mortality (standardized relative risk [SRR] = 0.69, 95% CI = 0.18 to 2.69). Talibov et al. (2018) did not see a significantly increased risk of other lymphohematopoietic cancers with night work.

### 4.5.3 Stomach and pancreatic cancer

Four studies of incident stomach cancer (two cohort and two case-control studies) were based on almost 600 exposed cases. In the two case-control studies (Parent et al. 2012, Gyarmati et al. 2016), risks for ever working nights were slightly elevated, but were not statistically significant (OR = 1.10, 95% CI = 0.80 to 1.40; OR = 1.34, 95% CI = 0.85 to 2.10, respectively). The two cohort studies reported a statistically significant elevated risk (Taylor and Pocock 1972) or non-statistically significant elevated risk for ever having worked night shifts (Yong et al. 2014a).

One study of incident pancreatic cancer reported on the risk of shift work among 221 exposed cases (Parent et al. 2012), and three mortality studies reported on the risk of shift work for 286 exposed deaths (Lin et al. 2013, Gu et al. 2015, Jørgensen et al. 2017). Only the case-control study of incident pancreatic cancer (Parent et al. 2012) reported a statistically significant elevated risk of ever working nights based on 70 exposed cases (OR = 2.27, 95% CI = 1.24 to 4.15); with those having worked nights within the past 20 years having a statistically elevated risk of cancer (OR = 3.81, 95% CI = 1.75 to 8.28). Risks did not increase with increasing duration, but were non-statistically significantly elevated in those working 5 to 10 and 10+ years. All other studies showed no elevation in risk of pancreatic cancer.

## 4.6 Other exposures and cancer

Two studies examined LAN exposure and risk of other cancers (Kloog et al. 2009, Garcia-Saenz et al. 2018). Kloog et al. (2009) found a positive correlation between incidence rates of prostate cancer, but not lung or colon cancers, with aggregate-level exposure to LAN. Garcia-Saenz et al. (2018) evaluated the risk of prostate cancer and exposure to both indoor and outdoor LAN in a Spanish case-control study. The study found an increased risk of prostate cancer with the highest exposure to both indoor LAN (OR = 2.79, 95% CI = 1.55 to 5.04) and outdoor blue LAN (OR = 2.05, 95% CI = 1.38 to 3.03). Although this was a well-conducted study (see evaluation in Section 3), it was the only study that met the inclusion criteria, as Kloog was an ecological study, and thus a formal cancer hazard evaluation was not conducted. Only one study was identified that evaluated transmeridian travel: a cancer registry study of Scandinavian flight attendants and cancer incidence (Pukkala et al. 2012). The study found increased incidence of multiple cancers in airline crew workers, compared to national estimates; however, no increased risk in any cancers was seen in the nested case-control sub-analysis.

Three studies were identified that evaluated position in a time zone and cancer risk. Circadian misalignment may be more severe in the western part of a time zone because people living in the western part of a time zone have greater light exposure later in the day compared to people living in the eastern part of a time zone. Gu et al. (2017) reported a positive association between moving from east to west in a time zone and county-level incidence rates for chronic lymphocytic leukemia in men and women; cancers of the stomach, liver, prostate, and non-Hodgkin lymphoma in men; and cancers of the esophagus, colorectum, lung, breast, and corpus uteri in women. A prospective analysis of over 56,000 liver cancer cases occurring in the United States between 2000 and 2014 also found that risk of liver cancer increased moving east to west after controlling, at a county level, for lifestyle factors, shift work, demographic, and environmental factors (VoPham et al. 2018). An early study conducted in 59 regions in Russia found that both latitude and position in a time zone were predictors of total cancer incidence and mortality; risk for most cancers increased with increasing latitude of residence and from the eastern to western border of the time zone. With respect to different cancer types, position in a time zone was the best predictor for breast and brain cancer incidence and mortality (Borisenkov 2011).

## 4.7 NTP level of evidence conclusion

There is limited evidence for prostate carcinogenicity of night shift work from human cancer epidemiology studies. Higher quality studies showed significant positive relationships, particularly with persistent night shift work, which includes increased risk of prostate cancer in those working nights for longer duration of exposure, a combination of duration, cumulative frequency, and length of the shift, or a significant positive trend of prostate cancer with night work duration. Despite the results, poor characterizations of night work exposure in many studies hindered the comparability across studies. Furthermore, only a few studies examined prostate cancer severity.

The available database was inadequate to evaluate the carcinogenicity of night shift work for other types of cancer (colorectal, female hormonal, and lung cancers) from human cancer epidemiology studies. The database was limited by the potential for exposure misclassification and limited number of informative studies. The relevant data on night work and lung cancer suggests the potential for confounding bias due to smoking status may be impacting results.