# 3 Human Female Breast Cancer Studies

## Introduction

The cancer hazard evaluation of electric lighting focused primarily on two exposure scenarios involving electric lighting practices that may cause circadian disruption: (1) night shift work, including permanent night shifts or rotating night and day shifts, and (2) exposure to LAN, such as indoor light in the sleeping area or outdoor environmental lighting. Also evaluated were studies of travel across time zones (transmeridian travel), which can cause circadian disruption as well. All three of these scenarios were evaluated with respect to the risk of breast cancer, the major tissue site of interest. Studies of the relationship between night shift work and cancer at other tissue sites are described in Section 4.

Details of the procedures (such as databases and literature search terms and screening methods) used to identify and select the primary studies and supporting literature for the evaluation of human female breast cancer (hereinafter referred to as “breast cancer”) in relation to these exposure scenarios are provided in Appendix A (literature search strings) and the RoC protocol (NTP 2018). Primary epidemiology studies were considered for the cancer evaluation if the study (1) was peer reviewed, (2) provided risk estimates (or sufficient information to calculate risk estimates) specifically for night work, exposure to indoor or outdoor environmental LAN, or transmeridian flights, and (3) provided exposure-specific analyses for night work, indoor or outdoor environmental LAN, or transmeridian flights at an individual level. Studies of workers that provided job title alone and no further specification of shifts worked (e.g., nurses) were not included. Outdoor LAN studies had to provide individual-level exposure (address-linked exposure data) and outcome data. Flight studies were chosen based upon whether they provided risk estimates for proxy measures of circadian disruption, such as numbers of transatlantic flights or computed numbers of time zones crossed.

This section begins with a brief overview of the epidemiology of breast cancer (Section 3.1) and a discussion of the key issues regarding each exposure scenario. Sections 3.2 through 3.4 assess the available epidemiologic literature for night work, light at night, and transmeridian travel in relation to breast cancer. Each of these sections begins with a discussion of the key issues to be addressed in the evaluation for that exposure scenario.

- Overview of the study methods and characteristics
- Evaluation of study quality
- Breast cancer hazard assessment: Synthesis of the evidence across studies

Section 3.5 concludes with NTP’s preliminary level of evidence conclusion.

## 3.1 Overview of breast cancer epidemiology

Breast cancer rates have been rising in the United States since 1975, when rates were 103 per 100,000 women. In the past 10 years rates increased by 0.3% per year and in 2018, the age-adjusted annual breast cancer rate was reported to be 126/100,000 women (SEER 2018 data for 2011 to 2015). Now, female breast cancer is the most common cancer in the United States, and accounts for 15% of all new U.S. cancer cases. The mortality rate is lower — 20.9/100,000 women — than the incidence rate and the five-year survival rate is 89.7%. Rates in U.S. young women vary according to race and ethnicity, with black women under the age of 35 having twice the incidence of invasive breast cancer and three times the breast cancer mortality of young white women (Shavers et al. 2003, Anders et al. 2009).

Incidence rates in European countries, where most of the cohort studies were conducted, were somewhat lower (IARC 2012), and mortality rates were similar. For example, in the European Union, breast cancer incidence per 100,000 women was 106.6, and mortality was 22.4.

Early-onset breast cancer and postmenopausal breast cancer differ with respect to risk factors and types of tumors. Breast tissue may be more susceptible to environmental exposures before the first full-term pregnancy or at younger ages; one explanation is that full-term pregnancy causes terminal differentiation of many cells, thereby reducing the number of stem cells at risk for malignant transformation (Institute of Medicine 2012).

## 3.2 Night shift work

None of the shift-work studies measured circadian disruption directly; however, certain working practices such as working night shifts for longer durations or more frequency may be surrogates for night work related to circadian disruption. Another issue to consider was the age at which women started night shift work as timing of exposure during susceptible hormonal stages has been shown to be important in breast cancer etiology. In general, the adequacy to evaluate different surrogates was reflected in the ratings of study utility and was systematically considered in the assessments of the evidence from the individual studies and across studies. Other key issues that were systematically evaluated were potential effect modifiers, such as chronotype (individual sleep-propensity rhythm). In addition, the type of breast cancer as defined by receptor status (e.g., positive or negative estrogen receptor [ER], progesterone receptor [PR], human epidermal growth factor receptor 2 [HER2]) was evaluated.

Twenty-six studies of breast cancer and shift work in independent populations satisfying the inclusion criteria were identified. These included twelve independent cohort studies (Jørgensen et al. 2017, Vistisen et al. 2017, Wegrzyn et al. 2017 [two separate cohorts using somewhat similar methods — NHS and NHS2], Travis et al. 2016 [three separate cohorts — U.K. Biobank, Epic Oxford, and Million Women], Schwartzbaum et al. 2007, Pronk et al. 2010, Knutsson et al. 2013, Koppes et al. 2014, Åkerstedt et al. 2015); five nested case-control studies (Tynes et al. 1996, Lie et al. 2011, Hansen and Lassen 2012, Hansen and Stevens 2012, Li et al. 2015); and eight population-based case-control studies (Davis et al. 2001b, Hansen 2001, O’Leary et al. 2006, Pesch et al. 2010, Fritschi et al. 2013, Grundy et al. 2013a, Menegaux et al. 2013, Papantoniou et al. 2015a); and one hospital-based case-control study (Wang et al. 2015a). Gu et al. (2015) reported on breast cancer mortality within the NHS cohort and thus is not counted as a separate study. In addition, a separate analysis pooling recoded data from five of the case-control studies was included in this assessment, as this analysis provided additional information beyond that reported in the individual studies (Cordina-Duverger et al. 2018). Nested case-control studies that were based on data recorded independently in administrative records about individuals who were later classified as cases and controls were grouped with the cohort studies (i.e., Tynes et al. 1996, Li et al. 2015), whereas those that collected data retrospectively from persons with known cancer diagnoses were grouped with the case-control studies (i.e., Lie et al. 2011, Hansen and Lassen 2012, Hansen and Stevens 2012). A pilot case-control study of working at night and breast cancer risk in India was not included in the evaluation because of inadequate reporting of study methods especially for assessment of night shift work (Datta et al. 2014). Studies are listed in Tables 3-1 (cohort studies) and 3-3 (case-control studies) from most recent to oldest publication.

### 3.2.1 Cohort studies and relevant nested case-control

#### Overview of study methods and characteristics

Twelve independent cohort studies of breast cancer and shift work and two nested case-control studies (Tynes et al. 1996, Li et al. 2015) for which data were collected on exposure prior to breast cancer diagnosis (Table 3-1, listed in reverse chronological order) are available for evaluation. The NHS and NHS2 cohorts, though independent, were considered together as one cohort in the quality evaluation, because the methods were similar, although not identical, and because considered together, they allowed analysis by age starting night work as the two cohorts differ by age of participants at baseline. Any differences in the quality assessment for a specific type of bias or sensitivity are noted below. Table 3-1 includes details only from the latest update of a study population or the most comprehensive report on a population, along with citations of related previous publications. Detailed data on study design, methods, and findings were systematically extracted as described in the study protocol. Seven additional publications on these populations were identified that contained relevant analyses or information used in the evaluation.

Table 3-1 Cohort studies of breast cancer and shift work

Reference | Population | Outcome and sources(s) | Exposure assessment and information
Jørgensen et al. 2017 | Danish Nurses Organization; 28,731 currently working nurses; Baseline 1993; members added in 1999; Older age: ≥ 44 yr at baseline | Breast cancer mortality; Danish Register of Causes of Death | Self-administered questionnaire; Metrics: currently working rotating shifts, fixed nights, fixed evenings; 22% worked rotating shifts and 5.4% fixed nights
Vistisen et al. 2017 | Danish Payroll Data Cohort; 55,381 women; 2007–2013 enrolled; Younger age: 39.4/35.5 yr average age total/inception | Breast cancer incidence; receptor status; Danish Cancer Registry | Danish Working Hour payroll data; Metrics: ever/never, timing of night work; Night work: workers with ≥ 1 yr for ≥ 3 hr of work only between midnight and 5:00 AM; 41.3% ever night work
Wegrzyn et al. 2017; preceded by (Schernhammer et al. 2001, Schernhammer et al. 2006b) | U.S. Nurses Health Study Cohorts (NHS and NHS2); 78,516 (NHS) 114,559 (NHS2); Enrolled 1976 (NHS) 1989 (NHS2); Older age: 28% premenopausal (NHS); Younger age: 82% premenopausal (NHS2) | Breast cancer incidence; receptor status; Self-report, proxy, postal system, or National Death Index (NDI), 93% validated with pathology reports | Self-administered mailed questionnaire; Metrics: ever, duration of rotating night work; for NHS2, both baseline and follow-up cumulative duration; Night work: no. years working rotating shifts ≥ 3/mo; 60%/62% ever rotating shifts (NHS/NHS2)
Gu et al. 2015 | Nurses Health Study (NHS); 74,862 nurses, 17 locations; Enrolled 1976, questionnaire in 1988; Older age: 6% premenopausal in 1988 | Breast cancer deaths; Next of kin and postal authorities, NDI; physician review of medical records and death certificates | Self-administered mailed questionnaire; Metrics: ever, duration of rotating night work; Night work: worked rotating shifts ≥ 3/mo; 59% rotating shift work
Travis et al. 2016 | U.K. Million Women Study; 522,246 women (general population); Enrolled 1996–2001; Older age: average 68 yr | Breast cancer incidence; NHS Central Registers incidence or death | Self-administered mailed questionnaire; Metrics: ever/never, duration, recency, latency, and timing of night work; Night work: midnight–6:00 AM, for ≥ 3 nights/mo; 14% ever night work
Travis et al. 2016 | U.K. EPIC Oxford; 22,274 women (general population); Enrolled 1993–1999; Older age: median 58 yr at exposure assessment | Breast cancer incidence; National Health Service (NHS) Central Registers invasive breast cancer incidence or death | Self-administered mailed questionnaire; Metrics: ever/never, duration; Night work: ≥ 1 yr and ≥ 1 night/mo or 12 nights/yr; 14% ever night work
Travis et al. 2016 | U.K. Biobank Study; 251,045 women (general population); Enrolled 2006–2010; Older age: average 51 yr | Breast cancer incidence; NHS Central Registers invasive breast cancer or death | In office touch-screen computerized questionnaire; Metrics: current work at night; usually or always; Night work: midnight–6:00 AM; 3.6% current night work
Åkerstedt et al. 2015 | Swedish Twin Registry Cohort; 13,656 women (general population); Enrolled 1998–2003; Older age: 41–60 yr at enrollment | Breast cancer incidence; Swedish Cancer Registry and Cause of Death Register | Computerized telephone interview; Metrics: ever/never nights, duration of night work; Night work: working hours that meant working nights “at least now and then”; Overall: 25% ever worked nights; 2.4% worked nights ≥ 21 yr
Li et al. 2015 | Shanghai Textile Worker Cohort (nested case-control); 267,400 active and retired textile employees at 551 companies; 1,709 cases, 4,780 controls; Enrolled 1989–1991; Older age: average 53.4 yr | Breast cancer incidence; Factory, occupational and government records, Shanghai Cancer Registry; histologically confirmed by review of pathology reports or tissue slides | Trained interviewers researched company records (80%), interviewed supervisors (12%) or participant (8%); all jobs held in factory/textile industry; Metrics: Frequency/intensity, duration, rotating nights, cumulative frequency; no permanent nights in population; Night work: midnight–5:00 AM; 67% ever nights; 33% ≥ 20 yr; 85% worked only 1–2 jobs during their tenure
Koppes et al. 2014 | Netherlands Labor Force Survey Cohort; 285,723 women (general population); Enrolled 1996–2009; Younger age: 85% < 50 yr | Breast cancer incidence; Hospital admission | Labor force survey data questionnaire and computerized in-person interview; Metrics: for current job, none, occasional, or regular; plus hr/wk worked within “occasional” and “regular” categories; Night work: midnight–6:00 AM for paid jobs held ≥ 12 hours, current job only; 10.4% occasional or regular night work
Knutsson et al. 2013 | Work, Lipids, and Fibrinogen Occupational Cohort; 4,036 women; Enrolled 1992–1995, 1996–1997, 2000–2003; Younger age: 82% premenopausal | Breast cancer incidence; Swedish Cancer Registry and cause of death registry | Self-administered mailed questionnaire; Metrics: ever worked nights ascertained over 3 time periods; Night work: 10:00 PM–6:00 AM or 6:00 PM–6:00 AM on ≥ 1 follow-up questionnaire; 13.6% night shift work
Pronk et al. 2010 | Shanghai Women’s Health Study; 73,049 women (general population); Enrolled 1996–2000; Older age: 26% premenopausal | Breast cancer incidence; Shanghai Cancer Registry and Shanghai vital statistics database | JEM and in-person interview, all jobs held ≥ 1 yr; Metrics: ever/never, frequency/intensity, duration; Self report: ≥ 1 yr night work ≥ 3 nights/mo starting at 10:00 PM; 44% JEM; 26% self-report
Schwartzbaum et al. 2007 | Swedish working women, register-based; 1,148,661 (general population); Working in 1960 and 1970; Younger age: 73% < 50 yr | Breast cancer incidence; Swedish Cancer Registry and Cause of Death Register | JEM for industries considered shift work based on jobs worked ≥ 20 hr/wk held in 1960 and 1970; Metrics: ever worked in occupation-industry combination with 70% shift workers or worked in occupational-industry combo. with ≤ 30% shift workers; 0.06% exposed
Tynes et al. 1996 | Norwegian radio and telegraph operators; 2,616 operators certified to work 1920–1980, working at sea; 50 cases/259 controls; Younger age: 58% < 50 yr | Breast cancer incidence; Norway Cancer Registry | Company records: job histories for each ship NOS; Metrics: duration, intensity; Night work: “frequent presence in the radio room both at night and during the day”; 63.7% ever night; 34% long duration of night work

JEM = job exposure matrix; NDI = National Death Index; NOS = not otherwise specified.

The cohorts were located in the United States, the United Kingdom, Sweden, Denmark, Norway, the Netherlands, and China. Eight studies were drawn from general populations (including seven studies of working women) selected from different geographical locations for the purpose of studying various environmental factors (Schwartzbaum et al. 2007, Pronk et al. 2010, Knutsson et al. 2013, Koppes et al. 2014, Åkerstedt et al. 2015, Travis et al. 2016). Four cohorts consisted of nurses or health professionals: NHS, NHS2 (Gu et al. 2015, Wegrzyn et al. 2017), the Danish nurses cohort (Jørgensen et al. 2017), and the Danish Payroll Data cohort (Vistisen et al. 2017). Other cohorts included members of specific occupations, such as textile workers (Li et al. 2015) and radio and telegraph workers (Tynes et al. 1996).

While the earliest study enrollment began in 1961 (Tynes et al. 1996), women may have reported night work three or more decades earlier, dating this exposure as early as the 1930’s. Typical shift-work schedules have changed considerably over this period (see Section 1). The proportion of the female population exposed to night work varied considerably, from 0.06% (Schwartzbaum et al. 2007) to 67% of women ever working nights (Li et al. 2015); general cohort studies of specific occupations (e.g., Tynes et al. 1996, Pronk et al. 2010, Li et al. 2015) had a higher proportion of night shift workers compared to population-based cohorts or case-control studies.

#### Evaluation of study quality

A detailed evaluation of the quality of the shift work cohort studies is provided in Appendix B, Table B-1. The most important issues bearing on the overall quality of the cohort studies were the potential for selection bias, exposure misclassification, and sensitivity.

##### Selection bias

The potential for selection bias in these studies ranged from low to high, with concerns focused mainly on potential healthy-worker survivor bias, completeness of follow-up, or left-truncation bias. In general, incomplete follow-up, if related to shift work, can introduce bias in either direction; left truncation is likely to bias results towards the null. In studies of shift work, the age range of the population can indicate the severity of survivor bias, with studies having the oldest populations at enrollment being most susceptible. Individuals who can adapt to night work are more likely to stay longer in jobs requiring night work, while those who cannot adapt or who become ill from night work may die, leave employment, or change to day shifts. In many occupations, night work is common early during a career (e.g., nurses) and less common as people continue to work and graduate to day shifts. Gu et al. (2015), reporting on breast cancer and night work in the NHS cohort, indicated that much of the follow-up of the older NHS cohort of surviving nurses was accrued at midlife or around retirement of these nurses; the percentage of nurses working rotating night shifts declined from 40% in their early 20s to less than 5% after age 45, with only very few women (< 2%) starting night shifts at midlife or later.

The age ranges represented in the cohort studies varied, with implications for consideration of left-truncation. The oldest cohorts included primarily postmenopausal women (Pronk et al. 2010, Travis et al. 2016, Wegrzyn et al. 2017 [NHS], Jørgensen et al. 2017) and the youngest cohorts included primarily premenopausal women (Tynes et al. 1996, Knutsson et al. 2013, Koppes et al. 2014, Vistisen et al. 2017, Wegrzyn et al. 2017, [NHS2]. While the older NHS cohort would likely be subject to left-truncation, the younger NHS cohort would not; considered together they highlight issues of how this selection bias can operate. Thus, for this latter reason we considered the studies together. The Shanghai textile workers, not an older cohort per se, could be considered a “survivor cohort,” as the population consisted of a high percentage of ever night workers (67%), with 33% having worked nights for at least 20 years (Li et al. 2015). The remaining populations fell into an intermediate age range. The Vistisen et al. (2017) study of a relatively young population of health professionals likely suffered from left-truncation bias, as well as potentially from other selection biases. Past data on this cohort were not available, so an inception cohort was formed to address the potential magnitude of this bias; however, the latter subcohort was on average 35.5 years of age, suggesting that these women would have worked prior to the specified analytic washout period. Differences in education and parity between the overall and inception cohorts suggested that other selection factors also might have been operating. The Knutsson et al. (2013) study was created from two subcohorts of workers with very low follow-up rates. Insufficient information was presented to determine whether selection factors might have been operating in ways that could have biased the results from this study. In addition, the Knutsson study reported 47% loss to follow-up over three follow-up periods.

##### Exposure misclassification

In general, the potential for bias in exposure assessment was rated by integrating three factors: (1) how night work was initially defined, (2) the quality of the measurements, and (3) whether the study included one or more metrics that could differentiate between the subjects with the more persistent night shift working history from those who had less intense night shift working history. In general, concern was greater about non-differential exposure classification than about differential exposure misclassification, with the bias most likely in the direction of underestimating the risk of breast cancer due to night shift work. The risk of exposure assessment bias was considered to be moderate or low in six studies and high in three studies; in four studies, the exposure assessment was considered to be inadequate.

Definitions of night work. Definitions of “exposed” and “unexposed” varied across the cohort studies making exposure difficult to compare across studies. Based on the conditions in Denmark, where hospital nurses have a tradition of working very regular shifts (7:00 AM to 3:00 PM, 3:00 PM to 11:00 PM, or 11:00 PM to 7:00 AM), Garde et al. (2016) found the most agreement and least potential misclassification among studies by using a definition of night work that specified a minimum number of hours of work during biological night (e.g., between midnight and 5:00 AM) or limited the definition of biological night to a narrow range of hours (e.g., any time between 1:00 AM and 4:00 AM). Half of the cohort studies defined night work using a minimum number of hours during the biological night (Schwartzbaum et al. 2007, Koppes et al. 2014, Li et al. 2015, Travis et al. 2016 [Million Women Study and UK Biobank Cohort], Vistisen et al. 2017), whereas two studies required respondents to provide start and end times for work periods (Pronk et al. 2010, Knutsson et al. 2013). The remaining three studies did not specify which hours in the night were worked (Åkerstedt et al. 2015, Travis et al. 2016 [UK EPIC Oxford], Wegrzyn et al. 2017). Some of the definitions required that the “exposed” women work a minimum number of nights or rotating shifts in a given time period, e.g., at least 3 nights per month in Pronk et al. (2010), Travis et al. (2016), and Wegrzyn et al. 2017) Million Women Study or at least 1 night per month in the Travis et al. (2016) EPIC Oxford Cohort. These differences affected the meaning of the estimates derived from these studies, as women working 3 or more nights per month could be more “exposed” than those working only 1 or more nights per month. In five of the cohort studies reporting a minimum exposure time, at least one year of night work was required for a woman to be considered “exposed.” Three studies (Koppes et al. 2014, Åkerstedt et al. 2015, and the Travis et al. 2016 EPIC Oxford Study) used vague definitions with respect to both the hours worked during night shift and how often night shifts were worked (e.g., “occasionally,” “worked nights at least now and then,” or “regularly”), which would tend to bias the findings towards the null, underestimating the risk of breast cancer.

In studies with large proportions of women ever performing night work, the definition of “unexposed” is important. In particular, most nurses begin their careers working nights, as night shifts are often routinely assigned during training. Therefore, the small numbers of “unexposed” women in studies of nurses might not have been completely unexposed, which would tend to bias the results towards the null. Studies having the highest overall proportion of women ever performing night work or performing night work for many years included Tynes et al. (1996) (radio and telegraph operators, 63.7% exposed), Li et al. (2015) (textile workers, 67% exposed), and Wegzryn et al. (2017) (nurses, 60% exposed in NHS and 62% exposed in NHS2).

Quality of exposure measurements. Correct classification of exposure depends upon having night-work metrics based on information that allows night work to be linked to specific jobs during specific periods of time. Studies based on self-reported lifetime occupational histories or complete individual histories from administrative records were considered the most informative. Self-reported data can be susceptible to non-differential memory bias; questions about job-by-job histories that provide multiple prompts to help respondents remember, however, are superior to those asking more general questions. Furthermore, collection of such complete job-by-job data enables the examination of multiple exposure windows, including the earliest exposures to night work. Two studies reported on the adequacy of memory of shift work, using information from repeated surveys. Knutsson et al. (2013) found, based on an overall question about lifetime night work, that night work was remembered well, whereas shifts without night work were remembered less well among those completing a baseline and two follow-up questionnaires. Travis et al. (2016) reported good agreement among a subset of participants who answered questions about shift work on two occasions, two months apart; 97.5% agreement was reported for ever shift work, and 96.2% agreement for duration of shift work.

Four of the cohort studies assessed exposure with a lifetime history method using questionnaires or interviews, querying all women who worked at least 1 or 3 nights per month (Pronk et al. 2010, Travis et al. 2016 [UK EPIC Oxford and Million Women Study], Wegrzyn et al. 2017). An advantage of the NHS2 cohort compared to the NHS cohort (Wegrzyn et al. 2017) was that rotating night shift was assessed at subsequent follow-up periods in addition to baseline.

Three studies (Koppes et al. 2014, Travis et al. 2016, [UK Biobank Study], Jørgensen et al. 2017) assessed exposure based exclusively on the current job and did not collect data on prior history of shift-work exposure, leading to the possibility that many “unexposed” women had actually been exposed. The exposure assessment for these three studies was considered uninformative, and they were excluded from the overall hazard evaluation.

Although administrative records (used in Tynes et al. 1996, Li et al. 2015, Vistisen et al. 2017) avoid memory bias associated with self-reported data, they are not without problems. In Li et al. (2015), factory-level shift-work information was linked to each study subject’s work history data, but data on lifetime exposure in non-textile industry jobs were not available. In Tynes et al. (1996), the definition of “night work” was vague and did not provide sufficient detail for understanding how exposed and unexposed women differed from one another. Vistisen et al. (2017) based their exposure assessment on a database of complete administrative payroll records; however, the definition of the unexposed “day workers” (at least 3 hours of work between 6:00 AM and 8:00 PM) might have misclassified a small number of women into categories that were not consistent with biological day or night (Kolstad et al. 2017, Stevens 2017).

Three studies used a job exposure matrix (JEM) that classified occupations by percentage of work performed at night or day based on an external survey (Schwartzbaum et al. 2007, Pronk et al. 2010, Koppes et al. 2014). As JEMs used in these studies did not assess exposure on an individual level, but rather used external data sources that estimated night work based primarily on job titles, exposure misclassification was likely introduced. Pronk et al. (2010) also collected data on lifetime history of night work and reported that while the JEM classified 44% of the women as potentially working night shifts, self-reported questionnaire data classified only 26% of women as night workers, suggesting substantial exposure misclassification (overestimation of exposure) by the JEM method. In the national study of working women in Sweden (Schwartzbaum et al. 2007), only 0.06% of women were reported to be night workers, an extremely low estimate in a country with an estimated 10% to 20% female night workers, suggesting that this JEM severely misclassified (underestimated) night work.

Multiple exposure metrics and effect modifiers. Studies that included one or more metrics (e.g., duration, number of night shifts per time period, or timing of exposure) differentiating the most highly exposed from those with inconsequential exposure have the potential to elucidate the type of exposure with the most impact on risk; these studies therefore received higher exposure assessment ratings. Nine of the studies included metrics on the duration of shift work, and two studies reported on number of night shifts per time-period (Pronk et al. 2010, Li et al. 2015). Schwartzbaum et al. (2007) reported night work at two censuses taken ten years apart.

##### Outcome misclassification

Gu et al. (2015) and Jorgensen et al. (2017) were studies of breast cancer mortality. Because breast cancer mortality is relatively low and survival high (as discussed above), it is unlikely to adequately reflect incidence, and such an analysis is likely to miss about 90% of cases having longer survival and later death, likely resulting in loss of statistical power to detect an effect. All other studies included incident breast cancer cases and with one exception had low or moderate risk of bias. Koppes et al. (2014) used hospital admission data which may lead to bias in estimates of incidence given differential access to medical treatment; in addition, their methods did not differentiate between prevalent and incident cases.

##### Potential confounding

As the presence of confounding can be assessed only after consideration of the results, the potential for bias resulting from inadequate inclusion of potential confounders in the analysis was assessed as part of the utility evaluation. The primary potential confounders specified in the protocol included occupational co-exposures, age, socioeconomic status or education, parity or age at first full-term pregnancy, and alcohol use. In the general population studies, occupational co-exposures were likely not of concern, as the numbers of participants across co-exposure categories were likely to be small. In the study of textile workers (Li et al. 2015) magnetic field exposure, which had been identified as a risk factor in a previous analysis of this cohort, was evaluated. Occupational co-exposures, such as ethylene oxide, were not considered in the NHS and NHS2 studies of nurses (Wegrzyn et al. 2017); however, such exposures could bias the effect away from the null if large numbers of nurses were exposed to such carcinogens in the course of their duties, as has been described in studies of exposures among nurses (e.g., EWG 2007). Meal timing was not measured and not controlled in any of the studies.

Another concern was the practice of adding variables to the models that were unrelated to night work or were in the causal pathway — e.g., age at menarche, body mass index (BMI), family history of breast cancer, and benign breast disease (Travis et al. 2017, Wegrzyn et al. 2017) — which could have the effect of biasing estimates towards the null; however, most studies included family history, BMI, and age at menarche in their analysis, with some studies including these in the final models. Studies that did not control for key potential confounding factors that could bias estimates away from the null included Koppes et al. (2014), who did not measure alcohol consumption, measured occupation as a proxy for socioeconomic status and education, and used the number of children in household as a proxy for parity, and Tynes et al. (1996) and Schwartzbaum et al. (2007), neither of which measured relevant potential confounders such as parity and alcohol use.

##### Sensitivity

Sensitivity to detect an effect was generally of major concern in the cohort studies due to a number of issues: (1) small numbers of cases among women with high exposure (level, duration, or number of night shifts per time-period) (Schwartzbaum et al. 2007, Pronk et al. 2010, Knutsson et al. 2013, Åkerstedt et al. 2015, Travis et al. 2016 [EPIC Oxford Study and UK Biobank Study]), (2) inadequate range in exposure levels or duration to allow evaluation of exposure-response relationships (Schwartzbaum et al. 2007, Knutsson et al. 2013, Åkerstedt et al. 2015, Travis et al. 2016), (3) inadequate length of follow-up (Pronk et al. 2010, Åkerstedt et al. 2015, Travis et al. 2016, Vistisen et al. 2017), or (4) older populations with potentially inappropriate windows of exposure (Pronk et al. 2010, Åkerstedt et al. 2015 [NHS], Travis et al. 2016 [Million Women Study]).

Studies with larger numbers of cases in the highest exposure category, and therefore greater sensitivity, included the NHS cohort (Wegrzyn et al. 2017), the Million Women study (Travis et al. 2016), and the Shanghai Women’s Health Study (Pronk et al. 2010). However, lower sensitivity was associated with the studies by Åkerstedt et al. (2015), Pronk et al. (2010), Travis et al. (2016) (all cohorts) and Vistisen et al. (2017) which had short mean follow-up times of 3.1 to 10 years. Only three of the cohorts (Schwartzbaum et al. 2007, Knutsson et al. 2013, Wegrzyn et al. 2017) had longer mean follow-up times (12.4, 19, and 24 years, respectively).

##### Overall utility of the cohort studies

Table 3-2 summarizes the results of the bias and quality evaluation of cohort studies of breast cancer and shift work. Overall, nine of the cohort studies had some utility for the cancer hazard assessment. Wegrzyn et al. (2017) was the most informative cohort study. Including data from the older and younger NHS cohorts (NHS and NHS2), together with the information provided by Gu et al. regarding attrition of older night workers in the NHS cohort, illustrates the bias from left truncation that can arise in older cohorts followed at late ages in studies of shiftwork, a bias that may be present in several of the other cohort studies. Three cohort studies had moderate utility for the evaluation (Knutsson et al. 2013, Li et al. 2015, Vistisen et al. 2017). The remaining six cohort studies had low utility to inform the cancer hazard evaluation, primarily because of limited exposure assessments, potential left-truncation bias due to older age at recruitment, and/or lower sensitivity.

Table 3-2 Summary of bias and quality evaluation: Cohort studies of shift work and breast cancer

Citation | Selection^a^ | Exposure | Outcome | Confounding | Analysis | Selective reporting | Sensitivity | Utility^b^
Vistisen et al. 2017 | + | + | +++ | ++ | +++ | ++ | + | ++
Wegrzyn et al. 2017 (NHS and NHS2) | +++ | ++ | +++ | ++ | +++ | +++ | ++ | +++
Jørgensen et al. 2017 | + | 0 | ++ | ++ | ++ | +++ | + | 0
Travis et al. 2016
Million Women Study | + | ++ | +++ | ++ | ++ | ++ | + | +
Epic Oxford Study | ++ | ++ | +++ | ++ | ++ | + | + | +
UK Biobank Study | + | 0 | +++ | ++ | ++ | + | 0 | 0
Åkerstedt et al. 2015 | ++ | + | +++ | ++ | +++ | +++ | + | +
Li et al. 2015 (nested) | ++ | ++ | +++ | + | +++ | +++ | + | ++
Koppes et al. 2014 | +++ | 0 | + | + | +++ | +++ | 0 | 0
Knutsson et al. 2013 | + | ++ | +++ | +++ | ++ | ++ | ++ | ++
Pronk et al. 2010 | ++ | ++ | +++ | +++ | ++ | ++ | + | +
Schwartzbaum et al. 2007 | ++ | 0 | +++ | + | ++ | +++ | 0 | 0
Tynes et al. 1996 (nested) | +++ | + | +++ | + | ++ | ++ | + | +

a Levels of concern for bias and for study sensitivity (columns for Selection through Sensitivity). Key: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

b Utility of the study to inform the hazard evaluation. Key: +++ = high utility; ++ = moderate utility; + = low utility; 0 = inadequate utility.

The studies by Jørgensen et al. (2017), Koppes et al. (2014), and Travis et al. (2016) (UK Biobank Study) were judged to have inadequate utility based on their exposure assessments, which were limited to the current job, with no prior history of night work exposure. That the cohorts investigated by Jørgensen et al. (2017) and Travis et al. (2016 UK Biobank Study) consisted mostly of older women made the omission of past jobs particularly problematic, as it is likely that many “unexposed” women had previous night work. In addition, the UK Biobank Study (Travis et al. 2016) and Koppes et al. (2014) used very short follow-up times, decreasing the studies’ sensitivity to detect an effect. The study by Schwartzbaum et al. (2007) also was judged to have inadequate utility because of its poor exposure assessment, an underestimate of the proportion of the population exposed, lack of metrics other than night work at two time periods, and inadequate control for confounding. Therefore, these four studies were not included in the full hazard evaluation, which considered only the remaining nine cohort studies.

### 3.2.2 Case-control studies including relevant nested case-control studies

#### Overview of study methods and characteristics

Twelve case-control studies were included in the evaluation: nine case-control studies and three nested case-control studies assessing exposure after diagnosis (Lie et al. 2011, Hansen and Lassen 2012, Hansen and Stevens 2012) (Table 3-3). Most studies were conducted in Europe (Denmark, France, Spain, and Germany), and the rest were conducted in Canada, the United States, Western Australia, and Guangzhou, China. Eight of the twelve studies were general population studies, and one study was hospital based (Wang et al. 2015a). Two studies included only nurses (Lie et al. 2011, [the Norwegian Nurses cohort], Hansen and Stevens 2012 [the Danish Nurses cohort), and one was a study of women in the military (Hansen and Lassen 2012). The numbers of case]s in these studies ranged from 141 (Hansen and Lassen 2012) to 7,035 (Hansen 2001), with most having between 660 and 1,700 cases. The proportion of control subjects working nights ranged from 4.6% (Hansen 2001) to 84.3% (Lie et al. 2011). The ages of the populations varied; the percentages of premenopausal case subjects ranged from 63% (Wang et al. 2015a) to 26% (Pesch et al. 2010) or 33% under the age of 50 (Hansen and Stevens 2012). Cordina-Duverger et al. (2018) pooled the results of five of these case-control studies (Pesch et al. 2010, Fritschi et al. 2013, Grundy et al. 2013a, Menegaux et al. 2013, Papantoniou et al. 2015a). Relevant highlights of the pooled analysis are mentioned in this section.

Table 3-3 Case-control studies of breast cancer and shift work

Reference | Population | Breast cancer incidence source(s) | Exposure assessment and information
Cordina-Duverger et al. 2018 | Pooled analysis of 5 case-control studies; Western Australia (BCEES), Canada (CBCS), France (CECILE), Germany (GENICA), and Spain (MCC-Spain) | Regional cancer registries (Canada, Australia) or major hospitals in study areas (France, Canada, Germany, Spain); Receptor status | In-person interview, all jobs held ≥ 6 mo (≥ 12 mo in Spain); Metrics: ever/never, duration of night work, night shift length, no. shifts/wk, no. night hours/wk, cumulative no. lifetime night shifts, years since last night shift, intensity by duration, intensity by night shift length, intensity by years since last night shift; Night shift: working nights midnight–5:00 AM, and most extreme value for each metric; 11.9% ever nights; 2.2% highest intensity of night work
Papantoniou et al. 2015a | MCC-Spain study; Population-based study; Enrolled 2008–2013; 30% < 50 yr of age; 1,708 cases; 1,778 controls | Catchment-area hospitals; Receptor status | In-person interview, all jobs held ≥ 1 yr; Metrics: ever/never, frequency, duration, rotating, permanent night work; Night shift: ≥ 1 year, midnight–6:00 AM for ≥ 3 times/mo (overnight, late evening [ending after midnight] and early morning [starting before 6:00 AM]); 13.3% ever nights; 5.9% ≥ 15 yr
Wang et al. 2015a | Guangzhou, China; Hospital-based study; Enrolled 2010 and 2012; 63% premenopausal; 661 cases; 714 controls | Consecutively recruited recent cancer cases in two hospitals; Receptor status | In-person interview, ever worked nights ≥ 6 mo ≥ 1 time/wk; Metrics: ever/never; night work + sleep duration + daytime napping; Night shift: ≥ 6 mo ≥ 1 time/wk, midnight–6:00 AM; 37.6% ever nights
Fritschi et al. 2013, Fritschi et al. 2018 | BCEES study; Population-based; Enrolled 2009–2011; 30% premenopausal; 1,202 cases; 1,785 controls | Western Australia Cancer Registry | Mailed questionnaire, and in-person interview for occupational questions, all jobs held ≥ 6 mo; Metrics: ever/never, duration, phase shift; Night shift: ≥ 6 mo, midnight–5:00 AM; 21.3% ever nights among controls; 5.6% 20+ yr
Grundy et al. 2013a | CBCS study; Population based; Enrolled 2005–2010; 35% premenopausal; 1,134 cases; 1,179 controls | Vancouver BC - British Columbia Cancer Registry; Kingston, ON -Breast Assessment Program; Receptor status | Self-administered questionnaire or telephone interview, all jobs ≥ 6 mo; Metrics: duration, % evenings/nights (20%, 40%, 60%, 80%, 100% (permanent night shift work), receptor status; Night shift: jobs with shifts from 11:00 PM–7:00 AM; 34.4% ever nights; 2.5% 30+ yr
Menegaux et al. 2013; Cordina-Duverger et al. 2016 (receptor status) | CECILE study; Population based; Enrolled 2005–2007; 31% < 50 yr of age; 1,232 cases; 1,317 controls | Catchment-area hospitals; Receptor status | In-person interview, all jobs ≥ 1 yr; Metrics: ever/never, frequency/intensity, duration; Night shift: ≥ 6 mo for ≥ 6 hr between 11:00 PM–5:00 AM; 11.2% ever nights; 3.6% ≥ 4+ yr for ≥ 3 nights/wk
Hansen and Lassen 2012 | Danish military workers; Nested case-control study; Occupational cohort; Enrolled 2005–2006; 45%/56% premenopausal (day/night workers) (intermediate age); Cohort = 18,551; 141 cases; 551 controls | Danish Cancer Registry | Self-administered mailed questionnaire, all jobs ≥ 1 yr; Metrics: ever/never, duration, frequency, cumulative exposure.; Night shift: respondents working 5:00 PM–9:00 AM for ≥ 1 yr (rotating and permanent nights); 29.4% ever worked nights; 8.4% worked ≥ 15 yr
Hansen and Stevens 2012 | Danish female nurse study; Nested case-control study; Enrolled 2002–2005; Older age: 33% < 50 yr; Cohort = 58,091; 267 cases; 1,035 controls | Danish Cancer Registry | Telephone interview, all jobs ≥ 1 yr; Metrics: cumulative frequency, duration, rotating, permanent nights; Night shift: respondents working after midnight for 8 hr for ≥ 1 yr (rotating and permanent nights); 77.8% ever nights; 12.5% 20+ yr
Lie et al. 2011; Lie et al. 2013 – receptor status | Norwegian Nurses Study; Nested case-control study; Assembled 2004 for cases diagnosed 1990–2007; Older age: 33% premenopausal; Cohort = 49,402; 699 cases; 895 controls | Norwegian Cancer Registry; Receptor status | Telephone interview, all jobs ≥ 1 yr after graduation; Metrics: duration of any night work; duration of work in hospitals; duration of work in schedules with ≥ 3 consecutive nights/mo, cumulative no. lifetime night shifts, lifetime average no. night shifts/mo; Night shift: respondents working ≥ 1 yr midnight–6:00 AM; 84.3% ever nights
Pesch et al. 2010; Rabstein et al. 2013 – receptor status | GENICA study; Population based; Enrolled 2000–2004; 26% premenopausal; 857 cases; 892 controls | Catchment area hospitals; Receptor status | In-person interview followed by a telephone interview, all jobs ≥ 1 yr; Night shift: ≥ 1 yr full-time work between midnight–5:00 AM; Metrics: ever/never, frequency, duration night work; 7% ever nights among controls; 1.2% 20+ years
O’Leary et al. 2006 | EBCLIS study; Selected general population; Enrolled 1996–1997; 39% premenopausal; 487 cases; 509 controls | First primary, in situ, or invasive breast cancers; Catchment area hospitals | Staff-administered in-home interview, all jobs ≥ 6 mo in past 15 yr; Metrics: ever/never, duration, frequency of nights; Night shift: ≥ 6 mo working nights = 7:00 PM–following morning or afternoon to 2:00 AM during past 15 yr; 9.8% ever nights in 15 yr prior to reference date for controls
Davis et al. 2001b | Seattle, WA, U.S.A.; Population based; Enrolled 1992–1995; 33% premenopausal; 813 cases; 793 controls | Cancer Surveillance System of the Fred Hutchinson Cancer Research Center of Seattle cancer registry | In-person interview, all jobs held ≥ 6 mo; Metrics: frequency, duration of night work, hours per week; Night shift: ≥ 6 mo working 7:00 PM–9:00 AM 10 yr prior to diagnosis; 5% ever worked nights
Hansen 2001 | Danish study of working women; Population based; Registry study conducted prior to 2001; 72% < 60 yr of age; 7,035 cases; 7,035 controls | Danish Cancer Registry | JEM: Record linkage to pension fund records; classification of jobs held ≥ 6 mo based on % night work from separate nationwide survey; Metrics: frequency, duration of night work; Night shift: ≥ 6 mo in trades where ≥ 60% of workers worked at night; Jobs with ≥ 60% night work; - 4.6% for ≥ 6 mo; - 1.4% for ≥ 6 yr

BCEES = Breast Cancer Employment and Environment Study, Australia; CBCS = Canadian Breast Cancer Study, Vancouver BC and Kingston, ON; CECILE Study = Cote d’Or and Ille-et-Vilaine, France; EBCLIS = Electromagnetic Fields and Breast Cancer on Long Island Study; GENICA = German Gene–Environment Interaction and Breast Cancer, Bonn, Germany; MCC-Spain = Multi-Case-Control-Study, Spain.

#### Evaluation of study quality

A detailed description of the quality of the shift work case-control studies is provided in Appendix B, Table B-2. The most important issues bearing on the overall quality of these studies were selection bias, exposure misclassification, and sensitivity.

##### Selection bias

Most studies showed low or moderate potential for selection bias. In three of the four studies with the lowest control participation rates and other methodologic differences that could potentially bias results (Pesch et al. 2010, Fritschi et al. 2013, Grundy et al. 2013a), the authors conducted sensitivity analyses to address these issues and reported no evidence to suggest the presence of selection bias. The O’Leary et al. study raised the most serious concern regarding selection bias. The subset of cases and controls in this study were selected from a larger case-control study based on long-term residential stability, and the low proportion of pre-menopausal women in the night work study (39%) differed from the full set of cases and controls by age, menopausal status, race, parity, education, BMI, and alcohol and hormone replacement therapy use, suggesting that some selection bias may have been introduced. No further information was available to assess bias due to differences in shift work, as these questions were asked during a second interview.

In the nested case-control studies, the healthy worker effect was also likely to have been present and to have biased estimates of effect toward the null if women who did shift work early in their careers and were diagnosed with cancer were not included in the cohort. In the Danish Military workers study (Hansen and Lassen 2012), 66% of case subjects diagnosed in the relevant time period were alive at the time of the interview, and only 40% of all case subjects completed the interview. Hansen and Stevens (2012) reported that data were not available to assess the impact of this loss from the original cohort, but in this study of somewhat older survivors, some selection bias was also likely.

##### Exposure misclassification

As with the cohort studies, the potential for bias in exposure assessment in the case-control studies was rated by (1) how night work was initially defined, (2) the quality of the measurements, and (3) whether the study included metrics that differentiated between subjects with more persistent night shift working history and those who had less intense night shift working history. Again, concern was greater about non-differential classification than differential misclassification, with the bias most likely to underestimate the risk of breast cancer due to shift work. The risk of exposure assessment bias was considered moderate or low in nine studies and high in three studies.

Definitions of night work. As with the cohort studies, the case-control studies of night work varied in their definitions of “exposed” and “unexposed,” with some definitions likely to result in a higher risk of misclassification than others. All the case-control studies except one (Grundy et al. 2013a) required a minimum exposure period, with about half requiring at least six months of night work and the rest requiring at least one year. Six studies defined night work as occurring within a specific time period, reducing the likelihood of misclassification (Pesch et al. 2010, Lie et al. 2011, Hansen and Lassen 2012, Fritschi et al. 2013, Papantoniou et al. 2015a, Wang et al. 2015a). Five studies required respondents to provide start and end times for work periods (Davis et al. 2001b, O’Leary et al. 2006, Hansen and Stevens 2012, Grundy et al. 2013a, Menegaux et al. 2013). Two studies required that the “exposed” women work a minimum number of nights in a given time period (e.g., at least 3 nights per month in Papantoniou et al. 2015a and at least 1 night per week in Wang et al. 2015a). Grundy et al. (2013a) allowed the definition of night work to vary from 20% to 100% of all jobs being spent on evening and/or night shifts, capturing both rotating and permanent (100%) night shift schedules. A more restricted night work variable (11:00 PM to 7:00 AM) was reported on, but in very little detail. That the main analyses included evenings reduced the value of these estimates. Cordina-Duverger et al. (2018) recoded individual-level data on night work from job-by-job detailed histories collected in five of these case-control studies (Pesch et al. 2010, Fritschi et al. 2013, Grundy et al. 2013a, Menegaux et al. 2013, Papantoniou et al. 2015a) to allow a common characterization of exposure to night work during the biological night (midnight to 5:00 AM). This new definition of exposure reduced the proportion of the exposed controls in each study by small amounts (1% to 4%) compared with the usually broader definitions used in the original studies. However, the reduction in the estimate of exposed controls was 17.7% for the Grundy et al. (2013a) study, indicating more serious exposure misclassification.

Quality of exposure measurements. All except one study used self-reported questionnaires or interviews to determine night work using answers to questions on a job-by-job basis. Two studies used different methods. Hansen (2001) used a JEM that classified occupations by percentage of workers likely to perform night work estimated from an external survey. Individuals working in trades in which at least 60% of workers were night workers were considered “exposed,” and those working in trades with fewer than 40% night workers were considered “unexposed.” This study did not collect additional self-reported data to compare with the JEM. While about 20% of females work nights in Denmark, only about 6% of this population was considered exposed by their methods.

Overall, recall bias was not considered to be a major concern in most of the case-control studies. Eight of the twelve studies collected data before 2007, when IARC classified shift work as a probable human carcinogen (IARC 2010), reducing the potential for recall bias, as issues of shift work in relation to cancer were not previously widely publicized. In addition, Hansen and Stevens (2012) and Hansen and Lassen (2012) did not find an association of breast cancer with reported exposure to electromagnetic fields (an exposure with no known association with breast cancer included in the questionnaire to test for recall bias), which suggests that recall bias was unlikely. Three studies collected all data after 2007 (Fritschi et al. 2013, Papantoniou et al. 2015a, Wang et al. 2015a), and one study collected data before and after 2007 (Grundy et al. 2013a); however, these studies did not uniformly report elevated risks of breast cancer among night workers. Lizama et al. (2017) conducted a study using memory prompts and questions about the participant’s belief that shift work causes breast cancer. Depending on the sequence of administration of these questions, they concluded that any observed association between shift work and breast cancer was unlikely to have been influenced by recall bias.

Finally, studies collecting night work histories on a job-by-job basis were less likely to be subject to recall bias than those asking more general questions about lifetime exposure to night work. Härma et al. (2017) used payroll data to evaluate the quality of self-reported shift work questions; they found that questions on “shift work with night shifts” and “permanent night work” showed high sensitivity (96% and 90%) and specificity (92% and 97%), while those asking about “regular day work” showed moderate sensitivity (73%) and high specificity (99%), and “shift work without night shifts” showed low sensitivity (62%) and moderate specificity (87%). The authors concluded that the validity of self-reported assessment of shift work varies among work schedules and is likely to contribute to bias towards the null when the question “shift work without night shifts” is used in the questionnaire.

Multiple exposure metrics. A strength of the case-control study database was that multiple metrics in several studies were evaluated with respect to duration, frequency, and timing of exposure. Some studies conducted more in-depth analysis using metrics such as consecutive nights (Lie et al. 2011), type of shift, and length of night shift (Cordina-Duverger et al. 2018). In addition, several studies reported on combined metrics of duration and frequency to classify those with the most persistent night shift work history (Davis et al. 2001b, Lie et al. 2011, Hansen and Lassen 2012, Hansen and Stevens 2012, Grundy et al. 2013a, Menegaux et al. 2013, Papantoniou et al. 2015a). Only one case-control study limited its exposure assessment to “ever/never” night work (Wang et al. 2015a). Hansen (2001) included an estimate of shift work duration which improved the quality of his exposure assessment, thus this study was retained in the database.

Beyond these metrics, Fritschi et al. (2013, 2018) defined an additional three-level metric, “phase shift.” This variable was based on individual data on shift schedules and the work by Haus and Smolensky (2013) indicating that forward rotations cause less circadian disruption than do backward rotations. Exposure was classified as “high” if the job involved 44 nights forward rotation or 46 nights backward rotation; “medium” with 3 to 4 nights forward or 4 to 6 nights backward rotation; and “low” with 3 nights backward rotation. If night shift was worked for ≥ 4 week block, phase shift was downgraded by one level assuming that peripheral rhythms would synchronize with central rhythms over this time. Fritschi et al. (2018) later incorporated chronotype into this metric, such that “late circadian disruption” occurred if one hour or more of the evening work day was after the start of the woman’s biological night, and “early circadian disruption” occurred if the start of the morning work day was before the end of the woman’s biological night.

##### Potential confounding

The potential for confounding bias across the case-control studies was generally of minimal concern; no study found any substantial difference between adjusted and unadjusted models. Overall, co-exposures were not controlled for, which is generally not an issue in population-based studies, as the numbers of people with similar co-exposures across a variety of jobs are typically small. As with the cohort studies, the practice of adding variables unrelated to night work or in the pathway to breast cancer when they were unrelated to exposure may have had the effect of biasing estimates towards the null (Menegaux et al. 2013). One study did not control for socioeconomic status (Davis et al. 2001b), and in two studies, alcohol use was not controlled for or data on alcohol use were derived from non-individual-level external sources (Hansen 2001, Pesch et al. 2010).

##### Sensitivity

The studies by Hansen and Lassen (2012) and Lie et al. (2011) had the highest ratings for sensitivity to detect an effect. In many studies, the numbers of case subjects working nights for long durations or at high frequencies was low, reducing the potential for these studies to find an effect (O’Leary et al. 2006, Pesch et al. 2010, Grundy et al. 2013a, Papantoniou et al. 2015a). Two case-control studies with older populations (Davis et al. 2001b, O’Leary et al. 2006) elicited exposure information only for the past 15 years prior to diagnosis or 10 prior to the reference date. The older age of these populations along with the restricted exposure period made these studies the least sensitive for finding an effect, particularly one based on long durations of night work at an early age. Although the Cordina-Duverger et al. (2018) pooled analysis was not separately rated for quality, this analysis was more sensitive than the individual studies, in that more cases of night shift work were included, and multiple levels of various exposure metrics across night workers enabled better differentiation of those with persistent night shift work.

##### Overall utility of the case-control studies

Table 3-4 summarizes the results of the bias and quality evaluation of case-control studies of breast cancer and shift work. Overall, a larger number of the case-control studies than the cohort studies were considered to have high or moderate utility for the cancer hazard evaluation. In general, these studies had detailed exposure assessments on lifetime history of shift work and included metrics of duration, intensity, and timing to evaluate persistent practices of night work. In contrast, the cohort studies often had little information on exposure metrics or complete occupational history. Because of their cross-sectional nature and the use of lifetime job histories, the case-control studies mostly avoided the complex issues of selection that plagued cohort studies (e.g., left truncation). Recall was likely to suffer at least from some non-differential misclassification; however, such questions as job-by-job start and stop times and length of employment in each job tend to increase the quality of recall, compared with more general questions about night work, decreasing concern about differential recall bias. Finally, more of the case-control studies were conducted before the 2007 onset of public and media interest in the relationship between shift work and cancer, which may also have lowered the chance of differential recall bias. Three studies (Hansen 2001, O’Leary et al. 2006, Wang et al. 2015a) were judged to have low utility to inform the evaluation because of concerns about exposure assessment and sensitivity to detect an effect. The overall quality of the case-control studies was improved by the inclusion of the pooled analysis using a uniform definition of night work and night work metrics across five studies.

Table 3-4 Summary of study quality evaluation: Case-control studies of shift work and breast cancer

Citation | Selection^a^ | Exposure | Outcome | Confounding | Analysis | Selective reporting | Sensitivity | Utility^b^
Papantoniou et al. 2015a | ++ | +++ | +++ | +++ | +++ | +++ | ++ | +++
Wang et al. 2015a | ++ | + | ++ | ++ | ++ | +++ | + | +
Fritschi et al. 2013 | ++ | +++ | +++ | +++ | +++ | +++ | ++ | +++
Grundy et al. 2013a | +++ | ++ | ++ | +++ | +++ | +++ | ++ | ++
Menegaux et al. 2013 | +++ | ++ | +++ | +++ | +++ | +++ | ++ | +++
Hansen and Lassen 2012 (nested) | ++ | +++ | +++ | +++ | +++ | +++ | +++ | +++
Hansen and Stevens 2012 (nested) | ++ | +++ | +++ | +++ | +++ | +++ | ++ | +++
Lie et al. 2011 (nested) | ++ | ++ | +++ | ++ | +++ | +++ | +++ | ++
Pesch et al. 2010 | +++ | ++ | +++ | ++ | +++ | +++ | + | ++
O’Leary et al. 2006 | ++ | + | +++ | +++ | +++ | +++ | + | +
Davis et al. 2001b | +++ | ++ | +++ | +++ | ++ | ++ | + | ++
Hansen 2001 | +++ | + | +++ | ++ | +++ | +++ | + | +

a Levels of concern for bias and for study sensitivity (columns for Selection through Sensitivity). Key: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

b Utility of the study to inform the hazard evaluation. Key: +++ = high utility; ++ = moderate utility; + = low utility; 0 = inadequate utility.

### 3.2.3 Breast cancer hazard assessment: Night shift work

The goal of the cancer hazard assessment was to determine the level of evidence (sufficient, limited, or inadequate, as defined by the RoC listing criteria) for the relationship between breast cancer risk and night shift work related to circadian disruption.

Findings of all the individual studies included in the shift work analysis are provided in Appendix B, Tables B-3 (cohort studies) and B-4 (case-control studies), and selected findings are shown in forest plots below.

#### Overview of methods

The first step in the cancer hazard assessment was to determine the confidence in the evidence from each study. This step was followed by synthesis of the level of evidence across studies, considering the key issues and the RoC listing criteria to reach a level-of-evidence conclusion. The cancer hazard assessment included consideration of the following factors:

- How consistent is the evidence across studies and what sources of heterogeneity might explain differences in results?
- Key issues: What exposure metrics predict breast cancer risk and/or breast cancer subtype? How does any consideration of latency or recency of exposure in these analyses affect the results? Does chronotype modify the association between night work and breast cancer?
- Can the findings be explained by chance, bias, or confounding?

The level of confidence in the evidence from the individual studies (rated as “evidence,” “some evidence,” “null,” or “inconclusive”) was reached by considering the strength of the association, the potential for specific biases or confounding, the expected directions and distortions of those potential biases or confounding, and the sensitivity of the study to detect an effect. Guidelines for evaluating the confidence of the evidence in each study are as follows:

Moderate to strong evidence: Elevated risk estimates of night shift work found for several analyses of different exposure metrics, exposure-response relationships, or effect modification reported usually in moderate to high utility studies. At least one of the estimates is statistically significant. Low utility studies can provide evidence of an association if the potential for bias is towards the null.

Some evidence: Statistically significant risk estimates found for at least one exposure metric of night shift work or multiple non-statistically significant estimates with at least moderate precision from multiple analyses. The evidence can come from high or moderate utility studies or studies with low utility if the potential for bias is towards the null, or if the study has low sensitivity.

Null: Studies which are considered “null” show effect estimates ≤ 1.0.

Inconclusive: Findings vary; the overall direction of potential biases is unknown; potential confounding may explain the findings; or studies have very low precision and the findings may be due to chance.

NTP did not consider the meta-analysis approach informative and thus did not include its own meta-analysis nor include the published meta-analyses in the cancer hazard assessment. The 2016 NTP Workshop on Shift Work at Night, Artificial Light at Night, and Circadian Disruption noted limitations in the utility of meta-analysis because of significant heterogeneity in definitions of “shift or night work.” For example, some studies defined shift work as working at specific hours, others defined it as working a certain number of rotating days per month or week. Thus, differences in the definitions of shift work across studies result in different meanings for “ever exposed” and for duration of exposure. In addition, breast cancer is a heterogenous disease, which also complicates pooling risk estimates. Finally, most meta-analyses did not conduct study quality evaluations, evaluate young age starting night work, or explore combinations of exposure metrics.

Seven meta-analyses have been published since 2013 (Ijaz et al. 2013, Jia et al. 2013, Kamdar et al. 2013, Wang et al. 2013, He et al. 2015, Lin et al. 2015, Travis et al. 2016), as well as a qualitative review of seven of these (Pahwa et al. 2018). Three of the four analyses found a statistically significant positive risk of breast cancer risk among women ever working night shifts; three of four analyses reported statistically significantly elevated risks for long duration; two of three analyses reported statistically significantly elevated estimates for a fixed number of years (e.g., risk for every 5 years); and both of the analyses reporting on fixed frequency of night shifts and/or cumulative nights reported statistically elevated estimates. Of note, the only meta-analysis finding no excess risk of breast cancer in shift workers (ever or long duration) was the study by Travis et al. (2016), who limited their analysis to cohort studies, which NTP considered to be less informative than the case-control studies.

#### Consistency of the evidence across studies

Overall, there is consistent evidence for a relationship between persistent metrics of night shift work and breast cancer risk across studies (as summarized in Table 3-5).

Of the twenty-one studies considered to have utility for the evaluation, seven provided “moderate to strong evidence,” and ten provided “some evidence” of an association between breast cancer risk and a metric associated with extreme or persistent night work. (Note that the two cohorts of the Nurse’s Health Study were counted as one study because they used similar methods to evaluate cancer risk in cohorts that differ by age at baseline, see Table 3-7). Moreover, consistent findings of increased risk of breast cancer in women exposed to night shift work were found across different occupational groups and different geographical populations.

The available data provide strong evidence that metrics associated with persistent night work — frequent, long-term, and night work starting in early adulthood — best predict risk of breast cancer. Although, in general, no linear exposure-response effects were seen in these data, the women with the highest levels of exposure had the highest risks. Some evidence also supports the hormonal pathway by which shift work is hypothesized to affect breast cancer risk. Statistically significantly elevated risks of breast cancer among night workers with receptor-positive cancer subtypes (e.g., ER+, PR+, or HER2+) were consistently observed, although most studies did not have large enough samples to find significant interaction; and some elevated but not statistically significant risks were also reported for receptor-negative subtypes. The studies that could investigate this risk by menopausal status also found that premenopausal night workers were at the highest risk of breast cancer of these breast cancer subtypes.

Across the four studies that had data to investigate chronotype as a potential effect modifier, chronotype was not clearly related to breast cancer risk. The evidence supporting these conclusions is discussed below.

The database is inadequate to determine the contribution of specific exposures contributing to night shift work – such as LAN, sleep, or meal timing – to the excess risk of breast cancer (see Section 6 for a discussion of sleep and altered meal timing). In these studies, confounding bias was generally of minimal concern. Risk estimates generally were no lower in models fully adjusted for confounding factors than in unadjusted models or models adjusted only for age. In some cases, the risk estimates were elevated in the fully adjusted models.

Table 3-5 Summary of levels of evidence from human studies of night shift work and breast cancer

Reference | Study design | Ever worked | Duration | Frequency/cumulative | Younger age^a^ | Receptor positive
Moderate to strong evidence of a positive association - informative studies
Wegrzyn (NHS2) 2017 | Cohort^b^ | – | ↑↑ | – | Pre | ↑
Davis 2001 | Case-control | ↑ | ↑↑ * | ↑↑* | – | –
Grundy 2013 | Case-control | – | (↑) | ↑↑^c,^* | I | ↑↑
Hansen & Lassen 2012 | Case-control | (↑) | ↑↑ * | ↑↑^c,d,^* | – | –
Hansen & Stevens 2012 | Case-control | ↑↑ | ↑↑ * | ↑↑ | – | –
Lie 2011, 2013 | Case-control | – | – | ↑↑^c,^* | – | ↑↑
Menegaux 2013; Cordina-Duverger 2016 | Case-control | ↑ | (↑) | ↑^c,e^ | YA | ↑↑
Some evidence for a positive association - informative studies
Knutsson 2013 | Cohort | ↑↑ | – | – | YA | –
Fritschi 2013, 2017 | Case-control | ↑^f^ | ↑^g^ | – | YA | –
Papantoniou 2015 | Case-control | (↑) | (↑) | (↑)^d^ | Pre | ↑
Pesch 2010; Rabstein 2013 | Case-control | Null | (↑) | (↑) | YA | I
Some evidence for a positive association - lower utility studies
Akerstedt 2015 | Cohort | Null | ↑ | – | YA | –
UK EPIC Oxford, Travis 2016 | Cohort | Null | ↑^e^ | – | – | –
Million Women, Travis 2016 | Cohort | Null | ↑^e^ | – | – | –
Tynes 1996 | Cohort | – | ↑↑ * | – | YA | –
Hansen 2001 | Case-control | ↑ | ↑ | – | – | –
Wang 2015 | Case-control | ↑ | – | – | Pre | ↑
No evidence of a positive association
Li 2015 | Cohort, informative | – | Null | Null | Null | –
Vistisen 2017 | Cohort, informative | Null | – | – | – | (↑)
Pronk 2010 | Cohort, low utility | Null | Null | Null | Null | –
O’Leary 2006 | Case-control, low utility | ↓ | ↓ | – | – | –

↑↑ = RR ≥ 1.8 and/or highest exposure metric or exposure response; ↑ = RR ≥ 1.2 or not the highest exposure metric; (↑) = RR ≥ 1.2, CI includes 1; ↓ = RR < 1; * = significant exposure response relationship; – = not reported; I = inconclusive; NHS2 = Nurses’ Health Study 2.

Shade of blue indicates the strength of the evidence with darkest color indicating the strongest relationship.

a Analyses based on collective information (including direct and indirect measures of age) suggesting breast cancer risk is higher in women starting work at a younger age (YA), among premenopausal women (Pre).

b Findings specific for the NHS (older cohort) not included in table as the collective findings from the two cohorts were considered as one study.

c Combined analyses of metrics frequency-related measures and duration of work.

d Cumulative number of night shifts.

e ↑ for an intermediate category of duration (e.g., at least 10 years), but not for the longest category of duration.

f Ever exposed to phase shift work.

g ↑ for ≤ 10 years duration category but not for longer duration categories.

#### Metrics of exposure

Several different types of exposure metrics were used in the studies, as summarized in Table 3-6.

Table 3-6 Summary of night shift work exposure metrics and potential effect modifiers

Citation | Ever/never | Duration | Permanent | Follow-up data | Frequency | Receptor status | Menopausal status | Age started | Last worked | Chronotype | Health workers^*^
Case-control studies
Danish Military Workers | X | X | | | X | | | | | X
Danish Female Nurse Cohort | X | X | X | | X | | | | | | X
Norwegian Nurses Cohort^a^ | | | | | X | X | X | | | | X
Fred Hutchinson Cancer Center Study | X | X | | | X
Western Australia Study | X | X | | | | | X | | | X
Canada Study^b^ | | X | | | | X | X | | | | X
Danish Female Workers | X | X
CECILE Study, France^c^ | X | X | | | X | X | X | X
MCC/Spain Study | X | X | X | | X | X | | X | | X
GENICA Study^d^ | X | X | | | X | X | | X | X
EBCLIS study | X | | | | X
Guangzhou, China Study | X | | | | | X
Cohort studies
Danish Payroll Data Cohort | X | | | | | X | | | | | X
Swedish Twin Registry | X | X
WOLF cohort | | | | X | | | | X
Shanghai Textile Worker Cohort | | | | | X | | X
Shanghai Women’s Health Study | X | X | | | X | | | X
Million Women Study | X | X | | X | | | | | X | X | X
Epic Oxford Study | X | X | | | | | | | | X
Norwegian radio and telegraph operators | | X^e^ | | | | | | x
Nurses Health Cohorts | | X | | X | | X | X | X | X | | X

See Tables 3-1 and 3-3 for citations.

EBCLIS = Electromagnetic Fields and Breast Cancer on Long Island Study; WOLF = Work, Lipids, and Fibrinogen.

* Population or subanalysis.

a Reported in two publications: Lie et al. 2011, Lie et al. 2013.

b Grundy et al. reported results by the percentage of all nights worked, but the definition of night work included nights and/or evenings.

c Reported in 3 publications: Menegaux et al. 2013, Truong et al. 2014, Cordina-Duverger et al. 2016.

d Reported in 3 publications: Pesch et al. 2010, Rabstein et al. 2013, Rabstein et al. 2014.

e Age-specific metric only.

#### Ever night work

As mentioned in the discussion of exposure misclassification, the metrics used to measure “night work” varied from study to study, complicating the comparison across studies. “Ever night work,” while used in 10 of the 12 studies, is perhaps the least sensitive metric of night work that may be involved in circadian disruption. Using “ever night work” or “ever phase shift” (Fritschi et al. 2013) as the exposure metric and stratifying by study design, Figure 3-1 shows that eight of ten case-control studies reporting on this metric observed a positive association between breast cancer and ever night work, one study found no relationship (Pesch et al. 2010), and one study reported an inverse association (O’Leary et al. 2006). Fritschi et al. (2013) reported a statistically significant dose-response relationship for phase shift (P = 0.04). In contrast, only one cohort study reported a positive association between breast cancer and ever night work (Knutsson et al. 2013). However, the heterogeneity was largely explained by study quality (Figure 3-2). The four highest-utility studies (Hansen and Lassen 2012, Hansen and Stevens 2012, Fritschi et al. 2013, Menegaux et al. 2013) reported 16% to 80% increased risk of breast cancer among those ever working nights, compared with the seven lowest-utility studies, four of which reported risk estimates close to 1.0 and one reporting an estimate below 1.0. The pooled analysis of five case-control studies (Cordina-Duverger et al. 2018) reported a risk estimate of 1.12 (95% confidence interval [CI] = 1.0 to 1.25) for ever working nights.

Figure 3-1 Breast cancer risk by “ever night work” by study design

*Trend P = 0.04 for phase shift.

+Rotating night shifts without permanent nightwork.

++Rotating night shifts with permanent nightwork.

The figure depicts a forest plot of the risk of breast cancer among women reporting ever night shift work by study design (cohort and case-control studies). Five of the six cohort studies show no relationship between night shift work and breast cancer. The Knutsson study from Sweden, however, reported a risk estimate of 2.01 based on 14 exposed cases. Nine of the ten case-control studies reported significantly increased risks of breast cancer from 22% to almost 180% among women ever working night shifts; the highest risk estimate (Hansen and Stevens, OR = 2.89) was reported for a subset of workers who worked rotating permanent nights. One study (O’Leary et al.) reported a statistically significant decreased risk. Six of the case-control studies reporting a statistically significant increased risk were based on at least 100 exposed cases.

Plotted points are based on calculated estimates (R statistical package) and may differ slightly from published estimates.

Figure 3-2 Breast cancer risk by “ever night work" by study utility

CI = confidence interval.

*Trend P = 0.04 for phase shift.

+Rotating night shifts without permanent nightwork.

++Rotating night shifts with permanent nightwork.

The figure depicts a forest plot of the risk of breast cancer risk among women reporting ever night work by level of study utility, starting with high utility studies and ending with low utility studies. Of the 4 unique high utility studies, 3 reported statistically significant elevated risk estimates ranging from 1.22 to 1.80, with one study reporting a risk of 2.89 among a subset of permanent night workers. Of the 5 moderate utility studies, two reported 60% to 2-fold significantly increased risk estimates among women working night shifts; while five of the seven low utility studies, some with large numbers of exposed cases, reported no risk of breast cancer among night shift workers.

Plotted points are based on calculated estimates (R statistical package) and may differ slightly from published estimates.

#### Duration of working the night shift

Across studies, categories of duration and frequency varied considerably, and some studies included frequency of nights within their definition of night work, thus duration of night work represented a somewhat combined measurement of frequency and duration. In general, the most extensive duration reported by each study tended to be associated with an increased risk of breast cancer. Eleven moderate- and high-utility studies reported on duration of night work, using various categories to classify years of work. Seven studies reported excess risks of 54% to 248% for the longest reported duration of night work, and three of these studies reported statistically significant results for durations of at least 15 years (Hansen and Lassen 2012) or at least 20 years (Hansen and Stevens 2012, Wegrzyn et al. 2017 [NHS2]). Hansen and Lassen reported a significant exposure response trend for duration and breast cancer risk (P = 0.03). Night work for at least 15, 20, or 30 years showed non-statistically significant associations with increased risks of 22% (Papantoniou et al. 2015a), 248% (Pesch et al. 2010), and 68% (Grundy et al. 2013a). Menegaux et al. (2013) and Davis et al. (2001b) reported non-statistically significant excess risks of 54% for at least 4.5 years and 60% for at least 3 years for at least one night per week. Davis also reported a statistically significant continuous exposure-response relationship (P = 0.04) between breast cancer risk and number of years working at least one night shift per week (odds ratio [OR] = 1.13, 95% CI = 1.01 to 1.27). Estimates close to 1.0 were reported for at least 20 years by Fritschi et al. (2013) and at least 27.67 years by Li et al. (2015) (see Figure 3-3).

Figure 3-3 Breast cancer risk by longest reported duration of night work by study utility

CI = confidence interval.

*Trend is P = 0.03.

**Trend is P = 0.04 for continuous duration.

+Travis Million Women study OR refers to total years worked among those who last worked nights within the past 10 years.

++Travis Oxford EPIC study OR was estimated by a fixed-effects model combining the categories of 10–19 years and ≥ 20 years duration (NTP).

+++A combined estimate for duration for all women in the Tynes et al. study was calculated using reported frequencies for women < 50 and ≥ 50 years of age.

The figure depicts a forest plot of the risk of breast cancer by the longest reported duration of night shift work. Studies are separated by utility, starting with high utility studies and ending with low utility studies. Of the 6 high utility studies, 4 studies reported elevated risks of 1.54 to 2.16, with 3 attaining statistical significance; one study reported a significant dose-response trend for increasing duration of night work. Among 5 moderate utility studies, 4 studies reported increased risks and one study reported a significant increasing dose-response trend of 13% for each additional year of night work; 3 of the 7 low utility studies reported statistically significant elevated risk estimates ranging from 1.4 to 1.92.

Plotted points are based on calculated estimates (R statistical package) and may differ slightly from published estimates.

Among studies with low utility, excess risks of 77% were reported for night work duration of at least 21 years (Åkerstedt et al. 2015), 70% for at least 6 years (Hansen 2001), and 92% for at least 3.1 years (Tynes et al. 1996, based on a calculated estimate of the age-specific estimates provided). In the U.K. EPIC Oxford study (Travis et al. 2016) only one exposed case subject had at least 20 years of exposure; combining estimates for 10 to 19 years and at least 20 years resulted in a calculated estimate of 58% increased risk for at least 10 years. The Vistisen et al. (2017) study of payroll workers did not support a short-term effect of night shift work in this young population (about two thirds of whom were aged 50 or younger).

No clear exposure-response pattern for duration was observed in these studies. However, six studies found statistically significant or borderline significant elevated risks of breast cancer in the range of 9% to over twofold for shorter durations of night work (Hansen and Stevens 2012), 1 to 5, 5 to 10, and 10 to 20 years; Grundy et al. (2013a) < 15 years; Papantoniou et al. (2015a) < 5 years; Wegrzyn et al. 2017), NHS < 15 years among women with ≤ 10 years of follow-up; Li et al. (2015) < 15 years among postmenopausal women; and Fritschi et al. (2013) for < 10 years duration of phase shift and graveyard shifts.

#### Frequency or cumulative (lifetime) number of night shifts

Results from nine high- and moderate-utility studies suggested that breast cancer risk was associated with a high frequency (average number of shifts per unit time) or cumulative number of night shifts over a lifetime (Figure 3-4).

Figure 3-4 Breast cancer risk by cumulative (lifetime) # night shifts or frequency

CI = confidence interval.

*Trend is P = 0.02.

**Trend is P = 0.03.

***Trend is P = 0.04.

+Refers to lifetime cumulative number of night shifts.

++Refers to lifetime cumulative number of permanent night shifts only.

The figure depicts a forest plot of the risk of breast cancer by cumulative lifetime numbers of night shifts or frequency of night shifts. Of the 7 studies that reported on cumulative lifetime frequency of night shifts, 2 reported statistically significant estimates ranging from 2.29 to 2.61; two additional studies reported elevated risks of 1.48 and 1.62, with the former estimate among women who worked permanent nights. Of the 4 studies reporting on the average number of nights worked per week or month, one study reported a 6% significantly increased risk for every additional hour worked per week, and a statistically significant increased risk of 2.29 among women working = 5.7 night hours per week. The other three studies reported estimates close to unity for frequent night shifts.

Plotted points are based on calculated estimates (R statistical package) and may differ slightly from published estimates.

Among the six high- or moderate-utility studies reporting on the cumulative (lifetime) number of night shifts, two studies reported statistically significant twofold excess risks among workers with the highest number of cumulative night shifts (Hansen and Lassen 2012, [229%], Hansen and Stevens 2012, [261%]). Hansen and Lassen observed a significant exposure response trend in risk with increasing cumulative night shift work, with an adjusted OR of 2.3 (95% CI = 1.2 to 4.6) in the highest tertile of exposure (P for trend = 0.02). Three studies (Pesch et al. 2010, Lie et al. 2011, Papantoniou et al. 2015a) reported a non-significant excess risk among those with the highest number of lifetime night shifts. Risk estimates (non-significant) less than one were reported from the Li et al. (2015) and the Pronk et al. (2010) study (a low-utility study); neither study found an association with breast cancer and any metric of shift work.

Two high-utility studies reported increased risks of breast cancer for fixed night work or permanent night schedules. Hansen and Stevens (2012) reported threefold excess risks of breast cancer among those ever working “ever fixed nights” in combination with rotating nights; and Papantoniou et al. (2015a) reported that a larger cumulative number of permanent night shifts was associated with a non-significant higher risk of breast cancer.

Among the three high- or moderate-utility studies reporting on the average number of nights or hours per week or month worked, only Davis et al. (2001b) reported a statistically significant exposure-response trend of increasing risk with more hours per week of night work; in this study women working at least 5.7 hours per week had more than a twofold increase in the risk of breast cancer. Also, the risk of breast cancer significantly increased with each additional hour per week (10-year weighted average) of night work (OR = 1.06 for each hour, 95% CI = 1.01 to 1.13). Menegaux et al. (2013) reported the highest intensity (≥ 3 nights per week) with an excess non-statistically significant risk of 14%. Lie et al. reported a non-significantly elevated risk of 20% for working ≥ 4 nights/month.

##### Combined measures of night shift work

Four high- or moderate-utility studies reported measures of duration of shift work combined with different measures of frequency, i.e., percentage of night shifts worked, consecutive nights worked, or average number of night shifts worked per week (Figure 3-5). Risks were elevated for all measures of long duration and frequent night shifts with one exception (Menegaux et al. 2013). Grundy et al. (2013a) reported non-significant doubling of risk among women working 15 to 30 years and ≥ 30 years for 100% evenings or nights; and 2- to 3-fold excess risks among women working ≥ 30 years at 50% or 80% evening/nights (Figure 3-5); however, evenings and night shifts were not differentiated. Lie et al. (2011) found elevated risks of breast cancer among nurses working 5 to 7 consecutive night shifts for at least 5 years. Hansen and Lassen reported a statistically significant doubling of risk for women with at least three night shifts per week for ≥ 15 years (P_trend_ = 0.02). Menegaux et al. (2013) reported a statistically significant elevated risk of breast cancer in women working < 3 nights per week for ≥ 4.5 years (OR = 2.1, 95% CI = 1.26 to 3.45), but not for ≥ 3 nights among per week for ≥ 4.5 years.

Figure 3-5 Breast cancer risk by percentage of all shifts worked, average consecutive number of shifts or average number of night shifts per week and duration of shift work (yrs)

CI = confidence interval.

*Trend is P = 0.02.

The figure depicts a forest plot of the risk of breast cancer by combined frequency and duration of night work. Statsitically significant elevated risks of 220% to 371% for women working 50% and 80% nights for at least 30 years were reported. Statistically significant risks of 60%-80% were reported among women working 5 to 7 consecutive night shifts for at least 5 years. Among women working at least 3 nights per week for at least 15 years the risk of breast cancer was significantly increased by 251%. Menegaux et al. reported elevated risks among women working fewer than 3 nights per week for at least 4.5 years; but not among women working 3 or more nights per week.

Plotted points are based on calculated estimates (R statistical package) and may differ slightly from published estimates.

#### Timing of exposure

Based on several lines of evidence related to the timing of night work, night work early in life appears to be related to an excess risk of breast cancer. The strongest evidence comes from studies of premenopausal vs. postmenopausal women with long duration of exposure, suggesting that shift work started in early adulthood. This evidence is supported by studies evaluating risk by age at starting work or analyses of younger populations. In addition to age starting work, recency of night work may also be an important determinant of breast cancer risk.

##### Analyses of premenopausal and postmenopausal women

The strongest evidence that breast cancer risk is related to shift work in early life comes from the pooled analysis (Cordina-Duverger et al. 2018) of five case-control studies (Pesch et al. 2010, Fritschi et al. 2013, Grundy et al. 2013a, Menegaux et al. 2013, Papantoniou et al. 2015a) which had the most statistical power to evaluate various metrics of exposure and stratify analyses by menopausal status. This analysis found that risk estimates for all metrics among premenopausal women were higher than among postmenopausal women or all women combined and most were statistically significant. In general, the highest risk of breast cancer occurred among women with persistent night shift work — those working the most nights or most night hours per week, most hours on a night shift, or higher frequency with more recent exposure. Similar elevated risks were observed among women working < 10 years and working ≥ 20 years. Moreover, risks were greater than two-fold among premenopausal women with the most persistent working conditions, that is, those who worked at least 3 nights per week for ≥ 10 years or ≥ 10-hour shifts. Persistent night shift work was not associated with postmenopausal breast cancer regardless of duration of exposure to night work or length of night shift with the possible exception of postmenopausal women working ≥ 3 nights/week within the past two years (see Table 3-7).

Among the individual case-control studies, the Spanish study (Papantoniou et al. 2015a) found a stronger association between breast cancer and night shift work in premenopausal women than in postmenopausal women, whereas increased risks of breast cancer among night workers (for some exposure metrics) were reported among both pre- and post-menopausal women in three other studies (Fritschi et al. 2013, Grundy et al. 2013a, Menegaux et al. 2013); the German study (Pesch et al. 2010) provided analyses of post-menopausal women only. In addition to the fact that the definitions of exposure differed across the individual studies and thus were difficult to compare, they each lacked the statistical power to clearly determine whether risk varied by menopausal status, and thus, detailed analyses of combined exposure metrics were limited.

Further evidence regarding shift work in early life comes from the Nurses’ Health Study. This study measured only one metric, duration of rotating work (defined as working ≥ 3 nights/month), in an older cohort of primarily postmenopausal women (NHS), and a younger cohort of primarily premenopausal women (NHS2). The results of these analyses are summarized in Table 3-7. In the NHS2 cohort a 2-fold statistically significant higher risk of breast cancer was observed among those working ≥ 20 years. However, in analyses stratified by length of follow-up, this effect was seen primarily among participants during the first 10 years of follow-up. In the older NHS cohort, no effect was observed even among those working rotating nights for ≥ 30 years, although a small, non-significant elevated risk was observed during the first 10 years of follow-up. These findings suggest that the effect of rotating work is stronger in younger women working long durations at an early age. In addition, in the NHS2 cohort, while nightwork for at least 20 years was significantly elevated by 116% among women reporting at baseline, the cumulative risk of breast cancer which incorporated follow-up data on shiftwork after the baseline showed only a borderline elevated risk of 40% (reported in Appendix B-3). This reduction may have been due to the addition of women with different patterns of shiftwork accumulated after baseline (e.g., women first starting shift work during later years), and illustrates the higher risk among women reporting shiftwork at early ages.

Table 3-7 Breast cancer risks among women in the NHS studies and pooled analysis of 5 case-control studies

NHS and NHS2 cohorts; Wegrzyn et al. 2017 | | Pooled analysis of 5 studies^a^; Cordina-Duverger et al. 2018
Exposure group | HR (95% CI) | Exposure group | OR (95% CI)
NHS2 (younger) | | Pre-menopausal
Duration (yr)^b^ & follow-up | | ≥ 3 nights/wk and
≥ 20 (all) | 2.15 (1.23–3.73) | ≥ 10 yr | 2.55 (1.03–6.30)
≥ 20 & ≤ 10 yr | 2.35 (1.04–5.31) | ≥ 10-hr shift | 2.15 (1.21–3.84)
| | ≤ 2 yr^c^ | 2.21 (1.30–3.76)
NHS (older) | | Post-menopausal
Duration (yr)^b^ & follow-up | | ≥ 3 nights/wk and
≥ 30 (all) | 0.95 (0.77–1.17) | ≥ 10 yr | 1.00 (0.56–1.77)
≥ 30 & ≤ 10 yr | 1.26 (0.97–1.64) | ≥ 10-hr shift | 0.90 (0.55–1.48)
| | ≤ 2 yr^c^ | 1.58 (0.68–3.64)

CI = confidence interval; HR = hazard ratio; OR = odds ratio.

a Includes Pesch et al. 2010, Fritschi et al. 2013, Grundy et al. 2013a, Menegaux et al. 2013, Papantoniou et al. 2015a.

b Since baseline.

c Last exposure.

The Guangzhou, China hospital-based case-control study by Wang et al. (2015a) provides further evidence based on an overall statistically significant positive relationship between “ever” night shift work and breast cancer risk (OR = 1.34, 95% CI = 1.05 to 1.72) which was due primarily to the effect in premenopausal women (OR = 1.47, 95% CI = 1.07 to 2.01) who made up over 60% of the study population. In contrast, the Shanghai Women’s Health Study (Pronk et al. 2010) which included primarily postmenopausal women reported no effect of night work on breast cancer risk.

##### Analyses related to young age

Increased risk of breast cancer among women working nights at early ages or before the first full-term pregnancy is moderately supported across the six studies reporting on this exposure, particularly in the two studies combining night work at an early age with the longest reported durations (Tynes et al. 1996, Menegaux et al. 2013). Both studies reported doubling of risks among women working ≥ 3 years before the age of 50 (not statistically significant) (Tynes et al. 1996) or for ≥ 4 years before the first full-term pregnancy (statistically significant) (Menegaux et al. 2013). Two of four studies reporting on night work prior to age 30 or first full-term pregnancy reported non-significant 25% increased risk (Papantoniou et al. 2015a) or 50% increased risk (Pesch et al. 2010), but did not report on duration of night work. Because it is common to work nights for short periods of time early in one’s career or during training, when analyses do not consider duration of night employment, many women are included who worked only for very short time periods, potentially diluting the estimates.

Two cohort studies that enrolled younger women found some increases in risk among women working long durations in subanalyses of the populations under the age of 60 compared to the entire population (Akerstedt et al. 2015, Knutsson et al. 2013).

No associations between breast cancer and exposure to night work before the birth of the first child were reported by Fritschi et al. (2013), nor by Wegrzyn et al. (2017), in the NHS2 cohort. Wegrzyn et al. explained that this null result in the NHS2 study might have been due to the exclusion of parous women at baseline (70%) in this analysis, because reported shift work at baseline could not be attributed to either the pre- or post-pregnancy period. Thus, only nulliparous women were included in this analysis, and the relevant time window in this secondary analysis may have been missed. Reporting on a younger cohort, Vistisen et al. (2017) found no evidence of a short-term effect of night work during a very short follow-up period; however, this study was likely biased by left-truncation, which likely biased the estimation of the effect towards the null.

##### Recency of night work

These data suggested that the risk of breast cancer was higher among women with recent night work. Pesch et al. (2010), the Travis et al. (2016) the Million Women Study, and Wegzryn et al. (2017) reported on recency of night work (years since women stopped working nights). In the NHS2 cohort (Wegzryn et al. 2017), a statistically significant interaction was found between rotating shift work and the follow-up time period (P = 0.03). Among women with at least 20 years of rotating shift work, the risk of breast cancer was significantly increased (HR = 2.35, 95% CI = 1.04 to 5.31) in the first 10 years of follow-up, but no association was observed during the second 10 years of follow-up. In the older NHS cohort, a 26% excess non-statistically significant risk was found in the first 10 years of follow-up (HR = 1.26, 95% CI = 0.97 to 1.64), but no association was found during the second ten years of follow-up. In an analysis restricted only to postmenopausal women, Pesch et al. found a 76% non-significant increase in the risk of breast cancer among those currently working night shifts, but a non-significant reduced risk of breast cancer among those with more than 20 years since their last night work. In the Million Women Study (Travis et al. 2016), among women working night shifts within the past 10 years, the risk of breast cancer was significantly increased (RR = 1.41, 95% CI = 1.07 to 1.86) among those working 10 to 19 years; no increase was observed for those working more than 20 years. The pooled analysis of case-control studies (Cordina-Duverger et al. 2018) found a statistically significant 26% excess risk of breast cancer among women whose last shift was within 2 years, but an excess risk of only 7% to 9% for longer times since last night work, with risk declining as time since the last night shift increased (no trend test was reported). This finding may help explain the observed higher risk of breast cancer in premenopausal compared to postmenopausal women, as mostly younger, premenopausal women work night shifts and older postmenopausal women work day shifts.

##### Type of tumor

Six high- or moderate-utility studies reported on effect modification by breast-cancer receptor status (Grundy et al. 2013a, Lie et al. 2013, Papantoniou et al. 2015a, Wang et al. 2015a, Vistisen et al. 2017, Wegrzyn et al. 2017, Cordina-Duverger et al. 2018), along with one low-utility study (Rabstein et al. 2013). Results across the studies, except for the low-utility study, consistently found significantly elevated risks of receptor-positive breast cancer subtypes (e.g., ER+, PR+, or HER2+) (Figure 3-6). The risk of HER2+ was elevated in two studies that investigated it (Vistisen et al. 2017, Cordina-Duverger et al. 2018), and the risk of HER2–subtypes also was elevated in Wang et al. (2015a). No study had large enough samples to detect significant interactions. The studies that could investigate risk by menopausal status (Papantoniou et al. 2015a, Cordina-Duverger et al. 2016) also found that premenopausal night workers were at highest risk of positive receptor subtypes of breast cancer, supporting the hormonal pathway by which shift work is hypothesized to affect breast cancer risk (Figure 3-7). In the pooled analysis (Cordina-Duverger et al. 2018), premenopausal women who had ever worked night shifts had statistically significant excess risks of ER+ breast cancer, with higher risk for ER+/HER2+ subtypes (77%) than ER+/HER2− (35%) breast cancer. Postmenopausal women who had ever worked night shifts also showed a statistically significant excess risk of ER+/HER2+ breast cancer (OR = 1.59, 95% CI = 1.11 to 2.28). Regarding receptor-negative subtypes, one statistically significant elevated risk was reported for ER–breast cancer among women with the longest duration of night work (Rabstein et al. 2013), with the remaining elevated estimates for receptor-negative subtypes based on small numbers of exposed cases, and aggregated within two studies (Lie et al. 2013, Rabstein et al. 2013) (Figure 3-8).

Three studies reported on shift work in relation to in situ and invasive cancers with conflicting findings (O’Leary et al. 2006, Grundy et al. 2013a, Papantoniou et al. 2015a). Papantoniou et al. (2015a) found a higher risk for invasive cancers; however, no difference in risk was reported by Grundy et al. (2013a) nor O’Leary et al. (2006). Wang et al. (2015a), however, reported a statistically significant elevated risk among women with localized tumors, but not in women with regional or distant breast cancer.

Figure 3-6 Risk of receptor-positive breast cancer and night work, all women

CI = confidence interval.

The figure depicts a forest plot of the risk of receptor positive breast cancer and night shift work in pre- and post-mentopausal women. Of the 10 studies reporting on breast cancer subtypes (ER+, ER+PR+, HEER2+, or PR+), all reported elevated risks overall or for subcategories of high frequency and/or duration of night work.

Figure 3-7 Risk of breast-cancer and night work by receptor subtypes, premenopausal women

CI = confidence interval.

The figure depicts a forest plot of the risk of breast cancer subtypes and nightwork among premenopausal women based on two studies. Both reported statistically significant elevated risks ranging from 1.38 to 3.29 for women with receptor positive status; also both studies reported elevated risks among women with mixed positive and negative receptor status, however, Papantoniou 2015 reported a null value for the ER+PR- subtype. Risk estimates among women with receptor negative subtypes were approximately null with one exception showing a statistically significant increased risk of 1.58 (Cordina-Duverger 2016, HER2-).

Figure 3-8 Risk of receptor-negative breast cancer subtypes and night work, all women

CI = confidence interval.

The figure depicts a forest plot of the risk of estrogen receptor negative breast cancer and night work among both pre- and post- menopausal women. Most studies reported null values for negative receptor subtypes with the exception of the Rabstein et al. 2013 study; and some studies which reported subsets of women working night shifts for long durations or at high frequency.

#### Effect modifiers: patient characteristics

##### Chronotype

Results from four studies reporting on chronotype suggest that chronotype was not clearly associated with the risk of breast cancer. Two studies reported that morning types may have a higher risk of breast cancer associated with night work (Hansen and Lassen 2012, Papantoniou et al. 2015a), and two studies reported no association (Fritschi et al. 2013, Travis et al. 2016 Million Women Study). Studies varied in how chronotype was assessed; some asked one question, while others used instruments developed for this purpose. The extent to which differences in assessment explain some of the heterogeneity is not clear. In each of these studies, the percentage of evening types tended to be highest among women with the longest durations of night work (either 10 to 20 years or at least 20 years) and lowest among women with no night work.

##### Occupation and race

Four studies included either nurses or health professionals exclusively (Lie et al. 2011, Hansen and Stevens 2012, Vistisen et al. 2017, Wegrzyn et al. 2017), and three others included them as a smaller analytic subpopulation (Grundy et al. 2013a, Travis et al. 2016 Million Women Cohort). Thus, the evidence for the association of night work with breast cancer was not restricted to nurses or health professionals. Increased risks were found for nurses and health-care workers (Lie et al. 2011, Hansen and Stevens 2012, Wegrzyn et al. 2017, [NHS2 cohort]), for other occupations, including textile workers, and in studies of mixed occupations. Similar patterns of risk were reported for both health-related and non-health-related occupations (Grundy et al. 2013a, Travis et al. 2016).

Race and ethnicity were also not specifically controlled for in any of the studies. All of the night work studies with the exception of the Wegryzn et al. (2017) U.S. NHS/NHS2 study were conducted in European or Asian populations, and none controlled for race. The NHS/NHS2 study would potentially be most informative for the U.S. population concerning the risk of night work among African-American women. However, only a small number of these women are part of the study population, and results are not reported by race. Although it has been hypothesized that the effect of light at night on breast cancer may vary by race, in particular, that Asian or brown-eyed individuals should be less sensitive to light at night than blue- or green-eyed individuals, findings on melatonin suppression are unclear (see Section 2). While the Pronk et al. (2010) study of Asian women in Shanghai found no effect of night work on breast cancer, the Chinese case-control study by Wang et al. (2015a) found an overall positive relationship between “ever” night shift work and breast cancer risk. However, the Pronk et al. (2010) cohort was older and primarily postmenopausal, and had a very short follow-up period, whereas over 60% of women in Wang et al. (2015a) were premenopausal. Thus, it is not clear whether race/ethnicity was the source of heterogeneity in these Chinese studies.

#### Chance, bias, or confounding

Alternative explanations for the evidence in these studies cannot be completely ruled out. Findings of elevated breast cancer risk among night workers in case-control studies have been discounted because of the probability of recall bias (Travis et al. 2016). Most of these studies collected data before 2007, when shift work first became widely publicized as a potential risk factor for breast cancer. In addition, two studies reporting elevated breast-cancer risks did not find an association of breast cancer with electromagnetic fields, an exposure with no known association with breast cancer included in questionnaires, which helps to alleviate concerns for differential recall bias. Furthermore, questions about lifetime job-by-job work schedules in most of the case-control studies reduced the likelihood of recall bias, and memory of night work in the past appeared to agree well with records of night work in populations where these data were available.

Studies were conducted in the United States, Europe, and Asia and included populations of shift workers that differed widely with respect to their reproductive history (e.g., parity, age at first full-term pregnancy), lifestyle factors (e.g., alcohol, smoking, physical activity, and hormone use), body mass index, and socioeconomic background, all factors related to breast cancer risk. However, almost all studies considered these risk factors as well as physical activity and BMI, and adjustments for potential confounders made no material difference in any of the studies reporting both crude and adjusted estimates. None of the nurses’ studies took into account co-exposures to carcinogens in the workplace; however, nurse cohorts only accounted for 3 of the 17 studies finding evidence of an association and the remaining positive studies were population-based studies in which specific occupational co-exposures are less of a concern.

Shift workers in the United States tend to have lower adherence to breast cancer screening guidelines and have lower income, education, and use of health insurance (Tsai et al. 2014). However, such a difference in breast cancer screening between day and night workers is not likely to explain the elevated risks among night workers found across the studies in this review. Such a difference would likely bias the relative risks toward the null, with fewer breast cancer cases detected in the exposed group. Tsai et al. (2014) also noted that shift workers in particular industries and occupations (e.g., manufacturing, food service and preparation, personal care services, and production) were least likely to get regular mammographies. Four studies controlled for mammography use or number of mammograms. In a study of nurses (Wegrzyn et al. 2017), an additional model was run to determine evidence of bias due to differential screening in shift workers and day workers but none was found. One additional population-based study (O’Leary et al. 2006) found that shift workers reported a lower number of mammograms but this variable did not reach the criteria for inclusion in the final model. Finally, as most studies controlled for socioeconomic status it is likely that confounding from screening would be somewhat controlled.

## 3.3 LAN

In general, the adequacy of the proxies used to define and measure LAN in relation to their likelihood to cause circadian disruption was considered in evaluating the studies. For example, brighter light, the color spectrum of light, and more frequent exposures to light during biological night may be more likely to cause circadian disruption. The key issues applicable specifically to outdoor environmental LAN and indoor LAN are discussed in detail below.

### 3.3.1 Overview of study methods and characteristics

The environmental LAN studies are listed in Table 3-8.

Table 3-8 Studies of breast cancer and environmental (outdoor and indoor) LAN

Reference | Population | Breast cancer incidence sources | Exposure information and assessment
Outdoor LAN
Garcia-Saenz et al. 2018 | MCC-Spain study; Population-based case-control study; Enrolled 2008–2013; 380 cases; 490 controls; 0% shift workers | Major hospitals in study area; Receptor status | In-person interviews for covariates and residential history; Outdoor LAN: images from International Space Station for Barcelona and Madrid for 2012–2013 with remotely sensed upward light intensity and blue light spectrum for each geocoded longest residence; Metrics: (1) outdoor visual ALAN as a proxy for luminance - visual light; and (2) melatonin suppression index (MSI) blue light
James et al. 2017 | U.S. Nurses Health Study 2 (NHS2); Cohort study; 109,672 registered nurses; Enrolled 1989–2013; 3,549 cases; 82% premenopausal at baseline; 42% of person-years from shift workers | Self-report, proxy, postal system, or NDI; Validated by medical record review, by state cancer registries, next of kin, or death records | Self-administered mail questionnaire for covariates and residential history; Outdoor LAN, satellite imagery data (DMSP) high-dynamic-range data 2006–2010; Metrics: cumulative average outdoor LAN; Cumulative average outdoor LAN: 29.7 nW·sr^−1^/cm^2^; Broad national range of outdoor LAN levels 0.39 to 248.1 nW·sr^−1^/cm^2^
Hurley et al. 2014 | U.S. California Teacher Study; Cohort study; 106,731 active and retired female enrollees; Enrolled 1995–1996; 5,095 cases; 46% < 50 yr; % shift workers NR | California Cancer Registry | Self-administered mailed questionnaire for covariates and residential history; Outdoor LAN, satellite imagery data (DMSP) 2006 high-dynamic-range data; Metrics: average annual nighttime radiance value assigned to residence at baseline; 17% with highest outdoor light exposure by DMSP; LAN range = 0–175 nW·sr^−1^/cm^2^; Mean LAN = 35 nW·sr^−1^/cm^2^; Median LAN = 32 nW·sr^−1^/cm^2^
Bauer et al. 2013 | Georgia U.S.A.; Case-referent study; Enrolled 2000–2007; 33,503 cases; 14,314 lung cancer referents; 29% < 54 yr; % shift workers NR | Georgia Comprehensive Cancer Registry | Georgia Comprehensive Cancer Registry and U.S. Census Data. Outdoor LAN, satellite imagery data, DMSP-OLS; Metrics: low (0–20 nW·sr−1/cm^2^) medium (21–41 nW·sr−1/cm^2^ high (> 41 nW·sr−1/cm^2^); 59.7% with high LAN levels; LAN range = 0 to 63 nW·sr−1/cm^2^
Indoor LAN
Garcia-Saenz et al. 2018 | MCC-Spain study; Population-based case control study; Enrolled 2008–2013; 1,219 cases; 1,385 controls; 30% < 50 yr of age | Major hospitals in study area; Receptor status | Indoor LAN In-person interviews; Metrics: Self-reported level of light in sleeping area at age 40; or at diagnosis/interview for those < 40; 78% controls exposed to some light
Johns et al. 2018 | Generations Study U.K.; Cohort study; Enrolled 2003–2012; 105,866 women; 1,775 cases; Average age = 46.5 yr; 16.9% shiftwork in past 10 yr | Self-report and NHS Central Registers; Verified against medical records | Indoor LAN; self-administered mailed or online questionnaire; Metrics: At recruitment and at age 20 read easily at night at work or see across the room (high); see hand in front of you, but not across the room (medium); too dark to see hand, or wear a mask (low); Yes/No night waking and exposure to light; Exposed: 79.1% reported medium or high LAN
White et al. 2017 | Sister Study, U.S.A.; Cohort study; Enrolled 2003–2009; 50,884 women; 2,736 cases; Average age = 55.6 yr; 0% shift workers | Annual health updates and follow-up questionnaires; 81.1% of cases verified by medical records | Indoor LAN, computerized telephone questionnaire; Metrics: Type of light on when sleeping; turning light on upon awaking during the night; 82.3% exposed to some indoor LAN
Keshet-Sitton et al. 2016 | Israeli Jewish workers; Population-based case-control study; Enrolled 2010–2014; 93 cases, 185 controls; Average age = 54.5 yr in controls; 0% shift workers | Comprehensive Cancer Center in Soroka Medical Center, Beer-Sheva, and the Baruch Padeh, Poria Medical Center in Tiberius | Indoor LAN, self-administered questionnaire; Metrics: subjective light level in bedroom at night, falling asleep or sleeping with TV on, light penetrating the room from outside, dim light on during the night, closed shutters; turning lights on when waking in the night; type of bedroom and bed light illumination (long or short wavelength); residing near strong ALAN sources during five years prior to diagnosis or reference date; % exposed NR
Hurley et al. 2014 | U.S. California Teacher Study cohort; See outdoor light | See outdoor light | Indoor LAN, self-administered mailed questionnaire; Metrics: non-users, heavy, light, and medium based on frequency of using bright light per week, months used, and hours per night; 5% used bright light during sleeping; 17% of bright light users had the highest level of frequency and duration
Fritschi et al. 2013 | BCEES Western Australia case; Population-based case-control study; Enrolled 2009–2011; 253 cases; 335 controls; 100% shift workers | Western Australia Cancer Registry | Indoor LAN at work, mailed questionnaire with follow-up telephone interview for shift work; Metrics: reading easily at night at work (high), able to see but not well enough to read at work (medium), enough light to read in bedroom when sleeping during the day (low); 51% controls reported high LAN
Kloog et al. 2011 | Northern Israel; Population-based case-control study; Enrolled 2000; 794 cases; 885 controls; Mean age = 64.6 yr; % shift workers NR | Residents of northern Israel at time of diagnosis identified from all hospitals in Israel | Indoor LAN, in-person interview; Metrics: bedroom light levels, light coming from outside the bedroom, availability of shutters in the bedroom, and sleeping with the television on; 22.6% of controls reported high ambient light levels
Li et al. 2010 | Connecticut, U.S.A.; Population-based case-control study; Enrolled 1994–1997; 363 cases; 356 controls; 20.4%/35.7% of cases/controls premenopausal; % shift workers NR | Yale-New Haven Hospital system and Comprehensive Cancer Center; Connecticut Tumor Registry | Indoor LAN, in-person interview; Metrics: lights on while sleeping, presence of various types of exterior light affecting the sleeping area, use of shades while sleeping, radio/TV/hall LAN on while sleeping during 10 years prior to diagnosis or reference date; 7.2% controls kept light on while sleeping
O’Leary et al. 2006 | EBCLIS, NY, U.S.A.; Population-based case-control study; Selected population; Enrolled 1996–1997; 487 cases; 509 controls; 39% premenopausal | Hospitals in Nassau and Suffolk Counties, NY | Indoor LAN, staff-administered in-home interview; Metrics: frequency of turning on lights during sleep hours in 5 yr prior to diagnosis; 7.6% worked nights in 15 yr prior to diagnosis/reference; 5.6% of controls turned lights on ≥ 2 times/night and ≥ 2 nights/wk
Davis et al. 2001b | Fred Hutchinson Cancer Research Center, WA, U.S.A.; Population-based case-control study; 1992–1995 enrollment; 808 cases; 708 controls; 33% premenopausal | Cancer surveillance system of the Fred Hutchinson Cancer Research Center, Seattle, WA | Indoor LAN, in-person interview; Metrics: turning on lights at night; % of time light on at night, ambient light levels at night, turning off lights to sleep in 10 years prior to diagnosis or reference date; 6.0% ever nights in 10 yr prior to diagnosis; 3.4% of controls had brightest ambient lights in bedroom

ALAN = artificial light at night; BCEES = Breast Cancer Employment and Environment Study; Australia; DMSP = U.S. Defense Meteorological Satellite Program; EBCLIS = Electromagnetic Fields and Breast Cancer on Long Island Study; LAN = light at night: MCC = Multi Center Case-Control- Study, Spain.

Five studies included measures of outdoor LAN: two cohort studies (Hurley et al. 2014, James et al. 2017), two case-control studies (Keshet-Sitton et al. 2016, Garcia-Saenz et al. 2018), and one case-referent study (Bauer et al. 2013). Ten studies (two cohort studies and eight case-control studies) included measures of indoor LAN, specifically LAN in the sleeping area; three of these reported on both indoor and outdoor LAN (Hurley et al. 2014, Keshet-Sitton et al. 2016, Garcia-Saenz et al. 2018). The studies of LAN in the sleeping area varied by the inclusion and treatment of night workers: three studies limited analyses to non-shift workers (Keshet-Sitton et al. 2016, White et al. 2017, Garcia-Saenz et al. 2018); two studies asked questions about shift work but did not integrate this information into the analyses (Davis et al. 2001b, O’Leary et al. 2006); one study incorporated information on shift work during the past 10 years into the analysis (James et al. 2017); three studies made no mention of shift work (Li et al. 2010, Kloog et al. 2011, Hurley et al. 2014); and one study restricted data on LAN to shift workers when they were working nights (Fritschi et al. 2013).

### 3.3.2 Evaluation of study quality

Studies measuring outdoor and indoor LAN were evaluated separately for their utility. A detailed evaluation of study quality for the LAN studies is provided in Appendix C, Table C-1. The most important issues bearing on the overall quality in these studies were the potential for selection bias and study attrition, exposure misclassification, confounding, and study sensitivity.

#### Outdoor LAN

##### Selection

The Bauer et al. (2013) study raised concerns regarding selection bias based on the removal of approximately 20% of addresses because they were not geocoded; these occurred particularly in rural areas, where LAN is low. Although the authors stated that rural Georgia has a higher proportion of white than black residents, there are notable exceptions — in many Georgia counties, the proportion of black residents is 50% to 78%, and these are largely rural areas in the southwest of the state, where addresses are likely to be too nonspecific to geocode, and LAN might be minimal. Being far from urban centers, these counties might also have had fewer diagnosed cases of breast cancer. Elimination of addresses in these counties may have biased the results away from the null. In the Garcia-Saenz et al. (2018) study, only 52% of potential controls participated, suggesting the possibility of attrition bias in an unknown direction. The Keshet-Sitton et al. (2016) study included only one question about residing near a strong source of LAN. Selection bias might have been operating in this study; case and control subjects might not have been selected from the same population, as the control subjects were friends or acquaintances of case subjects and women recruited through personal meetings in schools. Although home residence was matched, more control than case subjects lived in rural areas, defined as a settlement with fewer than 2,000 residents. In addition, significantly more control than case subjects were non-native born.

##### Exposure misclassification

Two separate issues were considered in evaluating exposure misclassification — first, whether an exposure surrogate was an acceptable proxy for the exposure of interest (i.e., the extent of the exposure to LAN to the individual is associated with circadian disruption, see Section 2 for studies on melatonin suppression), and second, how precisely the proxy was measured. In three of four studies, outdoor LAN measurements based on geocoded addresses were measured using light levels from satellite imagery data from the U.S. Defense Meteorological Satellite Program (DMSP; NOAA 2015). A study in Georgia (unpublished data cited as part of the study by Bauer et al. 2013) found a significant correlation with satellite data and ground level outdoor circadian light readings as measured by the Daysimeter. However, a study of teachers in Albany, New York and Vermont (rural, suburban, and urban areas) found no correlation between sky brightness (superimposed on addresses but not geocoded) and indoor light (e.g., light levels in the bedroom or in the bedroom window) nor with personal light exposure measurements measured at the eye between twilight and night time using a Daysimeter (which were not location specific). Personal light levels were predicted to suppress melatonin by ~ 7%. In addition, information on the use of individual activities related to exposure to LAN (such as using blackout curtains) was not available in any of the cancer studies of exposure to outdoor light.

Regarding the precision of the proxy measurement, the particular DMSP datasets and methods used to create exposure variables differed among the three studies and had implications for misclassification bias. Bauer et al. (2013) used the DMSP low-dynamic-range data, whereas James et al. (2017) and Hurley et al. (2013) used the DMSP high-dynamic-range data, which includes a much broader range of radiance in urban areas, thus reducing potential exposure misclassification in urban areas. The low-dynamic-range data do not vary beyond 63 nW·sr^−1^/cm^2^ in urban areas, which was the upper limit reported by Bauer et al. (2013); for James et al. (2017) and Hurley et al. (2013), the upper limits were 248 and 175 nW·sr^−1^/cm^2^, respectively.

The Garcia-Saenz et al. (2018) study used a different methodology to calculate visual LAN and the melatonin suppression index (MSI), which attempted to address the limitations in the previous studies using only satellite images. Their method was based on images taken with commercial Digital Single-Lens Reflex (DSLR) cameras of two cities by astronauts aboard the International Space Station (ISS) in 2012 and 2013 provided by the Earth Science and Remote Sensing Unit, NASA Johnson Space Center (NASA 2018). Unlike satellite images, these images provided information in three spectral bands in the visual range (RGB: red [R], green [G], blue [B]) with spatial resolution of about 30 m. The estimate of visual light was reported as well as the estimate for the MSI. The MSI represents the degree to which the spectrum shape of different lights are effective in suppressing the melatonin production compared to a standard which corresponds approximately to the average midday sunlight in Western and Northern Europe.

Each study used a different approach for handling address changes, which might have affected exposure misclassification. Only James et al. (2017) incorporated time-varying information on LAN, using updated addresses and DMSP values. Hurley et al. (2014) used the baseline address to assign LAN values and conducted sensitivity analyses comparing the overall population with a subset of the population that resided at the same address throughout the study period; the results were similar. Bauer et al. (2013) extracted and averaged LAN values for the one known address at diagnosis (or referent date) for each year of exposure prior to diagnosis, which ranged from 9 to 16 years, assuming that the address at diagnosis had been stable over those years prior to diagnosis. The direction and magnitude of misclassification resulting from this assumption is unknown; it depends on the residential mobility of the population and other population characteristics. The Garcia-Saenz study geocoded the longest residence, which in this low mobility population was greater than 30 years for 80.2% of the respondents.

##### Outcome misclassification

It is not clear whether the outcome methods in Bauer et al. (2013) clearly distinguished between relevant diseased and non-diseased participants, or whether lung-cancer cases were the appropriate comparison group, as it is unclear whether lung cancer is related to shift work or LAN (see Section 4). If LAN is related to lung cancer, then the estimate of effect in this study would be biased towards the null. Each of the other studies had low potential for bias due to outcome misclassification.

##### Sensitivity

If LAN exposure is most relevant at younger ages, all the outdoor studies have limited sensitivity to detect such an effect. Bauer et al. (2013) used different exposure windows, but none prior to 9 to 16 years before diagnosis in this older group of cases (mean age = 60, standard deviation = 14). In addition, the range of exposure levels was attenuated by use of low-dynamic-range DMSP data. In the Hurley et al. (2014) population, about 16% of women were under the age of 40 at baseline, when the current-year satellite image data were applied, meaning that LAN exposure data at young ages were not available for most women in the cohort. Data from an early exposure window were missing in James et al. (2017) as well, but because this cohort was younger at baseline and had a larger proportion of premenopausal women at the time of exposure measurement than either of the other studies, it has greater sensitivity to detect an effect of age at exposure. The Garcia-Saenz et al. (2018) population was somewhat older, and exposure to LAN was derived from recent LAN data (2013 to 2014); while this urban population was relatively stable, it is unknown how much LAN changed in the two cities over the decades when the population was younger, 30 to 40 years earlier. Finally, whether the LAN measurements from satellite data indicate results with levels high enough to cause circadian disruption was considered in the exposure-assessment section.

##### Potential confounding

Each of these studies raised some concern about confounding. In James et al. (2017), factors associated with outdoor LAN may not have been fully controlled for by factors included in the models; alternatively, factors unrelated to LAN but included in the model may have reduced the estimates of the effect. Regarding confounding from other sources of LAN that might influence the breast cancer and LAN relationship, only James et al. (2017) reported on the percentage of person-time that was rotating shift work and stratified analyses by shift work. The final models used by Hurley et al. (2014) included several variables unrelated to LAN, which might have lowered the risk estimates. Bauer et al. (2013) measured several relevant potential confounders on a county-wide, not individual, basis (parity, education, and smoking, but not race). Alcohol consumption was not controlled for in this analysis, and residual confounding was likely to remain because of the lack of individual-level data. As socioeconomic factors are associated with urban light, Garcia-Saenz et al. (2018) adjusted for socioeconomic status both at the individual and area level; however, adjusting for socioeconomic status may not resolve completely the potential bias introduced by high attrition in the controls.

##### Overall utility

Table 3-9 summarizes the bias and quality evaluation of the studies of breast cancer and environmental LAN. The Garcia-Saenz et al. (2018), James et al. (2017) and Hurley et al. (2014) studies each had moderate utility; Bauer et al. (2013) had low overall utility.

Table 3-9 Summary of study quality evaluation: LAN and breast cancer

Citation | Selection^a^ | Exposure | Outcome | Confounding | Analysis | Selective reporting | Sensitivity | Utility^b^
Outdoor LAN
Garcia-Saenz et al. 2018 | ++ | ++ | +++ | +++ | +++ | +++ | ++ | ++
James et al. 2017 | +++ | +/++ | +++ | ++ | +++ | +++ | ++ | ++
Hurley et al. 2014 (Outdoor) | +++ | +/++ | +++ | ++ | +++ | +++ | + | ++
Bauer et al. 2013 | + | + | +++ | + | +++ | +++ | + | +
Keshet-Sitton et al. 2016 (Outdoor) | + | + | + | ++ | +++ | ++ | + | +
Indoor LAN
Garcia-Saenz et al. 2018 | ++ | ++ | +++ | +++ | +++ | +++ | ++ | ++
Johns et al. 2018 | +++ | + | +++ | ++ | +++ | +++ | + | +
White et al. 2017 | +++ | + | ++ | +++ | +++ | +++ | + | +
Keshet-Sitton et al. 2016 (Indoor) | + | ++ | + | ++ | +++ | ++ | ++ | ++
Hurley et al. 2014 (Indoor) | +++ | ++ | +++ | ++ | +++ | +++ | ++ | ++
Fritschi et al. 2013 | ++ | + | +++ | +++ | ++ | +++ | ++ | +
Kloog et al. 2011 | ++ | ++ | ++ | ++ | ++ | ++ | ++ | ++
Li et al. 2010 | +++ | + | +++ | ++ | ++ | +++ | + | +
O’Leary et al. 2006 | ++ | + | +++ | ++ | +++ | +++ | + | +
Davis et al. 2001b | +++ | ++ | ++ | ++ | +++ | +++ | ++ | ++

a Levels of concern for bias and for study sensitivity (columns for Selection through Sensitivity). Key: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

b Utility of the study to inform the hazard evaluation. Key: +++ = high utility; ++ = moderate utility; + = low utility; 0 = inadequate utility.

#### Indoor LAN studies

##### Selection

Attrition in the case-control studies (O’Leary et al. 2006, Kloog et al. 2011, Fritschi et al. 2013, Garcia-Saenz et al. 2018) might have introduced selection bias; issues regarding selection for the Keshet-Sitton et al. (2016) study addressed above are relevant for indoor lighting as well.

##### Exposure misclassification

These studies used several different metrics of exposure to light in the sleeping area. As with outdoor LAN, the relevant issues are how well these metrics corresponded to actual levels of LAN that could reduce melatonin levels and/or cause circadian disruption and how accurately they were measured.

Exposure metrics. The studies used several metrics that could be roughly associated with lux levels, as described in Section 2: (1) daylight or sleeping during the day (200 to 400 lux), (2) various self-reported levels and durations of light in the sleeping area at night or before sleep, (3) awakening at night with LAN (5 to 200 lux), and (4) light from outside the sleeping area or use of shades or shutters (< 1 lux) or residing near strong sources of artificial LAN. Section 2 describes results from several studies concluding that changes in melatonin levels can occur at levels of exposure to polychromatic white light as low as 30 lux. Therefore, LAN metrics that capture exposure to types of light corresponding to greater than 30 lux may be most relevant; such LAN would include light from room LAN, e-devices, and television. Another metric used that was not specifically associated with lux levels was “non-peak sleep,” defined as not sleeping between 1:00 AM and 2:00 AM, when the melatonin peak occurs. None of these metrics represented measured light, specific types of LAN, or duration of LAN. In addition, alignment of the exposure categories and lux levels was imperfect, and several categories overlapped.

Ideally, specific information about the type, level, and duration of LAN that could differentiate individuals with high and low exposure would be available for each analysis; however, there was inadequate information available to assess the level of light exposure in the sleeping area or the conditions of LAN. Seven studies collected data on the subjective level of light in the sleeping area at night, the metric most likely to be useful for differentiating exposure levels (Davis et al. 2001b, Kloog et al. 2011, Fritschi et al. 2013, Hurley et al. 2014, Keshet-Sitton et al. 2016, Garcia-Saenz et al. 2018, Johns et al. 2018). However, none of these studies used methods that were precise enough to align a subjective level of light with specific lux levels, nor the light spectrum, and none were easily comparable with one another. For example, subjective levels considered to be “high” may vary within and across populations. Davis et al. (2001b) and Johns et al. (2018) asked participants to rate the level of ambient light in their bedroom on a scale of 1 to 5 or 6, with “night” being defined as the time between turning off the lights to go to sleep and waking up, the lowest light level defined by wearing a mask to keep light out, and level 6 defined as having enough light to be able to read comfortably.

Fritschi et al. (2013) assessed LAN by asking women whether they could read easily at night at work (high exposure) or could see but not well enough to read at work (medium exposure). Those women who did not fit either of these definitions but whose bedrooms were light enough to read in when they were sleeping during the day were assigned low exposure. Hurley et al. (2014) defined levels using categories of hours per night, days per week, and months per year sleeping with a bright light. The criteria for “heavy” users were at least 10 months of use for at least 5 days per week and 7 hours per night; the criteria for “light” users were 0 to 3 months, 1 to 3 days per week, and 1 to 2 hours per night; and “medium” users were defined as those with all other combinations of duration and frequency. Garcia-Saenz et al. (2018) asked women to report on light in the sleeping area at the age of 40 using a four-digit Likert scale: a) total darkness, b) almost dark, c) dim light, and d) quite illuminated. No additional specification of the scale was provided. For subjects < 40 years of age, this level was reported for the time of diagnosis or interview; responses were similar for those ≥ 40 and those < 40 years of age (Pearson R = 0.90). Neither Keshet-Sitten et al. (2016) nor Kloog et al. (2011) provided definitions for subjectively reported levels of light, but rather reported on continuous, not categorical, levels.

Quality of the measurements. The ability of study subjects to correctly recall past light levels and LAN practices in the bedroom bears on the quality of the measurements and may vary according to the recency of the exposure being asked about. Studies asked about time just prior to diagnosis (Kloog et al. 2011, Garcia-Saenz et al. 2018 [cases < 40 years old at interview], one year prior to recruitment (Hurley et al. 2014, White et al. 2017, Johns et al. 2018), for awakening during the night with lights on 5 years prior to diagnosis (O’Leary et al. 2006), 10 years prior to diagnosis (Davis et al. 2001b, Li et al. 2010, Johns et al. 2018 for light level), or 10 to 15 years prior to diagnosis (Keshet-Sitton et al. 2016). Johns et al. (2018) and Garcia-Saenz et al. asked about light level in the sleeping area at age 20 and at age 40, respectively, but for women many years older than these ages, memory of this exposure is likely to be misclassified. Although the 10 to 15 years prior to diagnosis may be the most relevant time for cancer etiology, ability to adequately recall LAN conditions might have been low. Recall bias might be somewhat of a consideration, although the association of light in the sleeping area with breast cancer was not directly addressed in the IARC report on shift work in 2007, and it is unknown to what extent this association was recognized in any of these studies at the time of data collection.

##### Sensitivity

In all studies, only a small proportion of women reported exposure to high levels of LAN when asked to rate the level in the sleeping area; however, at least 30 women in each study were classified as highly exposed using their respective classifications. Finally, the exposure window was not sufficiently described in several studies (Kloog et al. 2011, Fritschi et al. 2013, White et al. 2017).

##### Potential confounding

Overall, these studies raised low to moderate concerns about potential confounding, as most controlled for potential confounding factors. However, some studies likely over-controlled for variables likely to be in the breast-cancer pathway (e.g., BMI, age at menarche), introducing a bias towards the null particularly when unrelated to exposure.

##### Overall utility

None of these studies were considered to have high utility for evaluating the relationship between breast cancer risk and exposure to light that caused circadian disruption. Five of the studies were considered to have moderate utility for this evaluation, based on their attempts to capture levels of LAN in the sleeping area (Davis et al. 2001b, Kloog et al. 2011, Hurley et al. 2014, Keshet-Sitton et al. 2016, Garcia-Saenz et al. 2018). The remaining five studies were considered to have low utility.

### 3.3.3 Breast cancer hazard assessment: Environmental LAN

Findings of the studies of outdoor and indoor environmental LAN included in the analysis are provided in Appendix C, Table C-2. The level of confidence in the evidence (“evidence,” “some evidence,” “null,” or “inconclusive”) from the individual studies of environmental LAN was reached by considering the strength of the association, the potential for specific biases or confounding, the quality of the exposure assessment, the expected directions and distortions of those potential biases or confounding, and the sensitivity of the study to detect an effect. The evidence is summarized in a heat map below (see the “Indoor LAN” section).

#### Outdoor environmental LAN

Overall, all four satellite studies of outdoor environmental LAN and the study by Keshet-Sitton (2016) found a positive association between outdoor LAN and increased breast cancer risk. However, there are concerns whether satellite data is measuring LAN or behaviors associated with LAN, and whether LAN from the outdoors is sufficiently high to disrupt circadian processes.

The four studies reported statistically significant excess risks of breast cancer among women in the highest LAN quintiles of exposure (14% in James et al. 2017, 12% in Hurley et al. 2014, 12% in Bauer et al. 2013, 47% for blue-light MSI in Garcia-Saenz et al. 2018, but no relationship between visual light and breast cancer). Hurley et al. (2014) and James et al. (2017) both reported statistically significant exposure-response relationships (P-values of 0.06 and 0.02, respectively), and suggested that the effect of outdoor LAN was seen primarily among premenopausal women in the highest quintile of exposure, reporting statistically significant excess risks of breast cancer of 34% and 20%, respectively, with virtually no excess risk among postmenopausal women (neither study reached statistically significant interaction). Garcia-Saenz et al. (2018) reported that exposure to the highest versus lowest tertile of blue light spectrum was slightly higher in postmenopausal women (OR = 1.31, 95% CI = 0.84 to 2.03) compared with premenopausal women (OR = 1.09, 95% CI = 0.57 to 2.09; P for interaction = 0.7).

The findings do not seem to be explained by shift worker status as no significant effect modification for night shift work was found in the NHS2 study (James et al. 2017) and the Spanish study excluded shift workers (Garcia-Saenz et al. 2018).

Results regarding the effect of outdoor LAN on subtypes of breast cancer varied across the three studies reporting on them: two studies found elevated risks among women with hormone receptor-positive tumors (ER+ tumors, James et al. 2017); ER+/PR + tumors, Garcia-Saenz et al. 2018); whereas in contrast, Hurley et al. (2014) reported a marginally higher risk among women with ER− and PR− tumors compared to hormone receptor-positive tumors but noted that analyses were limited by small numbers and no actual data were reported.

Additional results indicated statistically significant interaction between never, past, and current smokers (P = 0.008), such that past smokers had a 23% increased risk, and current smokers a statistically significant 54% increased risk of breast cancer (James et al. 2017).

Consistent with these findings, seven ecological studies of countries or communities reported that LAN, as measured by satellite images, was associated with breast cancer incidence (Kloog et al. 2008, Kloog et al. 2010, Kim et al. 2015, Rybnikova et al. 2015, Portnov et al. 2016, Keshet-Sitton et al. 2017, Rybnikova and Portnov 2018). All of these studies, however, were limited by the lack of individual-level data on exposure, confounding, and outcome. However, Rybnikova and Portnov (2018) reported on the effect of different subspectra using a multi-spectral year 2011 satellite image for Greater Haifa Metropolitan Area in Israel. They reported a positive association between breast cancer incidence and short-wavelength (blue) LAN subspectrum, and insignificant associations with green and red subspectra.

Figure 3-9 Risk of breast cancer and light at night (LAN)

CI = confidence interval.

*Trend test P = 0.02.

**Trend test P = 0.06.

+Unspecified outdoor source of LAN.

The figure depicts a forest plot of the risk of breast cancer from outdoor light at night among women in the highest quintile of exposure. Of the 5 studies, all reported statistically significant elevated risk estimates ranging from 1.12 to 1.52.

#### Indoor LAN

Of the indoor LAN studies, two of the five studies with moderate utility and one of the five low utility studies provided some evidence of an effect. The major predictor of heterogeneity across these indoor LAN studies was the variation in surrogates used to measure approximate LAN levels (lux) in the sleeping area and the lack of specificity regarding lux levels. The results are summarized in Table 3-10.

Table 3-10 Heat map of indoor LAN results (risk estimate by exposure metric)

Citation | Garcia-Saenz | Johns | White | Keshet-Sitton | Hurley | Fritschi | Kloog | Li | O’Leary | Davis
Highest ambient level in sleep area (~100–200 lux) | | ≤ 1 | | ≤ 1 | 1.13 ns | 1.25 ns | | | | 1.4 ns
Turns on light on during waking (~20–200 lux) | | ≤ 1 | ≤ 1 | ≤ 1 | | | | 1.4^a^ ns | 1.65^b^ sig | ≤ 1
Room light on while reading before sleep (~200) | | | | ≤ 1
Medium light in the sleeping area (~20–100 lux) | | ≤ 1 | ≤ 1 | ≤ 1 | ≤ 1 | ≤ 1 | | | | ≤ 1
Low levels (5–80 lux)^c^ | | ≤ 1 | ≤ 1 | 1.26^c^ | 1.17 ns | ≤ 1 | ≤ 1 | ≤ 1 | | ≤ 1
Low to high subjective light intensity^d^, continuous | ≤ 1 | | | 1.2^d^ ns | | | 1.22^d^ sig | | | 1.1 ns
Any use of LAN at night | | | | | ≤ 1
Bed light used for reading before sleep | | | | ≤ 1^c^ sig
Light from the outside (~< 1 lux) | | | ≤ 1 | ≤ 1^f^ sig | | | ≤ 1 | 1.2 ns
Frequency of non-peak sleep | | | | | | | | | | 1.7 sig
Daylight or sleeping during the day (~200–400 lux) | | | ≤ 1 | | | 1.25 ns | | 1.4^a^ ns

ns = not statistically significant; sig = statistically significant.

a Postmenopausal.

b Frequency of waking and turning on lights ≥ 1/week and ≥ 2/night.

c Reported use of specific low sources such as dim light, TV, clock radio, hall light, nightlight in the sleeping area hall.

d Self-reported ordinal levels of subjective light intensity from low to high.

e Reported that participants used long wavelength incandescent/halogen illumination as bed lights in this study.

f Reported closed shutters in the sleeping area.

Among the five moderate-utility studies, two found some evidence of breast cancer being associated with the highest self-reported ambient light level (40% statistically significant excess risk; Davis et al. 2001b), or subjective light level (22% statistically significant excess risk [Kloog et al. 2011]). In addition, Davis et al. (2001b) reported a significant 70% excess risk of breast cancer associated with frequent non-peak sleep. Kloog et al.(2011) reported a modest, but statistically significant effect of increasing light levels.

Results from the Hurley et al. (2014) study were inconclusive as there was no clear pattern of risk, and results from the highest level of light were only weakly elevated. Garcia-Saenz et al. (2018) reported a non-statistically significant inverse relationship between the highest level of light and breast cancer. Results from Keshet-Sitton et al. (2016) for indoor light are inconclusive as there is no effect with high reported levels of light, but a weak non-significant relationship between low light levels and breast cancer.

Among the five low-utility studies, only one study indicated some evidence of an effect (O’Leary et al. 2006), reporting a 65% increased risk of breast cancer among women who woke up at least once a week and turned on the lights at least twice per night.

Results from the four low utility studies were either inconclusive or null. The results from the studies by White et al. (2017) and Johns et al. (2018) were null; however, the Johns et al. (2018) study reported a significantly reduced risk of breast cancer among premenopausal women with ER+ breast cancer and elevated risks of postmenopausal ER− breast cancer among women with high and medium self-reported ambient light levels in the sleeping area. Fritschi et al. (2013) queried LAN only among shift workers, and observed a non-statistically significant 25% elevated risk of breast cancer among women who worked at night in light sufficient to read easily and among those who had slept with medium or high levels of light for up to 19 years, yielding inconclusive results. The results from the Li et al. (2010) study were also inconclusive.

#### Key issues and chance, bias, and confounders

##### Outdoor LAN

Whether satellite images are an appropriate proxy for LAN or proxies for other behaviors of daily living associated with LAN, or whether the LAN measurements from satellite data at the residence are sufficient to cause circadian disruption remain unanswered questions. The finding by Garcia-Saenz et al. (2018) that breast cancer risk was associated with the blue-light spectrum but not the full visual spectrum suggests that this measure of outdoor LAN may be more relevant. However, to understand the association between outdoor LAN and breast cancer, additional studies measuring exposure to all sources of light at night and their intensities and spectral characteristics are needed. Regarding confounding, while James et al. (2017) adjusted for air pollution and population density, other studies did not. Furthermore, other factors related to both breast cancer and LAN (Rybnikova et al. 2015) could potentially explain the associations observed in these studies.

##### Indoor LAN

Findings for indoor LAN were inconsistent across studies; the major predictor of heterogeneity across indoor LAN studies was the varied metrics used to measure indoor LAN, making it difficult to compare studies. The positive finding observed for some metrics in some studies may be due to chance, bias, or confounding. Whether the low light exposure levels and the light spectra used in the sleeping areas in indoor studies were sufficient to disrupt circadian rhythms remains a question. Furthermore, none of these studies considered LAN during the evening. Although some studies asked about shades or curtains to block light from outside, none presented such data by subjective levels of LAN. The use of incandescent vs. fluorescent or LED LAN varies across countries and time periods, and better representation of types of LAN could help with interpretation of these results. In addition, the average proportion of the night when LAN was used was measured only by Davis et al. (2001b); this metric could be used to stratify data on light levels. Overall, more precise measurements and a better understanding of the relationships of these various metrics to one another would strengthen this literature base.

## 3.4 Transmeridian travel

### 3.4.1 Overview of study methods and characteristics

Six publications of four independent cohort or nested case-control studies investigating the relationship between transmeridian travel and breast cancer in the United States and Scandinavian countries were identified (Reynolds et al. 2002, Linnersjö et al. 2003, Pinkerton et al. 2012, Pukkala et al. 2012, Schubauer-Berigan et al. 2015, Pinkerton et al. 2016). Three of these included analyses of the U.S. Pan American cohort (Pinkerton et al. 2012, Schubauer-Berigan et al. 2015, Pinkerton et al. 2016). The mortality study by Pinkerton et al. (2012) was not included in the assessment because of the high survival rates for breast cancer (as discussed above). The Pan Am cohort incidence studies were based on retrospectively collected exposure data from case and non-case subjects in the survival cohort. Other studies were based on administrative data, including both the retrospective cohorts (Reynolds et al. 2002, Pukkala et al. 2012) and a nested case-control study within a retrospective cohort (Linnersjö et al. 2003). Table 3-11 lists the five studies included in the cancer hazard evaluation.

Table 3-11 Studies of breast cancer and transmeridian travel

Reference | Population | Outcome assessment method | Exposure assessment and metrics
Pinkerton et al. 2016 | Pan Am World Airways cohort, nested case-control in same cohort as Schubauer-Berigan 2015; 344 cases and 5,749 controls in the cohort of 6,093 flight attendants | Same as Schubauer-Berigan et al. 2015 | Retrospective telephone interview (2002–2005) and domicile records, 1930–1990); Metrics: standard sleep interval (SSI 10:00 PM–8:00 AM); cumulative travel hr; no. time zones crossed; Exposed: > 933.9 time zones crossed; > 395 hours working during SSI; > 853 days employment duration; Comparison: lower exposure and U.S. population rates; Additional analyses for effect modification and confounding
Schubauer-Berigan et al. 2015 | Pan Am World Airways cohort, nested case-control study; 6,093 female flight attendants working at least 1 yr between 1953 and 1990 | Invasive breast cancer incidence; Self or proxy report and medical record review; Registries in states with Pan Am domicile locations | Same as Pinkerton et al. 2016
Pukkala et al. 2012 | Nordic Airlines Cohort (Finland, Iceland, Sweden); Retrospective cohort study of 8,507 female cabin crew employed at varying times per country generally between 1955 and 2005. | Breast cancer incidence; Population-based registries in Finland, Iceland, Sweden, and Norway; 577 cases | Historical airline timetables; Metrics: flight duration, frequency, avg annual no. of 1-way flights crossing ≥ 6 time zones; Exposed: 100+ flights crossing ≥ 6 time zones
Linnersjö et al. 2003 | Swedish Scandinavian Airline System (SAS); Nested case-control study; 2,324 female cabin crew employed between 1957 and 1994 | Breast cancer incidence; Swedish National Cancer Register and National Cause of Death Register; 76 cases | Administrative records from SAS; Metrics: employment duration, total block hr, block hr of high-altitude, long-distance flights; Exposed: 10,000+ block hr; high-altitude, long-duration flight duty; ≥ 5,000 block hr of high-altitude long-distance flight
Reynolds et al. 2002 | Association of Flight Attendants in California; Retrospective cohort of 6,895 females diagnosed between 1988 and 1995 | Breast cancer incidence; California Cancer Registry; 60 cases | Administrative records; Metrics: international or domestic flights, duration of service, age at entry

### 3.4.2 Evaluation of study quality

A detailed evaluation of study quality of the transmeridian travel studies is provided in Appendix C, Table C-3, and the quality evaluation is summarized in Table 3-12. The most important issues bearing on the overall quality of these studies were the potential for exposure misclassification, confounding, and study sensitivity.

Table 3-12 Summary of study quality evaluation: transmeridian travel and breast cancer

Citation | Selection^a^ | Exposure | Outcome | Confounding | Analysis | Selective reporting | Sensitivity | Utility^b^
Linnersjö et al. 2003 | ++ | + | +++ | + | +++ | +++ | + | +
Pukkala et al. 2012 | +++ | ++ | +++ | ++ | +++ | ++ | ++ | ++
Reynolds et al. 2002 | ++ | + | +++ | + | +++ | +++ | ++ | +
Pinkerton et al. 2016 (update of Schubauer-Berigan et al. 2015) | ++ | +++ | ++ | +++ | +++ | +++ | ++ | ++
Schubauer-Berigan et al. 2015 | ++ | +++ | ++ | ++ | +++ | +++ | ++ | ++

a Levels of concern for bias and for study sensitivity (columns for Selection through Sensitivity). Key: +++ = low/minimal concern or high quality; ++ = some concern or medium quality; + = major concern or low quality; 0 = critical concern.

b Utility of the study to inform the hazard evaluation. Key: +++ = high utility; ++ = moderate utility; + = low utility; 0 = inadequate utility.

The studies with the highest utility for the evaluation were the nested case-control studies of the Pan Am cohort (Pinkerton et al. 2016 and Schubauer-Berigan et al. 2015), which were based on adequate exposure assessment, control of confounding factors, and study sensitivity. However, based on information provided by the studies together with the earlier mortality analysis, it is possible that these studies were limited by selection bias towards the null. The study sample consisted largely of survivors exposed to long durations of transmeridian flight at young ages, and surviving members of the incidence cohort had longer employment histories (based on flight records) than the full mortality cohort (Pinkerton et al. 2012). With respect to exposure assessment, the studies captured the number of time zones crossed, long-haul flights, and hours working during a standard sleep interval (10:00 PM to 6:00 AM), using self-reported data on employment duration and cumulative number of time zones crossed calculated with algorithms developed by Grajewski et al. (2003) and Waters et al. (2009). While this study captured working hours during the standard sleep interval and could conceivably be included with other night shift studies, it was not included in Section 3.2, as working on flights crossing time zones during the standard sleep interval can be considered to be a very different exposure scenario. That is, flying across time zones into daylight, with concomitant changes in the level and timing of lighting and meals is sufficiently different from working nights in one time zone. Although these studies were able to sufficiently differentiate between individuals with high and low exposure, the exposure metrics were highly correlated, and certain relevant analytic subsets included relatively few women. Pukkala et al. (2012) also attempted to quantify time zones crossed, using historical airline timetables to estimate flight durations and frequencies to which these women would have been exposed; women were classified as exposed if, based on their employment duration, they were estimated to have worked 100 or more flights crossing at least 4, 5, or 6 time zones. The calculations resulted in an estimate of at least 40% of flight crew being highly exposed.

Studies with less precise exposure metrics for circadian disruption used block hours and the number of high-altitude flights, with no further information about time zones crossed (Linnersjö et al. 2003), or whether flight assignments were considered to be primarily international or domestic (Reynolds et al. 2002), again with no additional information on time zones crossed or numbers of flights beyond years of employment.

Linnersjö et al. (2003) and Reynolds et al. (2002) did not have sufficient information to control for potential confounding. The remaining studies included potential confounding factors in their analytic models, and had either low or moderate risk of bias due to confounding. As with the shift-work studies, adjustment for potential confounding did not materially change the unadjusted estimates. The sensitivity of most of the studies was limited by their inability to differentiate the most highly exposed aircrew.

### 3.4.3 Breast cancer hazard assessment: Transmeridian travel

Findings of the studies of transmeridian travel included in the analysis are provided in Appendix C, Table C-4.

Overall, the studies provided inadequate evidence of an association between high levels of transmeridian travel and breast cancer risk. The results from studies of transmeridian travel were heterogenous, likely because of differences in exposure classification and low sensitivity of the studies to detect effects. The levels of evidence are summarized in Table 3-13.

Table 3-13 Summary of levels of evidence from studies of breast cancer and transmeridian travel

Study utility or informativeness | Level of evidence | Retrospective cohort studies | Retrospective nested case-control studies
Moderate:; 2 studies | Some evidence | | Schubauer-Berigan et al. 2015; Pinkerton et al. 2016 (in subgroup of women with parity ≥ 3)
Moderate:; 2 studies | Null | Pukkala et al. 2012
Low: 2 studies | Moderate to strong evidence | Reynolds et al. 2002
Low: 2 studies | Some evidence | Linnersjö et al. 2003

Among the moderate-utility studies, two studies found some evidence for an association between transmeridian flights and breast cancer (Schubauer-Berigan et al. 2015, Pinkerton et al. 2016), and the third study found no such evidence (Pukkala et al. 2012). In the Pan Am cohort overall, high levels of transmeridian flights did not increase the risk of breast cancer, but the authors could not exclude the possibility that high levels of transmeridian flight might increase breast cancer risk in a subgroup of women (Pinkerton et al. 2016). Among the approximately 15% of the Pan Am cohort with parity of 3 or more, a significant positive exposure-response trend was observed for cosmic radiation and number of time zones crossed that were robust to multiple model assumptions. In addition, among high-parity women a non-statistically significant positive trend was observed for hours spent traveling during the standard sleep interval. The high correlation among exposure metrics made it impossible to assess whether radiation and transmeridian travel (which may be a proxy for circadian disruption) were independently associated with breast cancer. Pukkala et al. (2012) found no association between breast cancer risk and number of flights crossing at least 4, 5, or 6 time zones.

Among the low-utility studies, Reynolds et al. (2002) reported statistically significant elevated risks of breast cancer for three exposure metrics (79% for flying on international vs. domestic flights, 57% for at least 15 years of employment vs. less than 15 years, and 72% for working as a flight attendant before the age of 25 vs. beginning work at age 25 or later). Linnersjö et al. (2003) reported a non-statistically significant 80% excess risk of breast cancer among those flying on high-altitude long-distance flights compared to those who did not; and a non-statistically significant threefold increased risk for flying more than 5,000 block hours (total time from flight departure to arrival, including time on the ground) in high-altitude long-distance flights, based on small numbers of exposed case subjects.

#### Key issues

The major issues in these studies were exposure assessment, study sensitivity, and potential confounding. Exposure to crossing time zones is difficult to study, as this specific information typically is not captured by airlines in administrative records. Furthermore, potential co-exposures, such as cosmic radiation, are usually highly correlated with exposure to transmeridian travel. Exposure proxies used in these studies were less than satisfactory, as “international flights” can include flights within only one or two time zones; without more information, this proxy is difficult to interpret. Similarly, data on block hours might indicate years of service or flight intensity, but yield little information about time zones. Self-reported lifetime total number of time zones crossed is likely to be highly misclassified. Such uncertainty regarding exposure assessments resulted in low sensitivity to differentiate levels of exposure.

#### Chance, bias, or confounding

Alternative explanations for the reported increased risks of breast cancer from transmeridian travel cannot be completely ruled out. Neither of the low-utility studies that reported elevated risks (Reynolds et al. 2002, Linnersjö et al. 2003) had sufficient information to control for potential confounding. In Pinkerton et al. (2016), low cumulative exposure, potential exposure misclassification, and low participation in the nested study may have contributed to the finding of elevated risk in the small group of women with parity of at least 3. An evaluation of the final models among cohort members with at least 3 births revealed little confounding of the exposure estimates by any of the covariates.

## 3.5 NTP level-of-evidence conclusion

There is strong, but not sufficient evidence from cancer epidemiology studies that persistent night shift work (e.g., frequent and long-term, or working a large number of night shifts over a lifetime, especially in early adulthood) causes breast cancer in women.

In general, female night shift workers found to be at elevated risk for breast cancer are those who started working before age 30 and worked at least 3 times/week and for 10 or more years; however, the exact conditions (e.g., number of years worked) which put an individual at increased risk may depend on the specific combination of these metrics (e.g., duration may be longer if frequency is less) or other factors. Although the evidence is strong, it does not quite meet the criteria for “sufficient,” as bias cannot be completely ruled out and two informative cohort studies did not find an association between night shift work and breast cancer risk (Li et al. 2015, Vistisen et al. 2017).

The epidemiology data from the night shift work studies are unable to evaluate the roles of LAN, sleep disturbances, or other factors related to shift work in breast cancer carcinogenicity. In general, behaviors of daily life related to stress, such as smoking or alcohol consumption, were considered in the night shift work studies and these factors did not explain the risk.

The data available from epidemiological studies are inadequate to evaluate the relationship between breast cancer and exposure to LAN (both indoor and outdoor).

Although some studies found positive associations for specific metrics of LAN and an increased breast cancer risk, overall, the evidence across studies for specific metrics of indoor light was inconsistent and there are concerns whether satellite data is measuring individual exposure to LAN or other behaviors of daily life that may correlate with the satellite data.

The data available from epidemiological studies are inadequate to evaluate the relationship between human cancer and transmeridian travel.