# 2 Light at Night and Night Shift Work: Circadian Disruption Studies

This section provides an overview of the literature on LAN and night shift work and circadian disruption, primarily as assessed by melatonin suppression and altered clock gene expression as these are primary factors in the proposed mechanisms of carcinogenicity. Studies on potential effects on cancer are discussed in Sections 3, 4, and 5, and studies on biological effects related to cancer are discussed in Section 6. Studies of offshore shift workers were not included in the review as these workers may have additional stresses (such as absence of family and social contact) that may affect circadian rhythms (Folkard 2008).

## 2.1 Biomarkers and characteristics of circadian disruption

As mentioned in Section 1, daily oscillations or rhythms of physiological and behavioral processes occur in humans and almost all other species. Figure 2-1 depicts the timing of some of the major circadian rhythms. These include melatonin, cortisol, body temperature, and clock gene expression, which have been used as biomarkers to measure the extent of circadian disruption among shift workers or people exposed to LAN. Ideally, these biomarkers should be physiological rhythmic variables, reproducible, and reliable (Touitou et al. 2017). Altered sleep due to LAN and shiftwork is related to circadian disruption, and thus is briefly reviewed, as well as behavioral (i.e., non-photic zeitgebers) models of circadian disruption. A limitation is that few studies measured multiple markers of circadian disruption and thus could not evaluate uncoupling of biomarkers.

Figure 2-1 The circadian clock

This figure depicts the face of a clock that shows the times of sun light and times of darkness, surrounded by physiological effects at different times of the day. During the early morning, which is between midnight and 6 AM when there is little natural light, sleep is deepest and the body temperature is lowest. During mid-morning, which is around 6 AM, when natural light is starting to increase, cortisol is released. During late morning, which is from 6 AM to 12 noon, when natural light is high, blood pressure increases the fastest and alertness is high. During the early afternoon, which is between noon and 6 PM, when natural light is high, coordination and reaction times are at their peak. At mid-afternoon, around 6 PM, when natural light is decreasing, body temperature peaks. During night time, which is from 6 PM to midnight, when there is little natural light, blood pressure peaks and melatonin is secreted.

Figure adapted from Nobel Prize 2017, with permission.

### 2.1.1 Melatonin

As discussed in Section 1.1, melatonin secretion and rhythms are controlled by the SCN and are suppressed or shifted by exposure to LAN. It is a modulator (albeit not the only modulator) of the central and peripheral circadian clocks as well as an important regulator of numerous biological processes in tissues and organ systems, including the breast (Slominski et al. 2012, Reiter et al. 2014, Hill et al. 2015, Smolensky et al. 2015). In humans, melatonin also regulates the sleep-wake cycle by chemically causing drowsiness and lowering the body temperature by fine-tuning vascular tone in the skin (Brown 1994, Kräuchi et al. 2006). Melatonin production (e.g., changes in amplitude, duration, and timing) is considered to be a useful biomarker of circadian dysregulation. Compared to other circadian biomarkers, it is less influenced by external factors. It is also a regulator of the hypothalamic-pituitary gonadal axis and gonadal function (Mirick and Davis 2008, Bonde et al. 2012). In normally entrained individuals, plasma melatonin levels are low during the day and start to increase in the evening (~2 hours before bedtime), peak in the middle of the biological night (midnight to 5:00 AM), and then decrease rapidly. The peak of melatonin levels is approximately 2 hours before the nadir of the core body temperature rhythm (~5:00 AM) and approximately 4 to 6 hours before the crest of the cortisol rhythm (Dijk et al. 2012, Touitou et al. 2017).

Melatonin can be measured in the saliva, urine (as its major metabolite, 6-sulfatoxymelatonin [aMT6s]), plasma, or blood. Morning urinary aMT6s accounts for 70% of the previous night total plasma melatonin and thus is related to peak nocturnal melatonin production (Schernhammer et al. 2004). Several studies have found that a single morning urinary melatonin sample or serum melatonin is a reliable marker for assessing melatonin levels over time (6 months to up to 5 years) (Schernhammer et al. 2004, Nogueira et al. 2013). Serum or plasma melatonin has a short half-life and its measurement reflects the amount of melatonin circulating at the time of sample collection (Nogueira et al. 2013). Measurement of plasma melatonin at multiple time intervals can be useful for determining time of melatonin onset or peak melatonin, duration of melatonin secretion, and total amount of melatonin secretion (see below); however, multiple blood draws are impractical for epidemiological studies. Salivary melatonin levels and time of peak melatonin highly correlate with serum melatonin levels except in people with low melatonin levels. Similar to plasma melatonin, multiple sampling is required; however, a major advantage is that the testing is non-invasive and participants can collect their own samples (Mirick and Davis 2008). However, there is considerable interindividual variability in both the peak and total levels and circadian rhythm of melatonin (Slawik et al. 2016). Potential sources of variation of melatonin levels include season or length of day (usually higher in the winter), age, sex, menstrual cycle phase, smoking, alcohol consumption, socioeconomic status, and body mass index (Davis et al. 2001b, Hurley et al. 2013, Nogueira et al. 2013, Wada et al. 2013).

Figure 2-2 Cosinor modeling of melatonin metabolite (aMT6s) production over time for day and night workers

amp = amplitude or the distance between the maximum and mesor; aMT6s = 6-sulfatoxymelatonin; h = hour; m = mesor or the circadian mean; t = peak time (for day and night workers).

The figure depicts a graph of the urinary concentration of the melatonin metabolite, 6-sulfatoxymelatonin or aMT6s, correct for the creatinine concentration over the time of day for both day workers and night workers. In day workers the level of melatonin metabolite starts low at midnight, then peaks at 6 AM and reaches a minimum concentration at 6 PM. In night workers, however, the level of melatonin metabolite overall is lower compared to day workers and it is shifted forward so that the peak and the minimum concentrations are a few hours after the peak and minimum concentrations seen in day workers.

The circadian rhythm production of melatonin over time can be modeled as a cosine wave in which the mesor is the average level of melatonin (see Figure 2-2). The amplitude is the difference between the lowest and highest level of melatonin (e.g., fluctuation) over time, and the acrophase is the time of the highest or peak melatonin levels (Gómez-Acebo et al. 2015). The circadian phase of melatonin rhythms can also be assessed via dim light melatonin onset (DLMO), which is the timing of the onset of melatonin secretion above a threshold level (prior to bedtime) when collected under dim light conditions (Lewy 1999) and is the most sensitive and direct index for identifying an individual’s biorhythm. Studies using cosinor modeling have an advantage over those using single void samples in that the latter have the potential for confounding due to circadian phase differences in individuals (e.g., if night shift workers adapt to their shift schedule, a single void sample would come at a different point in their cycle compared with day workers) (Papantoniou et al. 2014).

### 2.1.2 Clock and clock-controlled gene expression

Clock gene expression can also be used to evaluate circadian disruption. In human blood leukocytes, mRNA levels of the negative regulators of the peripheral clock — PER, CRY1 and CRY2 — peak in the morning whereas the mRNA levels of the positive regulator, BMAL1, peak in the evening or midnight; CLOCK (also a positive regulator) has not been found to have rhythmicity in blood leukocytes in most population studies (reviewed by Reszka et al. 2013). One study of normally synchronized healthy humans found interindividual variability of clock gene expression profiles in peripheral blood lymphocytes (Teboul et al. 2005).

Two recent studies report methods to accurately estimate internal circadian time based on the rhythmic expression of clock and clock-associated genes from a single blood sample (Wittenbrink et al. 2018) or a single skin sample (Wu et al. 2018). These studies identified partially overlapping sets of blood- and skin-based transcript biomarkers (CRISPLD2, CRY1, ELMO2, FKBP4, HSPH1, KLF9, LGALS3, NR1D1, 2, and PER1, 2, 3, were selected by Wittenbrink et al. and ARNTL, HLF, NPAS2, NR1D2, and PER2 by Wu et al.) that were as accurate as the dim-light melatonin onset (the current gold standard method) and much more practical and economical.

### 2.1.3 Other circadian biomarkers: Cortisol, core body temperature

Cortisol is a hormone that is regulated by the hypothalamus-pituitary-adrenal axis, and has anti-inflammatory, metabolic (gluconeogenesis), and immunosuppressive effects (Ulhôa et al. 2015). Under normal conditions, cortisol levels peak in the early morning around awakening (cortisol awaking response) and decline throughout the day; they are lowest at the beginning of nocturnal sleep (Boivin and Boudreau 2014). Cortisol is also a putative endogenous circadian entrainer of peripheral clocks along with other glucocorticoids (Mavroudis et al. 2012). Glucocorticoids induce the expression of clock genes by binding to the glucocorticoid receptor element in these genes, which can lead to downstream regulation of the peripheral clock network. Cortisol levels can be influenced by stress, and chronically elevated cortisol levels have been associated with adverse health outcomes such as cardiovascular disease (as reviewed by Griefahn et al. 2006).

Core body temperature is at its highest one to two hours before bedtime; afterwards it decreases, reaching its lowest temperature approximately two hours prior to waking, and then steadily increases during the day (Boivin and Boudreau 2014). Although mammals maintain a generally constant body temperature and normally do not entrain to external environmental temperature cycles, the SCN drives subtle circadian rhythms in body temperature (Buhr et al. 2010). Peripheral clocks in mammals are sensitive to these subtle changes such that body temperature is recognized as an important timing cue for peripheral but not central clocks (see Section 1.1).

### 2.1.4 Sleep

Sleep is regulated by an interaction between (1) the homeostatic process, which corresponds to the rhythms of sleep pressure (which increases during the wake period and decreases during the sleep period), and (2) the circadian process, which corresponds to rhythms of sleep propensity during the biological day. These two systems are linked and changes in one system affect the other. Sleep parameters such as sleep onset latency, sleep efficiency, sleep duration, and REM sleep latency vary with the circadian phase and depend on the timing of sleep relative to core body temperature and melatonin rhythms (Boivin and Boudreau 2014, Samuelsson et al. 2018). As mentioned previously, melatonin production peaks in the evening (prior to bedtime). Although melatonin production, which starts to increase in the evening prior to bedtime, is not required to sleep, in experimental studies, elevated melatonin production has been associated with increased sleepiness (Burch et al. 2005).

## 2.2 Light at night and circadian disruption biomarkers

This section focuses primarily on studies of acute melatonin suppression and chronic circadian disruption (as measured by altered or desynchronized clock gene expression) in humans and experimental animals since these effects are linked with tumor growth (see Section 6).

### 2.2.1 Human studies of melatonin suppression and clock gene expression

LAN at an applicable wavelength, sufficient level and duration, and appropriate timing can acutely suppress melatonin, which can be measured by the timing and amount of nocturnal melatonin production. In addition, the total light experience (or photic history) as well as individual sensitivities to light can modify how light will affect the circadian system, including melatonin suppression and clock gene expression (Figueiro 2017, Lunn et al. 2017). Sleep disruption is also an important downstream effect of exposure to LAN (Smolensky et al. 2015).

#### Light characteristics related to circadian disruption

Nighttime melatonin suppression can occur after exposure to light with wavelengths from 420 to 600 nm (Brainard et al. 2001); however, short-wavelength light or “blue” light wavelengths are more effective than longer wavelengths in reducing daily melatonin production (Brainard et al. 2001, Figueiro et al. 2017). For example, one experimental study in humans found that exposure to narrowband short-wavelength light (peak wavelength = 460 nm) induced a two-fold greater melatonin suppression and two-fold greater phase delay compared to exposure to narrowband middle-wavelength light (555 nm) of equal photon density (Lockley et al. 2003). Peak sensitivity for melatonin suppression occurs at 446 to 474 nm, with a peak sensitivity (i.e., lowest irradiance required to elicit a constant criterion response) occurring at 460 nm (Brainard et al. 2001, Figueiro et al. 2017).

Although short-wavelength light is more effective in inducing circadian disruption, the human circadian system is also sensitive to ordinary room light levels. Based on a model developed by Rea and colleagues (as reviewed by Figueiro et al. 2006) using experimental data, a potential threshold for melatonin suppression (~10% melatonin suppression) would be ~30 lux of warm white light at the cornea after 60-minute exposure (see Figure 2-3). This model is somewhat consistent with three studies of volunteers which reported that evening exposure to indoor lighting conditions typically found at the workplace or home can cause acute melatonin suppression. A study by Gooley et al. (2011) reported that exposure to electric light (range 60 lux to 130 lux at the eye) before bedtime induced a delay in melatonin onset, resulting in shortened nighttime melatonin duration and decreased nighttime melatonin levels.

Figure 2-3 Human nocturnal melatonin suppression as a function of circadian light stimulus

The figure depicts a scatter plot with a line of regression of the percentage of nocturnal melatonin suppression over different intensities of either incandescent light or daylight designated as circadian stimulus or CS on the x-axis. At low intensities of both sources of light, the percent of melatonin suppression is low, while suppression increases as the intensity of light increases. Incandescent light is less efficient at suppressing melatonin than daylight at all levels of intensity.

Logistic models using plasma melatonin data from volunteers exposed to 6.5 hours of light (ranging from 3 to 9,100 lux at the eye) during the early biological night predicted that half-maximal melatonin suppression occurs in the range of indoor light intensity (~50 to 130 lux at the eye) (Zeitzer et al. 2000). This study also found that circadian phase shifting occurred in a dose-dependent manner with light exposure of 15 lux and 500 lux (at the eye). Wahnscaffe et al. (2013) reported that 30 minutes of exposure to different types of normal lighting conditions containing varying amounts of blue light – office daylight white (500 lux), bathroom daylight white (130 lux), hall daylight white (500 lux), and “Planon” (an experimental light prototype) warm white (500 lux) – one hour before bedtime reduced salivary melatonin both during and after exposure to light in healthy men and women. Melatonin levels were not reduced after exposure to bedroom yellow light (130 lux). The comparison in this study was melatonin levels from constant exposure to dim light (less than 10 lux) from 7:00 PM to midnight. In contrast to polychromatic light, under controlled conditions (dilated pupils while subjects’ heads rested in an apparatus that provided a uniform, patternless stimulus that encompassed the entire visual field) exposure to 0.4 to 3.3 lux of monochromatic blue light (440 to 480 nm) for 1.5 hours suppressed melatonin by 50% in healthy humans (Brainard et al. 2001, Glickman et al. 2002).

The duration of LAN exposure needed to induce circadian disruption depends on other characteristics of light such as wavelength, timing, and level. For example, Nagare et al. (2018) reported that exposure duration was a significant factor in inducing melatonin suppression in subjects exposed to two different types of white light (circadian stimulus of 0.25 at the eye level) for one to four hours.

The timing of light can influence whether light advances (i.e., shortens the 24-hour cycle) or delays the biological clock. Exposure to light in the morning (after the nadir for core body temperature) causes a phase advance (i.e., melatonin peaks earlier than normal) whereas exposure to light at the end of the afternoon and early evening (prior to the nadir for core body temperature) causes a phase delay (Touitou et al. 2017).

The circadian clock is sensitive to the entire 24-hour pattern of light exposure, and recent studies show that the amount of daylight exposure is also important in regulating circadian rhythms. Light levels in indoor offices are typically below what is needed for activation of the circadian system. Some experimental studies suggest that blue light exposure during the daytime or morning can help reduce LAN-induced melatonin suppression (Kozaki et al. 2015, 2016, Nagashima et al. 2018) and improve measures of sleep quality and mood (Viola et al. 2008). In addition, night-time sensitivity to light-induced circadian disruption (usually measured by melatonin suppression) is influenced by light exposure during the day (reviewed by Figueiro 2017 and Lunn et al. 2017).

#### Individual sensitivities to LAN

Individual sensitivities related to age, sex, chronotype, and polymorphisms in clock genes can affect sensitivity to LAN. Circadian photoreception decreases as a result of aging; middle-aged adults have only 50% of circadian photoreception compared with children. Loss of circadian photoreception is due to age-related increases in crystalline lens light absorption and decreases in pupil area (Turner and Mainster 2008). Several experimental studies have shown that children are more sensitive (approximately two-fold) to LAN-induced melatonin suppression than middle-aged adults after exposure to similar light conditions (reviewed by Turner and Mainster 2008, Higuchi et al. 2014). Self-luminous displays induced a greater degree of melatonin suppression (23%) in teens (aged 15 years to 17 years) after 1 hour of exposure than college students or middle-aged adults (Figueiro and Overington 2016). Moreover, some studies suggest that children may be more sensitive to lower light conditions and that the youngest children have the greatest circadian sensitivity. Higuchi et al. (2014) reported that melatonin secretion was significantly suppressed in school-aged children but not adults (mean age ~42 years) exposed to room light conditions (140 ± 82.7 lux). To ascertain the effect of LAN on puberty, male adolescents were grouped by Tanner staging as pre- to mid-pubertal children (age 9.1 to 14.7 years) and late to post-pubertal adolescents (age 11.5 to 15.7 years); the pre- to mid-pubertal group experienced greater melatonin suppression from evening light exposure at 15, 150, and 500 lux than late to post-pubertal adolescents (Crowley et al. 2015).

Chronotype describes people as being “morning types,” who have an earlier sleep schedule and usually earlier circadian phase and “evening types,” who have a later sleep cycle and usually later circadian phase. It can be measured using questionnaires such as the Munich ChronoType Questionnaire and Horne-Østberg morningness-eveningness questionnaire (Roenneberg et al. 2007, Roenneberg and Merrow 2007). Some studies suggest that morning types and evening types experience different light profiles; morning types may spend more time exposed to sunlight (bright light) with less exposure to light in the evening than evening types; exposure to bright light during the day may increase the amplitude of the light-dark cycle (difference between daylight and nighttime light intensity). There is also a spectrum of responses within the morning and evening type chronotypes with some individuals having more extreme circadian phases. Morning types with very early circadian phases are thought to have a shorter endogenous period than 24 hours; therefore, without proper entrainment, these subjects will continue to advance their circadian phase progressively each day. When these subjects were exposed to light close to the DLMO, it produced a phase delay and might prevent further advancement of their circadian phase. The converse was found for evening types with very late circadian phases with endogenous periods longer than 24 hours. In this case, light exposure 10 to 12 hours after the DLMO produced a phase advance and may prevent further delay of their circadian phase. Other morning and evening types have intermediate circadian phases, and differences in sleep patterns may not be related to circadian phases and could be related to homeostatic sleep regulation (Goulet et al. 2007 and studies reviewed by Goulet et al. 2007).

#### Sources of light exposure potentially associated with circadian disruption

Several randomized cross-over studies of teens or young adults have shown that the use of electronics with self-luminous displays (such as computers or tablets) prior to bedtime can acutely suppress melatonin onset, disrupt sleep, or decrease morning alertness (Cajochen et al. 2011, Figueiro et al. 2011, Wood et al. 2013, Chang et al. 2015, van der Lely et al. 2015, Figueiro and Overington 2016, Green et al. 2017, Chinoy et al. 2018) (see Table 2-1 for a description of these studies). These studies suggest that blue light is a main factor in suppressing melatonin since a stronger association with exposure to LAN was observed when subjects were exposed to electronics using blue light goggles (Figueiro et al. 2011, Wood et al. 2013) or computer screens with short wavelengths (Green et al. 2017). In addition, the use of goggles that blocked blue light attenuated the melatonin suppression (van der Lely et al. 2015). A study of middle-aged adults found that subjects using smart phones emitting blue light had delayed melatonin onset but similar melatonin levels as subjects using smart phones with non-blue light (Heo et al. 2017). In addition to wavelength, the amount of circadian disruption from self-luminous electronics may depend on the duration of the exposure and prior light exposure. Tablet use prior to bedtime for two hours but not one hour induced melatonin suppression in a small study of teens and young adults (Wood et al. 2013). Teenagers exposed to bright light (for 6.5 hours) during the daytime and who used tablets prior to bedtime had similar salivary melatonin levels as those reading a physical book, suggesting that bright light during the day-time can attenuate induction of nocturnal melatonin suppression by short-wavelengths emitted from electronic devices during evening exposure (Rångtell et al. 2016). Findings from a cross-sectional study found that young adults with delayed sleep schedules had a later DLMO and reported more time using light-emitting devices (cell phones, tablets, TVs, computers) before bedtime than control subjects (Van der Maren et al. 2018).

Table 2-1 Studies of melatonin suppression and exposure to electronics with self-luminous displays

Study | Study design/population | Exposure | Results
Cajochen et al. 2011; Switzerland | Randomized cross-over; Young adult males; Aged 19–35 yr | 5-hr exposure; - White LED backlit; - Non-LED screen; - LED screen with more than twice as much 464 nm light emission than a white non-LED-backlit screen | LED vs. non-LED; - ↓ nighttime salivary melatonin
Chang et al. 2015; United States | Randomized cross-over; 12 healthy young adults; 25 ± 2.9 yr | Reading 4 hr before bedtime for 5 consecutive nights with fixed sleep times; - Light-emitting eBook; - Printed book | eBook reader vs. printed book; - ↓ nighttime plasma melatonin & phase shift; - sleep problems: ↑ time to fall asleep, ↓ evening sleepiness, & ↓ morning alertness
Chinoy et al. 2018; United States; Follow up of Chang et al. 2015 | Randomized cross-over; 9 young healthy adults; 25.7 ± 3.0 yr | Reading 4 hr before bedtime for 5 consecutive nights with self-selected sleep times; - Light-emitting eBook; - Printed book | eBook reader vs. printed book; - ↓ nighttime plasma melatonin & delayed onset; - sleep problems: later self-selected bedtime ↓ evening sleepiness, and ↓ morning alertness
Figueiro et al. 2011; United States | Cross-over; 21 subjects; age 28 ± 9.9 yr | 1 hr at midnight to computer monitor; - Alone (33 lux at eye); - + blue goggles (short wavelength 470 nm, 40 lux); - + orange goggles (“dark” control) | LAN vs. dark control; - ↓ melatonin blue-light goggles; - ↓ (not significant) melatonin computer monitor only
Figueiro and Overington 2016 | 20 adolescents; Aged 15 to 17 yr | Self-luminous devices starting 3 hr prior to bedtime; 1^st^ night: orange goggles (“dark”); 2^nd^ night: 1 hr orange goggles + 2 hr without goggles; Melatonin collected at 1 (T1), 2 (T2), and 3 hr (T3) from start of study | LAN vs. T1; - ↓ melatonin at T2 and T3; highest suppression T3
Green et al. 2017; Israel | Random cross-over; 19 subjects; Aged 24.3 ± 2.8 yr | Exposure for 2 hours at night to computer screen; 3 days rest between exposures; Light intensity: low (LI): vs. high (HI); Wavelength: short (SWL) vs. Long (LWL); Four conditions; LI/SWL, HI/SLW, LI/LWL, HL/LSW | Melatonin measured at 3 time points; SWL: Greatest melatonin suppression irrespective of intensity
Heo et al. 2017; South Korea | Randomized, cross-over; 22 middle-aged adult males | Smart phones with and without blue light; Played smart phone video games from 7:30 PM to 10:00 PM | Blue vs. non-blue light; - Later onset of serum melatonin (phase delay) but no difference in melatonin levels; Blue light also affected sleep, body temperature, and performance
Rångtell et al. 2016; Switzerland | Randomized, cross-over; 14 healthy adults | Reading for 2 hr (before bedtime) following 6.5 hr exposure to constant bright light (~569 lux); - Light-emitting eBook; - Printed book | LED tablet vs. printed book; No difference in salivary melatonin or sleep parameters
van der Lely et al. 2015 | Randomized cross-over; 13 male high school students; Aged 15–17 yr | LED computer screen with clear lens (CL) glasses (control); LED computer screen + blue light blocking glasses (BB) | CL vs. BB glasses during late evening; - ↓ melatonin levels prior to sleep and attenuated evening rise in melatonin; - ↑ subjective sleepiness but no effect on sleep measures; - ↓ psychomotor performance; Significant interaction of sampling time & glasses for melatonin and borderline interaction of sampling time & glasses for subjective sleepiness
Van der Maren et al. 2018 | Cross sectional; 28 subjects; Aged 18–28 yr; 14 with delayed sleep schedule (later than midnights, complaints); 14 matched controls | Observational measured light recordings, circadian phase (salivary DLMO) and sleep | Delayed vs. control; - Later wake time and shorter sleep duration; - 2 hr later than DLMO; - ↑ exposure to blue light at night and greater use of light-emitting devices (mainly computers) 3 hr prior to bedtime; - ↓ exposure to blue light during the day
Wood et al. 2013 | Randomized cross-over 13 volunteers; Aged 18.9 ± 5.2 yr | 1–2 hr exposure to tablets at night; - Highest brightness; - + blue light goggles; - + orange light goggles | Tablets vs. dark control; - ↓ melatonin levels for tablet + blue light at 1 and 2 hr; - ↓ melatonin levels for tablet at highest brightness at 2 hr but not 1 hr; - No effect with tablets + orange light

BB = blue-light blocking; CL = clear lenses; DLMO = dim light melatonin onset; HI = high light intensity; hr = hour; LED = light emitting diode; LI = low light intensity; LWL = long wavelength light; SWL = short wavelength light; yr = year.

Most studies on bedroom lighting did not find an association between indoor LAN and melatonin suppression; however, the few available studies may not have had the power to detect an association and light exposure during the day was not measured or controlled in these studies. A cross-sectional study of adolescents with self-reported behaviors on sleep patterns and exposure to bedroom lighting found that urinary melatonin metabolite levels were lower among participants who experienced sleep interruption and turned on lights but not among participants who did not turn on lights (Hersh et al. 2015). However, self-reported measures of bedroom light (e.g., light outside the bedroom, electronic or TV use) did not affect metabolite levels. Levallois et al. (2001) reported that nocturnal urinary melatonin levels were somewhat lower, but not significantly so, among individuals reporting light use at night compared to those not using light; no differences in nocturnal melatonin levels were found for those exposed to nocturnal bedroom light greater than and less than 50 lux (measured using a light meter; details on whether this was at the eye were not provided). No association was found between melatonin suppression and turning lights on during the night or ambient light in the bedroom ≥ 10 lux; however, the studies might not have had enough statistical power to detect an effect as the levels of ambient light were low (median = 2.1 lux), the proportion of nights with light ≥ 10 lux was low, and the number of times light was turned on at night was low (median = 0, range = 0 to 6) (Davis et al. 2001a). A study of Japanese children also did not find an association between bedroom lighting and morning urinary melatonin levels (Wada et al. 2013). An experimental study found that eight-hour exposure to bedroom light intensity (50 lux at the eye) prior to bedtime caused melatonin suppression compared to exposure to dim light (< 3 lux); suppression was reduced using a LED light with selective reduction in short wavelengths (Rahman et al. 2017).

The California Teacher Study found a small, non-statistically significant inverse relationship between outdoor LAN (measured using satellite imagery data obtained from the U.S. Defense Meteorological Satellite Program [DMSP]) and 24 hour urinary aMT6s levels (Hurley et al. 2013); a limitation of the study was that they did not directly measure nocturnal melatonin suppression (e.g., the investigators did not measure first urine void). Studies of light entering sleeping areas after residential lights have been turned off (i.e., light trespass) generally indicate that, due to low light levels received at the cornea through closed curtains and further through closed eyelids, light trespassing into bedrooms is likely ineffective for melatonin suppression during sleep (Figueiro et al. 2006).

#### Clock gene expression studies

Blue light has been reported to alter clock gene expression. Non-ocular exposure to blue light phototherapy (total irradiance including room light at 5,500 lux to 7,200 lux) decreased the expression of BMAL1 and increased the expression of CRY1 in jaundiced full-term neonates (aged 12 days to 27 days) after 24 hours of treatment with eyes covered compared to levels before treatment (Chen et al. 2005). Plasma melatonin levels were also decreased; however, this study could not evaluate whether there is a relationship between decreased melatonin levels and altered clock gene expression because samples were only taken one time before and one time after exposure. No change in clock gene expression was observed in infants not given phototherapy after covering their eyes for 24 hours (total irradiance from room lights was 72 lux to 84 lux). A study in adult volunteers using lower doses and shorter duration of monochromatic light (12.1 µW/cm^2^ for 460 nm and 10.05 µW⁄cm^2^ for 550 nm, which is in the range of 70 lux to 85 lux for 2 hours) found that exposure to blue light (460 nm) in the evening significantly increased PER2 expression in oral mucosa samples measured 24 hours after exposure; exposure to green light (550 nm) caused a lower non-significant increase in PER2 gene expression (Cajochen et al. 2006).

### 2.2.2 Experimental animal studies on melatonin suppression and clock gene expression

The circadian systems of nocturnal rodents and diurnal humans differ in both their spectral and absolute sensitivities to light (Bullough et al. 2006). In terms of absolute sensitivities, nocturnal rodents are 3,000 to 10,000 times more sensitive to LAN-induced circadian disruption than humans, as measured by the ratio of the thresholds for melatonin suppression and for circadian phase shifting (Bullough et al. 2006, Figueiro 2017). Although diurnal rodents (e.g., ground squirrels, Eastern chipmunks) have similar sensitivities to light as humans, they are rarely used as models to investigate the health consequences of LAN. Nevertheless, when the difference in sensitivity is accounted for, nocturnal rodents and humans show similar levels of light-dependent circadian disruption as measured by the cross correlation between light and dark and activity and rest patterns (Radetsky et al. 2013, Rea and Figueiro 2014).

Most studies of circadian disruption in animals used constant dim LAN (< 1 lux) or constant bright LAN (≥ 300 lux), while a few studies investigated the effects of exposure to a 30-minute bright LAN pulse during the middle of the night (see Sections 5 and 6). These studies show a wide range of psychological effects and physiological biomarkers of LAN-induced circadian disruption including melatonin suppression, altered clock gene expression, and biological effects related to both cancer and non-cancer outcomes (see Section 6 for mechanistic studies related to carcinogenicity; non-cancer outcomes are beyond the scope of this evaluation).

#### Melatonin suppression

The relationship between LAN exposure and melatonin in experimental animals appears to be particularly complex and is influenced by the pattern and intensity of LAN exposure as well as the spectrum of light exposure during the day (Travlos et al. 2001, Cos et al. 2006, Blask et al. 2009, Dauchy et al. 2014, Dauchy et al. 2016). These studies show that melatonin suppression is dose-dependent but exposure to dim LAN (0.2 lux) can reduce melatonin secretion by 65%. Exposure to dim indoor lighting during the day is also associated with greater circadian phase shift responses to LAN. Travlos et al. (2001) reported that female F344 rats exposed to intermittent light pulses every two hours for one night showed an average melatonin suppression of 65% compared to controls. When exposure to light pulses continued for 2 or 10 weeks, the overall suppression was reduced to 35% and 25%, respectively, with a slight phase advance in the melatonin rhythm. However, rats exposed to light pulses every two hours at night for 26 weeks had serum melatonin levels that were three-fold higher than controls, which suggests an adaptive process that is consistent with the diminishing effect observed in the first 10 weeks. This study also reported evidence that pinealectomized rats were able to reestablish a melatonin cycle, suggesting that melatonin was produced by organs or tissues other than the pineal gland.

Exposure to bright sunlight affects nocturnal melatonin synthesis by increasing nocturnal melatonin secretion and decreasing vulnerability to suppression and circadian disruption by LAN (Dauchy et al. 2013, Smolensky et al. 2015). Studies in male albino Buffalo rats or nude rats demonstrated that daytime exposure to broad-spectrum cool white fluorescent lighting filtered through blue-tinted cages or to LED lights enriched in the blue portion of the visible spectrum (465 to 485 nm) resulted in a 6- to 7-fold increase in nighttime peak plasma melatonin levels and increased the duration of the nighttime melatonin signal compared to rats held in clear cages and exposed to cool white fluorescent lights during the day (Dauchy et al. 2013, Dauchy et al. 2015, Dauchy et al. 2016, Dauchy et al. 2018). Moreover, mean or total plasma or blood levels (over 24-hr day) of total fatty acids, linoleic acid, acid-gas levels, glucose, corticosterone, and leptin were lower in rats exposed to daytime blue light compared to the controls, suggesting that daytime blue light affects circadian regulation of rodent metabolism. These data, in combination with the studies of LAN, suggest that the totality of the daily light environment includes complementary exposures that contribute to circadian disruption (i.e., too little sunlight during the day and too much LAN).

#### Clock gene expression

LAN exposure also altered clock gene expression in the SCN and peripheral tissues of experimental animals (Table 2-2). Most studies used mice, and Clock, Bmal1, Per1, Per2, and Cry1 were the most frequently studied genes. Several studies also investigated clock proteins. Although all of the studies show that LAN exposure clearly affects expression of some clock genes and proteins in peripheral tissues and the central clock, not all genes investigated were altered in all tissues. These studies used different designs and results varied by light source and intensity, tissues, species, and the specific genes or proteins studied. These data may also reflect the functional redundancies and complexity built into the molecular clockwork circuitry, which include at least two functionally redundant isoforms for all clock genes except Bmal (Schibler et al. 2015).

Table 2-2 Effects of LAN exposure on clock gene expression

Reference | Species (sex) | Light exposure; day:night hr (day:night lux) | Endpoint; Clock genes and proteins; Tissue(s) | Results (gene/protein expression)
Gubareva et al. 2016 | SHR mice | 12:12: C; 24:0^a^ | Proteins: CLOCK, BMAL1, CRY1; Skin | CLOCK, CRY1: no effect; BMAL1: increased
Fonken et al. 2013a | Swiss Weber mice (M) | 14:10 (150:0): C; 14:10 (150:5) | Genes: Clock, Bmal1, Per1, Per2, Cry1, Cry2, Rev-erbα; Proteins: CLOCK, BMAL1, PER1, PER2; Hypothalamus/SCN, hippocampus, liver, fat | Hypothalamus/SCN; - Clock, Bmal1, Cry1, Rev-erbα: no effect; - Per1, Per2, Cry2: reduced; - CLOCK, BMAL: no effect; - PER1, PER2: reduced; Liver; - Clock, Rev-erbα: no effect; - Bmal1, Per1, Per2, Cry1, Cry2: reduced; Hippocampus and fat: no effect
Shuboni and Yan 2010 | CD1 mice (M) | 12:12 (300:1): C; 12:12 (300:20): dim light with/without 30 min LAN pulse (300) | Genes: Per1, Per2; Proteins: PER1; SCN | Dim LAN; - PER1: increased at baseline but not at peak (overall decrease in amplitude of PER1 rhythm); - Per1 and Per2: increased; LAN pulse; - Per1 and Per2: increased in control and dim LAN treatment groups but lower in the dim LAN group
Bedrosian et al. 2013 | Siberian hamsters (F) | 16:8 (150:0): C; 16:8 (150:5) | Proteins: BMAL1, PER1, PER2; SCN, hippocampus | SCN; - BMAL1: no effect; - PER1, PER2: abolished peak expression; Hippocampus; - BMAL1, PER1: no effect; - PER2: reduced peak expression
Honda et al. 2017 | Broiler chicks (M) | 12:12: C; 12:12: white:blue light; 24:0^a^ white light | Genes: Bmal1, Cry1, Per3; Diencephalon, liver, skeletal muscle | Continuous white light; - Bmal1, Cry1, Per3: altered mRNA levels in all three tissues; White:blue light: no effect

C = control; F = female; M = male.

a Continuous light.

## 2.3 Shift-work and circadian disruption biomarkers

This section reviews studies of night shift workers and melatonin suppression, clock gene expression, and shift work tolerance or adaptation.

### 2.3.1 Studies of night shift workers

Night shift work includes permanent and rotating night shift work, which are discussed in Section 1, and can include many different types of scheduling patterns including consecutive shifts in either forward (i.e., clockwise or day to evening to night shifts) or backward (i.e., counterclockwise or night to evening to day shifts) directions, consecutive nights on a specific shift (e.g., morning, evening, or night), and variations in the number of days off between shifts. Most biomonitoring studies have not compared effects for different types of rotating shifts; however, a few studies suggest that effects on circadian disruption are more pronounced in backward (or counterclockwise) working schedules than forward (or clockwise) schedules (Nesthus et al. 2001, Boquet et al. 2004, Vangelova 2008).

People working at night and sleeping during the day are continuously exposed to external synchronizers promoting a day-oriented schedule and thus experience circadian desynchrony, as evidenced by changes in levels and timing of peak melatonin production and other biomarkers of circadian disruption, such as changes in the rhythms of core body temperature. In addition, night and rotating shiftwork may alter cortisol levels and the cortisol awaking response (reviewed by Ulhôa et al. 2015). One study found young shift workers (under age 40) had higher long-term cortisol levels as measured in hair samples than day workers (Manenschijn et al. 2011). However, findings are somewhat conflicting across studies; some studies found no effect, others found differences in the direction of the effects (e.g., lower or higher levels among night workers, increased or decreased cortisol activation), or found a flattened or blunted cortisol profile (reviewed by Fekedulegn et al. 2012, Niu et al. 2015, Hung et al. 2016).

Night shift workers also complain about reduced sleep quality, shortened sleep periods, and insomnia, especially following a night shift. Duration of daytime sleep in night shift workers usually ranges from four to seven hours, and workers sleep longer on rest days. Night shift workers are usually awake during their nocturnal melatonin peak periods, which may also contribute to night-time sleepiness as melatonin plays an important role in regulating sleep (reviewed by Boivin and Boudreau 2014 and Kim et al. 2015).

#### Adaptation to shift work

Overall, most shift workers do not appear to tolerate shift work or adapt their circadian rhythms to their sleep schedule (i.e., melatonin continues to peak at night instead of during their daytime sleep) (Boivin and Boudreau 2014). Some studies have found that individual workers who are able to alter the timing of their melatonin production to parallel their sleep time had better shift work tolerance and improved sleep quality compared to workers who did not alter their timing; however, there are individual differences (reviewed by Burch et al. 2005). A review of six studies of permanent shift workers found that only a small minority of permanent night shift workers (< 3%) underwent a complete phase adjustment and only 21% showed substantial adjustment so as to derive any benefit from it (Folkard 2008). Furthermore, there was no difference in results regardless if shiftwork occurred in dim or normal lighting. The review concluded that only a small minority of permanent night workers undergo complete phase adjustment of endogenous melatonin.

A more recent review found that circadian rhythms of melatonin, cortisol, and heart rate are not adapted to night work after one to three consecutive night shifts (Jensen et al. 2016). A meta-analysis of studies of experimental shift work tolerance found that circadian desynchronization (as measured by oral temperature circadian rhythms) still occurred among male workers classified as shift work tolerant (based on lack of medical complaints such as sleep alteration, fatigue, changes in behavior, or digestive problems) although at a lower rate (16.7%) than non-tolerant shift workers (55.8%) (Reinberg and Ashkenazi 2008). Circadian desynchronization occurred in 11% to 17% of former shift workers who were currently symptom free but had been discharged from shift work due to poor tolerance. A study of 48 shift workers found that tolerant shift workers were older and worked longer durations than non-tolerant workers (Reinberg and Ashkenazi 2008).

Sleep strategy, age, chronotype, and genetic susceptibility may influence adaptation to night shift work. A review of 60 studies on shift work tolerance found conflicting findings for age, gender, and chronotype (Saksvik et al. 2011). In general, studies have found that individuals at younger age are better at adapting to shift work as measured by cognitive skills or sleep, while older workers had better health outcomes, which may be influenced by the healthy shift worker effect. Most studies found that morning (or earlier) chronotypes have more difficulties adapting to night shift work than evening types as measured by problems with sleep; some studies found evening chronotypes did better as measured by their perception of work performance and perceived shift work tolerance (Saksvik et al. 2011). Gamble et al. (2011) reported that rotating night shift workers who used sleep deprivation to switch to and from night shift work and diurnal sleep during days off were the most poorly adapted (based on self-reported adaptation and questions related to sleep) to shift work. There was some suggestion that clock gene polymorphisms were associated with sleep behavior and might contribute to shift work adaptation (Gamble et al. 2011).

The effect of race on adaptation to shift work remains an important research gap although some studies have suggested that the period of endogenous circadian rhythms differs between European Americans and African Americans. African Americans were predicted to be less likely to delay circadian rhythms when working nights and sleeping during the day, and adapted less readily to night work than European Americans (Eastman et al. 2016). These results may also have implications for African-American shift workers in the United States, who are disproportionately represented in night work (see Section 1.3.2).

#### Studies of melatonin suppression

There is strong evidence that night shift work suppresses or disrupts nighttime melatonin production (see Table 2-3). As most night shift workers do not adapt their circadian rhythms to their sleep:wake cycle, the most informative studies are those that compared melatonin levels at multiple time periods, such as those using cosinor analysis of mesor (average levels), amplitude (fluctuation), and acrophase (timing of peak melatonin production) in night shift vs. day shift workers. Studies comparing nighttime melatonin in night shift workers after night work to levels in day shift workers after nighttime sleep were also informative. Several studies in different geographical locations and of different types of workers found that night shift workers (permanent and rotating) had lower morning urinary aMT6s after night work compared to day shift workers after sleep (Schernhammer et al. 2003, Burch et al. 2005, Davis et al. 2012, Ji et al. 2012, Bracci et al. 2013, Mirick et al. 2013). Compared to day shift workers on a work day, night shift workers also had lower total (Borugian et al. 2005, Daugaard et al. 2017) or mean melatonin levels (Hansen 2006, Papantoniou et al. 2014, Gómez-Acebo et al. 2015, Leung et al. 2016, Song et al. 2016), or amplitude (Gómez-Acebo et al. 2015), or a later acrophase (Papantoniou et al. 2014, Gómez-Acebo et al. 2015) on a work night.

Findings regarding the suppression of melatonin levels in night shift workers after nighttime sleep on a day off are conflicting, however. Urinary aMT6s levels were lower after night sleep on a non-work day for night workers compared to levels in day workers after night sleep in Seattle health care workers (Davis et al. 2012, Mirick et al. 2013), but not in Italian health workers (Bracci et al. 2014).

The studies indicate that persistent night shift work (i.e., frequent or long-term) was associated with nighttime melatonin suppression; however, findings for specific exposure metrics across studies are somewhat difficult to compare due to differences in the type of shift worker (e.g., permanent or rotating), gender, melatonin measurements, or analyses. Three studies of female rotating night shift workers found that a high frequency of shift work or several consecutive shifts was associated with decreased nighttime (measured in the morning) or average melatonin levels. The following are key findings from these studies:

- A significant (P = 0.008) inverse association between morning urinary aMT6s levels and increasing number of working nights in the two weeks prior to collection of the urine samples was found among premenopausal nurses in the Nurses’ Health Study (Schernhammer et al. 2004).
- A study of Polish midwives and nurses who currently worked night shifts found decreased morning UaMT6s for working ≥ 8 night shifts/month in all women and in premenopausal women (Peplonska et al. 2012).
- Compared to day workers, a Canadian study (Leung et al. 2016) found a greater reduction in average aMT6s levels between hospital workers who worked ≥ 3 consecutive nights and women who worked < 3 consecutive nights.

However, a Spanish study of permanent male and female night workers from various occupations (Papantoniou et al. 2014) found the most pronounced reduction of average urinary aMT6s levels in subjects who worked ≤ 4 consecutive nights (compared to day workers) in the two weeks prior to urine collection. Permanent night shift workers had a delay in the time of peak melatonin production compared to day workers, which was most pronounced among men who worked the most nights in the railroad industry, suggesting partial adaptation of circadian timing with sleep:wake cycle (Papantoniou et al. 2014). Three studies also found an inverse relationship between long-term shift work and average melatonin levels (Papantoniou et al. 2014, Leung et al. 2016 — nurses only analyses) or peak melatonin level (Grundy et al. 2011). No significant trend was found for morning melatonin levels and shift work duration or cumulative number of night shifts among Polish nurses and midwives (Peplonska et al. 2012); however, this analysis was limited because it combined the current and former rotating Polish nurses and midwives.

Studies that compared melatonin levels in rotating shift workers or current night shift workers after working day and night shifts were not considered as informative since there may be more chronic effects on melatonin suppression due to shift work (as discussed above). Analyses of melatonin levels during day and night sleep time in night workers may be evaluating differences in melatonin due to circadian timing rather than from night work per se, as indicated in a study of Canadian rotating nurses. Grundy et al. (2009) reported lower melatonin levels during nighttime sleep after working days and during daytime sleep after working nights, but not in nighttime melatonin levels after working night shift or during nighttime sleep after working days (Grundy et al. 2011). Anjum et al. (2013) reported that melatonin levels were lower in nurses after working nights than days when within-subject comparisons were made. In contrast, a small study of telecommunication rotating night workers (Dumont et al. 2012) using within-subject comparisons found that melatonin levels were similar between the night and day shifts.

The relationship between shift work and melatonin levels may be modified by race/ethnicity, age, and chronotype (Bhatti et al. 2014, Papantoniou et al. 2014, Leung et al. 2016), although findings for these potential modifiers are somewhat inconsistent across studies, and the database is limited in its ability to evaluate whether race is an effect modifier, as Asians are the only group that has been specifically evaluated. Bhatti et al. (2013b) reported that Asian-American night shift workers had urinary aMT6s levels closer to their day shift levels compared to white workers (female health workers in Seattle), suggesting they may be able to adapt better to shift work than whites. In contrast, the Shanghai Women’s Health Study found some evidence to suggest that night shift work causes melatonin suppression in middle-aged Chinese women based on the findings of a significant inverse relationship between morning urinary aMT6s levels (not first void) and job exposure matrix scores for night shift work (Ji et al. 2012). Of note, urinary aMT6s levels were low in this study, which could be due to the fact that first void samples were not collected and the study may not have directly measured nocturnal melatonin suppression. Two studies of postmenopausal Japanese workers (Nagata et al. 2008, Nagata et al. 2017) were considered to be uninformative because of low numbers of night shift workers and because biological samples were not collected after night work.

Some support for the findings comes from an experiment which suggested that sensitivity of melatonin to light suppression is influenced by eye pigmentation and/or ethnicity. Caucasian and Asian males were exposed to 1,000 lux light two hours prior to their salivary melatonin peak. The percentage of suppression of melatonin secretion was significantly larger in light-eyed Caucasians (88.9%) than in dark-eyed Asians (73.4%) (P = 0.01) (Higuchi et al. 2007). No studies were identified for other races.

#### LAN during shift work and melatonin suppression

There is some evidence from six field studies (two in overlapping populations) (Table 2-3) and one experimental study to suggest that LAN contributes, in some part, to melatonin suppression observed in night shift workers; however, few studies measured melatonin and light in the same study. It is difficult to compare findings across studies because of differences in study design, sample type, type of workers, and light levels. Daugaard et al. (2017) reported that LAN at > 80 lux during the night mediated ~5.9% of 16.5% melatonin suppression in night shift workers. Two overlapping Canadian studies of rotating nurses found an inverse relationship between urinary or salivary melatonin levels and average LAN (Grundy et al. 2009, Grundy et al. 2011), and a Spanish study found that permanent night workers with the highest LAN exposure had greater melatonin suppression (38% vs. 27% suppression) and more pronounced shifts in the timing of peak melatonin than workers with the lowest LAN exposure, albeit levels of light at night were low in this study (Papantoniou et al. 2014). A small study of rotating night workers found an inverse relationship between light exposure and total 24-hour urinary melatonin secretion but not melatonin levels secreted during the work night (Dumont et al. 2012). To determine the direct effect of night work on nighttime melatonin production in moderate intensity light exposure and to assess the effect of consecutive night shifts on melatonin production, an experimental study of healthy volunteers subjected to three nights of simulated shift work (50 lux at the eye level) was conducted. The authors reported that nighttime melatonin production based on 24-hour urine collections significantly decreased after the third consecutive night, and the decrease was progressive over the three nights. The authors suggested that decreases in melatonin levels, however, were mainly the result of circadian disruption associated with the process of re-entrainment rather than the direct effect of low intensity light (< 100 lux) (Dumont and Paquet 2014).

Table 2-3 Field studies of night shift work and melatonin levels in shift workers

Study; Country (year or years of exposure) | Population | Methods: timing | Results | Comments
Night shift workers vs. day shift workers
Davis et al. 2012; Mirick et al. 2013; Bhatti et al. 2013b, 2014; USA; Women: 2003–2008; Men: 2007–2011 | Seattle healthcare workers — at least 20 hr/wk nights or days; Women — pre-menopausal ages 20–49 yr; Men — ages 20–55 yr; Davis (women); 172 NSW; 151 DSW; Mirick (men); Bhatti 2014 (women & men); 354 NSW; 310 DSW; Bhatti 2013 (white & Asian women); NSW: 110 white and 19 Asian; DTW: 115 white and 32 Asian | UaMT6s; After sleep; NSW: Daytime sleep following 1^st^ night shift; NSW: Nighttime sleep on night off after ≥ 2 consecutive night shifts; DSW: nighttime sleep after ≥ 1 day shifts; After work; NSW: 2^nd^ night shift; DSW: day shift | All studies; ↓ UaMT6s NSW compared to DTW; - Nocturnal (NSW night work, DTW night sleep); - Nighttime sleep; - Day sleep (NSW) vs. night sleep (DSW); ↓ UaMT6s within NSW; - Day sleep vs. night sleep; - Night work vs. night sleep | Bhatti 2014: chronotype; Morning-type night workers had levels closer to day shift workers compared to evening-type night shift workers; Bhatti 2013: race; Asians suffered less disruption than whites (UaMT6s closer to DSW than whites); Adjusted for potential confounders
Borugian et al. 2005; Canada | Convenience sample ages ≥ 19 yr, working ≥ 20 hr/wk; 14 rotating NSW nurses; 3 DSW nurses; 5 DSW office (2 men, 3 women) | Salivary melatonin; 3 times in 24 hours (awaking, midday, and mid sleep relative to night or day work schedule) | NSW vs. DSW; ↓ Total melatonin on work nights than day workers on work days | Light measured using light logger; Rotating shift workers had two times higher light exposure during night shifts than on their day off or day-shift work (not statistically significant); Small numbers of participants limit the utility of the study
Bracci et al. 2013; Italy (2011) | National Health Service hospital wards – 184 nurses (premenopausal); 31 rotating NSW; 31 DSW; ≥ 48 night-shifts/yr | UaMT6s; 7:00 AM; end of night shift or beginning of morning shift | ↓ UaMT6s NSW compared to DSW regardless of nap | Rapid rotating clockwise: day, evening, night, off, off; No association with clock gene expression; Adjusted for potential confounders
Bracci et al. 2014; Italy (2012) | National Health Service hospital wards; 184 nurses (premenopausal); 60 rotating NSW; 56 DSW; 56 permanent daytime nurses; Assigned for ≥ 2 yr for ≥ 60 night-shifts/yr with no schedule breaks in last 6 months | UaMT6s; Beginning of morning shift after a regular night sleep on a day off | UaMT6s similar in night shift workers & permanent day workers | Rapid rotating clockwise; Alterations in clock gene expression; Adjusted for potential confounders
Burch et al. 2005; United States (2001–2002) | Medical device manufacturing unit; 171 workers; 3 non-rotating shifts:; - day (6:00 AM–2:00 PM); - swing (2:00 PM–10:00 PM); - night (10:00 PM–6:00 AM) | UaMT6s (creatinine adjusted); Post work and post sleep (including all voids during sleep) | NSW vs. DSW; - ↓ UaMT6s total sleep period; - ↑ UaMT6s post work; - ↓ Sleep:work ratio | Light exposure measured using light logger; NSW non-significantly lower 24-hr light exposure than DSW; Ratio of post sleep and post work—potential indicator of circadian disruption; Comparing post work and sleep may not be informative for workers who do not adapt to night shift work since it will not capture peak melatonin levels for each shift type; Adjusted for potential confounders
Daugaard et al. 2017; Denmark | 87 NSW; 254 DSW; 322 work days and 301 off days | Salivary melatonin; Samples every four hours on a work day and a day off with initial sample after waking (morning for DSW and afternoon for NSW) and a sample before bedtime | NSW vs. DWS; - ↓ 16.5% on work nights; similar on day off; LAN > 80 lux during night; - ↓ melatonin after ≥ 10 minute exposure; - ↓ 5.9% melatonin mediated by LAN (> 80 lux) | Light measured using a light logger. On work days, LAN higher for NSW than DWS; light during the day higher for DSW than NSW. Light levels similar for DSW and NSW on off days; Limitation: Participants decided on which day to take sample in a 7-day week
Dumont et al. 2012 | 13 rotating NSW telecommunication (aged 23–50) | 24-hr UaMT6s; Two 48-hour periods (once when working day/evening shift and the other for night shift) beginning of 2^nd^ work shift | Day vs. night shift; No difference in melatonin levels; Light & melatonin; Inverse association between light exposure during night and 24-hr melatonin but not melatonin during work time | Light measured using a light logger; no difference in median light exposure between day and night periods over 24 hr or during work time
Hansen et al. 2006; Denmark | 170 nurses (volunteers); 81 rotating; 89 fixed: 50 fixed night; 27 fixed day; 12 fixed evening | UaMT6s; Spot urine samples over 24 hours at various times on a workday and on a day off: the 2^nd^ workday of a shift and 2^nd^ day off | ↓ UaMT6s; - NSW (rotating or fixed) vs. DSW on a workday; - Workday vs. day off for NSW (fixed or rotating) but not DSW | Adjusted for sampling time and potential confounders
Ji et al. 2012; China (1997–2000) | Shanghai Women Health Study (aged 40–70); 296 women/night shift work measured by JEM | UaMT6s (creatinine adjusted); Early morning, middle morning, late morning, and afternoon | ↓ UaMT6s with ↑ JEM scores for night shiftwork for early morning samples only | Adjusted for potential confounders; Samples not based on first void
Nagata et al. 2017; Japan (2008–2009) | Follow-up of women attending breast cancer screenings; 617 participants; 10 current night shift workers; 532 not currently working shift work | UaMT6s (creatinine adjusted); Following a night’s sleep on a day off | No differences in UaMT6s levels between current shift workers and workers not currently working shifts | Uninformative study: only 10 workers, measured on a day off; Current shift work without information about previous shift work duration; Adjusted for potential confounders
Schernhammer et al. 2004, Schernhammer et al. 2006a; United States NHS (1989–1990); NHS II (1996–1999) | Nurse’s Health Study II (NHS II); 2004: 80 randomly selected cancer-free participants (premenopausal); 2006: 459 rotating NSW from NHS II, primarily pre-menopausal nurses (ages 33–50), includes 80 nurses from 2004 study | UaMT6s (creatinine adjusted); 2004: repeated measurements; 2006: one measurement | 2004 NSW: inverse association with increasing numbers of nights worked within 2 weeks of urine collection and urinary melatonin level; 2006: ↓ UaMT6s (NS); NSW vs. DSW; > 4 nights in 2 weeks of urine collection | Same study population as cancer studies; 2004: Repeat melatonin measure (3 samples per woman, 80 women): ICC = 0.72; Adjusted for potential confounders
Song et al. 2016; Korea (NR) | 100 female medical technologists (≥ 40 hr/wk); 50 permanent NSW; 50 DSW; NSW – no earlier than 6:00 PM – at least 8 hr | Serum melatonin; blood samples collected between 8:00 AM and 9:00 PM | NSW compared to DSW; - ↓ mean melatonin levels; - ↓ melatonin receptor expression | No difference in p53 expression in NSW vs. DSW
Cosinor analyses
Gómez-Acebo et al. 2015; Spain (2012–2013) | Health care workers (aged 20–65) or teachers (aged 20–30); 63 rotating NSW (health care workers); 73 DSW (health care workers & teachers) | UaMT6s; Collected over a 24-hr period following the 2^nd^ day or 2^nd^ night shift | NSW compared to DSW; - ↓ average UaMT6s (mesor); - ↓ UaMT6s fluctuation (amplitude); - Later time of peak UaMT6s (acrophase) | Forward rotating: 2 or 4 morning shifts, 2 afternoon shifts, 2 night shifts, 2 off days
Leung et al. 2016; Canada (NR) | 261 female hospital workers; 114 rotating NSW; 147 DSW | UaMT6s; 48-hr time period; Fixed: 2 workdays; Rotating: 1 day, 1 night shift | NSW (night shift) vs. DSW; - ↓ average UaMT6s (mesor); - Earlier time of peak UaMT6s (acrophase); Within participant comparison of rotating workers: night vs. day shift; - ↓ average UaMT6s (mesor); Earlier time of peak UaMT6s (acrophase) | Chronotype; Differences in UaMT6s (mesor) between NSW and DSW were more pronounced among later chronotypes and among shift workers working ≥ 3 consecutive nights; Among nurses, cumulative shift work (duration) was associated with ↓ mesor; Mesor or acrophase not associated with duration of past shift work; Adjusted for potential confounders
Papantoniou et al. 2014; Spain (2011) | Workers at 2 hospitals, a car industry, and railroad company; 63 men and 54 women; 75 permanent NSW; 42 DSW | UaMT6s; 24-hour time period on work day | NSW (night shift) vs. DSW; - ↓ average UaMT6s (mesor); - Later peak time UaMT6s (acrophase); Exposure response; - Lower average UaMT6s among those with longest lifetime duration and lower frequency in a 2-week period; - Phase shift was related to # of hours worked; NSW with highest LAN exposure vs. DSW; - Greatest ↓ melatonin levels Greatest phase shift | Light exposure measured using a data logger; mean light on overnight shift ranged from 15 to 246 lux; Chronotype; Morning preference chronotype had lower melatonin levels but chronotype did not affect acrophase; Adjusted for potential confounders
Night shift vs. day shift in rotating night shift worker
Anjum et al. 2013; India | 62 rotating men and women health professionals (aged 20–40): working 9 continuous shifts that alternated between day and night | UaMT6s; Every 8 hours (afternoon, night, morning) | Within person comparison NSW vs. DSW; ↓ mean UaMT6s for afternoon, night, and morning with greatest difference at night and in the morning | Within person comparisons
Grundy et al. 2009; Canada (2006) | 61 rotating night nurses (aged 30–65 yr); DD, NN, 5 days off; 29 sampled on day shift; 32 sampled on night shift | UaMT6s; NSW: after awakening from daytime sleep for those working 2^nd^ consecutive night shift and nighttime sleep for those working 2^nd^ consecutive day shift; Salivary melatonin; 4 samples over 24 hr | UaMT6s; - ↓ after night shift than day shift; Salivary melatonin; - No alteration in timing of peak salivary melatonin levels (peak still occurred at night regardless of shift); Light intensity (average between midnight and 5:00 AM): inverse relationship with UaMT6s; - All subjects combined (P = 0.002); - NSW (P = 0.06); - Lower levels during day sleep and peak at night during work (midnight to 5:00 AM) | Light measured using light meter; higher light during sleep and during night hours for those working night compared to those working the day shift; Study limitation: not comparing peak UaMT6s levels in both groups since peak after night shift is during the night and UaMT6s were measured after daytime sleep in the night workers; Adjusted for potential confounders
Grundy et al. 2011; Canada (2008–2009) | 123 rotating nurses aged 30–65 yr); DD, NN, 5 days off; Participated in the study twice (after night and day) in summer and winter; 1st season:118 both shifts; 2^nd^ season: 96 night, 103 day | UaMT6s; Two samples: Early morning (after night shift for night or nighttime shift for day) and midday (after daytime sleep for night and mid shift for day); Salivary melatonin; 4 samples over 24 hr | UaMT6s; - No differences between night and day shift; ≥ 20 yr shift work associated with increase in peak and possibly change in melatonin levels; Light intensity: small inverse relationship; - Peak (P = 0.07) and change (P = 0.04) in melatonin levels and light observed in night work group | Same population sources as Grundy et al. 2009; Measured light using light meter, maximum levels at night 37.2 lux; Session and chronotype no effect; Adjusted for potential confounders
Peplonska et al. 2012; Poland | 1,117 nurses and mid-wives selected from national registries (aged 40–60 yr); 724 provided morning samples; 354 currently rotating NSW; 370 currently DSW | UaMT6s; Morning samples for analysis of NSW; Evening samples used for between subject variability | Current NSW vs. DSW; - Similar morning UaMT6s; - ↓ morning UaMT6s for working ≥ 8 night shifts/month in total (P = 0.019) and in premenopausal women (P = 0.011); - ↓ morning UaMT6s for working ≥ 10 hr/night (P = 0.06); Combined DSW and NSW; - No trend with duration, total hours, or cumulative number of night shifts | No association with subjective type of light at night at work; Sensitivity analysis excluding 10 women who moved to day jobs in last year before study start; Study limitation: women currently working days had previously worked rotating NSW for an average of 12 yr (most ≥ 5 yr before study start). Analysis of cumulative history of shiftwork included melatonin measurement from current DSW after sleeping; Adjusted for potential confounders

D = day; DSW = day shift workers; hr = hour; ICC = intraclass correlation coefficient; JEM = job exposure matrix; N = night; NSW = night shift workers; UaMT6s = urinary 6-sulphatoxymelatonin; yr = year.

#### Studies of clock gene expression

There is some evidence from field studies (Table 2-4) and one experimental study that expression of peripheral clock genes (primarily measured in blood) is altered in night shift workers compared to day shift workers; however, the database is limited by small numbers of studies, differences in the genes evaluated, and types of samples collected across studies (see Table 2-4). Sample timing and methodology appear to be key factors in interpreting the findings. A series of studies of overlapping populations of Italian nurses found that several clock genes had altered expression in night rotating workers compared to day workers when RNA was measured in blood samples taken after a day off work (Bracci et al. 2014) but not when measured in blood samples taken immediately after working night shift (Bracci et al. 2013); the degree of overlap in the studies is not known. The third study of this population found that PER2 expression (as measured in pubic hair) was decreased in night shift workers compared to day shift workers in samples taken in the morning but not at other times (Bracci et al. 2016). Fang et al. (2015a) reported that PER2 expression was affected by both types of shift work and sampling time in a crossover studies of interns working day and night shifts. After night work, PER2 expression was higher in the evenings than the mornings whereas the opposite pattern (higher PER2 expression in the morning than the night) was observed after day shift; therefore, when PER2 was measured in the evening, its expression was increased after night shift compared to day shift. A small experimental study using polychromatic white light to simulate 8 hours of night shift work for 9 days (10-hour shift in the sleep/wake cycle) found that expression of PER1 and PER2 adapted to the shifted sleep/wake schedule within 3 days on the shifted sleep/wake schedule (James et al. 2007). Increased PER1 expression was found to be related to lifetime exposure to working nights among current night shift workers compared to current day shift workers who previously worked nights, suggesting that persistent night shift work may be associated with circadian desynchrony (Reszka et al. 2013). Epigenetic mechanisms may be responsible for changes in clock gene expression; several studies found that long-term shift work was associated with epigenetic changes in clock genes (Zhu et al. 2011, Bhatti et al. 2015, Samulin Erdem et al. 2017b, see Section 6.3.2, Table 6-2).

Table 2-4 Field studies of clock gene expression in shift workers

Study | Population | Methods: timing | Results | Comments
Bracci et al. 2013; Italy (2011) | National Health Service hospital wards; 184 nurses; Premenopausal ≥ 2 yr; 31 rotating NSW; 31 DSW; ≥ 48 night-shifts/yr | BMAL1, NPAS2, CRY1, CRY2, PER2, PER3, and REVERBa; Blood; 7:00 AM at the beginning of the day shift or end of night shift | No association in adjusted analyses; ↑ PER2 and PER3 in NSW vs. DSW in crude analyses | Rapid rotating clockwise: day, evening, night, off, off; Adjusted for potential confounders
Bracci et al. 2014; Italy (2012) | National Health Service hospital wards; 184 nurses; 60 rotating NSW; 56 DSW; Premenopausal; ≥ 2 yr; Assigned for ≥ 2 yr for ≥ 60 night-shifts/yr with no schedule breaks in last 6 months | BMAL1, CLOCK, NPAS2, CRY1, CRY2, PER1, PER2, PER3, and REVERBα mRNA; Blood; Beginning of morning shift after a regular night sleep on a day off | NSW vs. DSW; - ↑ BMAL1, CLOCK, NPAS2, PER1 and PER2, REVERBα; - ↓ CRY1, CRY2, and PER3 | Rapid rotating clockwise: day, evening, night, off, off; Adjusted for potential confounders
Bracci et al. 2016; Italy (2012) | National Health Service hospital wards; 184 nurses; 23 rotating NSW; 25 DSW; Premenopausal; ≥ 2 yr; Assigned for ≥ 2 yr for ≥ 60 night-shifts/yr with no schedule breaks in last 6 months | PER2 mRNA; Saliva and pubic hair follicle cells; Working day after a day off; 6:00 AM, 9:00 AM, 3:00 PM, 8:00 PM, 4:00 AM | NSW vs. DSW; - ↓ PER2 at 8:00 AM (maximum value); no significant differences at other times; - ↓ 24-hr variations of PER2 expression | Rapid rotating clockwise: day, evening, night, off, off; Significant differences in cortisol and temperature profiles but not melatonin level
Reszka et al. 2013; Poland (2008– 2010) | 184 nurses and midwives who currently work day or rotating shift (aged 40–60 yr); 92 current NSW and 92 current DSW; All workers had previously worked rotating NSW | BMAL1, CLOCK, CRY1, CRY2, PER1, PER2, and PER3; Blood morning after night work (average 7:15 AM) or before day work (average 8:30 AM) | ↑ PER1; - Current NSW vs. DSW; - > 15-yr NSW vs. DSW; - Lifetime duration of night shift work among NSW but not DSW | 38% of DSW had worked nights for ≥ 15 yr; average 7.3 yr since quitting DSW; Large inter-individual differences; PER2 and PER 3 down regulated in late vs. early morning; Adjusted for potential confounders and sample time
Fang et al. 2015b | Crossover study; 15 shift workers (aged 21–34 yr); ≥ 7 days on floating night shift rotation | PER2, NR1D mRNA; Blood: Before (6:00 PM) and after (8:00 AM) night shift; Blood: Before (8:00 AM), during (1:00 PM), and after (6:00 PM) day shift | NSW vs. DSW; - ↑ PER2 in evening | Shifts effects; Day shift: PER2 higher in the morning than in the evening; Night shift: PER2 higher in the evening than the morning

DSW = day shift worker; hr = hour; NSW = night shift worker; yr = year.

### 2.3.2 Experimental animal studies of simulated jet lag/simulated shift work and melatonin suppression and clock gene expression

This section reviews the principal findings from simulated jet lag, simulated shift work, and circadian disruption in experimental animals. Similar to studies of LAN exposure, simulated jet lag and shift work animal models indicate that these exposures show altered patterns of clock gene and hormone expression patterns that contribute to circadian disruption.

Jet lag is simulated by exposing experimental animals to an advance or delay in the daily timing of light followed by re-entrainment to the new light/dark cycle (Arble et al. 2010, Evans and Davidson 2013, LeGates et al. 2014). The magnitude and direction of the phase shift affects the rate and probability of re-entrainment and takes longer following phase advances than phase delays (Illnerová et al. 1989, Ruby et al. 1998, Reddy et al. 2002). Simulated shift work studies with experimental animals are highly variable in both protocol and measured endpoints.

The effect of jet lag on melatonin levels in animal models is not clear. Most studies used mice that are melatonin deficient, or melatonin levels were not measured (Filipski et al. 2004, Filipski et al. 2005, Filipski et al. 2006, Davidson et al. 2009, Lee et al. 2010, Wu et al. 2010, Wu et al. 2012, Kettner et al. 2015, Van Dycke et al. 2015, Kettner et al. 2016, Papagiannakopoulos et al. 2016). One study reported that jet-lagged mice showed altered temporal profiles of melatonin and corticosterone levels, although their overall levels throughout the day did not reach statistical significance (Iwamoto et al. 2014). No shift work models were identified that measured melatonin secretion patterns.

Clock gene expression rhythms in the SCN and peripheral tissues were altered in most experimental animal studies of acute or chronic jet lag or simulated shift work (Table 2-5). As with LAN studies, the genes most frequently studied were Clock, Bmal1, Per1, Per2, and Cry1. These studies show that clock genes in the SCN and peripheral tissues are differentially affected, re-entrain to the altered light-dark cycle at different rates, and re-entrainment is generally more difficult after phase advance than phase delay (Haus and Smolensky 2013). Thus, circadian disruption results in differential re-entrainment times of clock genes in the SCN and peripheral tissues following jet lag leads to transient desynchronization during periods where some tissues are re-entrained while others are not (Arble et al. 2010, Haus and Smolensky 2013). Some cells and tissues may take several weeks to fully re-entrain (Haus and Smolensky 2013). One study also reported that chronic jet lag altered clock gene expression in mouse lung in a sexually dimorphic manner (Hadden et al. 2012). Another study in rats reported that chronic shift-lag altered Bmal1 and Per2 gene and protein expression patterns in natural killer (NK) cells and that these alterations were correlated with suppressed NK cytolytic activity (Logan et al. 2012).

Studies of simulated shift work in male Wistar rats reported that PER1 and PER2 protein expression was not altered in the SCN (Table 2-5) (Salgado-Delgado et al. 2008, Salgado-Delgado et al. 2010). However, forced activity during the normal rest phase induced internal circadian gene desynchrony within the hypothalamus and liver and uncoupled metabolic functions from the SCN (Salgado-Delgado et al. 2010, Salgado-Delgado et al. 2013). Female Copenhagen rats exposed to a chronic jet lag protocol showed disrupted expression of Per2 and DNA damage-response genes (Fang et al. 2017). Other studies showed that simulated chronic jet lag efficiently suppressed expression of Bmal1 and Per2 mRNAs in brown adipose tissue (Lee et al. 2010), PER2, CRY1, and BMAL1 proteins in white adipose tissue (Kettner et al. 2015), and Bmal1, Per1, Per2, Clock, Cry1, and Rev-erbα mRNAs and BMAL1, CRY1, and PER2 proteins in livers of wild-type C57BL6/J mice (Kettner et al. 2016).

Table 2-5 Effects of simulated shift work or jet lag exposure on clock gene expression in experimental animals

Reference | Species (sex) | Exposure | Clock gene(s)/proteins; Tissue(s) | Results
Reddy et al. 2002 | CD1 mice (M) | 12:12 LD: C; 6-hr phase advance; 6-hr phase delay | Per1, Per2, Cry1; SCN | Phase advance; - Per1, Per2: increased rapidly day 1, then declined to control levels after 2–3 hr; - Cry1: Not acutely affected; - Days 3–8: dissociation of Per and Cry1 gene expression due to rapid entrainment of Per to the new photoschedule and slower entrainment of Cry; Phase delay; - Per and Cry rhythms entrain rapidly (within 2 cycles in parallel with activity-rest cycle)
Yamazaki et al. 2000 | Transgenic rat (mouse Per1 promoter linked to luciferase reporter) | 12:12 LD: C; 6- and 9-hr phase advance; 6- and 9-hr phase delay; (Only SCN and skeletal muscle examined after 9-hr shifts) | mPer1 transgene; SCN, liver, skeletal muscle, lung | Phase advance (6 hr); - SCN: entrained after first cycle; - Muscle, lung: arrhythmic or disrupted after first cycle, entrained after sixth cycle; - Liver: Shifted 2 hr after first cycle, entrained by sixth cycle; Phase delay (6 hr); - SCN: entrained after first cycle; - Muscle, lung: shifted 4 hr after first cycle, entrained after sixth cycle; - Liver: arrhythmic or unshifted after first cycle, shifted 3.5 hr after sixth cycle; Phase advance (9 hr); - SCN: entrained after first cycle; - Muscle: arrhythmic after first cycle; Phase delay (9 hr); - SCN: entrained after first cycle; - Muscle: shifted 3 hr after first cycle
Davidson et al. 2009 | mPer2^LUC^ knock-in mice (M/F) | 12:12 LD: C; 6-hr phase advance | mPer2 | SCN: partial shift on day 1 and entrained by day 3; however, varies by subregion. SCN shown to have population of fast-shifting cells that are more prevalent in the ventral aspect; Thymus, lung: entrained by day 3; Esophagus: partial shift by day 3, entrained by day 5–8; Spleen: No shift by day 3, entrained by day 5; Full resynchronization of the SCN and peripheral tissues after 8 days
Iwamoto et al. 2014 | CBA/N mice (M) | 12:12 LD: C; 8-hr phase advance every 2 days for 10 days; All mice transferred to continuous dark schedule for 3 days prior to sacrifice | Clock, Bmal1, Per1, Per2, Cry1; SCN, liver | SCN: temporal profiles of all clock genes were altered, acrophases delayed by 5.5 to 9 hr, and peak levels of Per1 and Per2 were 65% of controls; Liver: significant interaction between lighting conditions and time in expression of all clock genes, acrophases delayed by 7 to 11.2 hr, Per1 and Per2 increased, Clock suppressed
Hadden et al. 2012 | C57BL6J mice (M/F) | 12:12 LD: C; 8-hr phase advance every 2 days for 4 wk | Clock, Bmal1, Per1, Per2, Cry1, Rev-erbα; Lung | Males: Clock decreased, Per2 and Rev-erbα increased; Females: Bmal1 and Rev-erbα decreased, Per2 and Cry2 increased. Per2 expression was higher in females than in males; Overall, all clock genes showed a higher coefficient of variation in chronic jet lag groups of both sexes
Lee et al. 2010 | C57BL6J mice (M/F) | 12:12 LD: C; 8-hr phase advance every Monday followed by 8-hr phase delay every Thursday for 8 wk | Bmal1, Per2; Brown adipose tissue | Complete suppression for both Bmal1 and Per2 mRNAs
Kettner et al. 2015 | C57BL6J mice (M) | 12:12 LD: C; 8-hr phase advance every Monday followed by 8-hr phase delay every Thursday for 8 wk | BMAL1, PER2, CRY1; White adipose tissue | Complete suppression of both PER2 and BMAL1 protein expression and significantly decreased CRY1 protein expression and abolished rhythmic expression
Kettner et al. 2016 | C57BL6J mice (M) | 12:12 LD: C; 8-hr phase advance every Monday followed by 8 hr phase delay every Thursday for 8 or 26 wk | Clock, Bmal1, Per1, Per2, Cry1, Rev-erbα; BMAL1, PER2, CRY1; Liver | Decreased and arrhythmic expression of Bmal1, Clock, Cry1, Rev-erbα expression. Decreased and shifted Per1 and Per2 expression rhythm. Completely suppressed PER2 and BMAL1 protein expression and significantly decreased CRY1 protein expression and abolished rhythmic expression
Logan et al. 2012 | F344 rats (M) | 12L:12D: C; 6-hr phase advance every 2 days for 10 shifts | Bmal1, Per2; BMAL1, PER2; Natural killer cells (spleen) | Circadian expression patterns of both clock genes and proteins altered, acrophases shifted for all except PER2
Salgado-Delgado et al. 2008 | Wistar rats (M) | 12:12 LD: C; Simulated night work (forced activity for 8 hr during the light phase/normal sleep phase) | PER1, PER2; SCN | PER1 and PER2 proteins remained in phase with the LD cycle
Salgado-Delgado et al. 2010 | Wistar rats (M) | 12:12 LD: C; Simulated night work (forced activity for 8 hr during the light phase) | PER1; SCN, arcuate and dorsomedial nuclei of hypothalamus | SCN: no effect; Arcuate and dorsomedial nuclei: PER1 rhythms were shifted and uncoupled from the SCN
Salgado-Delgado et al. 2013 | Wistar rats (M) | 12:12 LD: C; Simulated night work (active for 8 r during the light phase) | Clock, Bmal1, Per1, Per2; Liver | Clock, Bmal1, and Per1: acrophase inverted; Per2: lost rhythm
Fang et al. 2017 | Copenhagen rats (F) | 12:12 LD: C; Simulated jet lag (advanced light onset by 12 hr for 7 days; day of shift, 24-hr L and day of shift back to regular LD cycle, 24-hr D | Per2; Mammary glands | Disrupted rhythmic expression of Per2 and reduced rhythmic expression of most DNA-damage response genes

C = control; F = female; M = male.

### 2.3.3 Behavioral modifications: non-photic zeitgebers

Overall, behavioral modification studies show that feeding schedules are potent zeitgebers that uncouple the daily metabolic and clock gene oscillations in peripheral tissues from the SCN and can override the influence of the SCN on the peripheral oscillators (Damiola et al. 2000, Escobar et al. 2007, Hoogerwerf et al. 2007, Asher and Sassone-Corsi 2015). High-fat diets also modified circadian synchronization to light after a simulated jet-lag test (Mendoza et al. 2008). Nocturnal rats that were trained to perform a task requiring sustained attention during the day produced a powerful and reversible diurnal activity pattern that was maintained after a six-hour phase advance in the light cycle (Gritton et al. 2009). The SCN, in turn, influences attentional processing via modulation of circadian sleep/wake/arousal states. These data suggest that the forebrain structures involved in attention and the SCN likely interact in a bi-directional manner. Finally, rat models of night shift work show an altered temporal pattern of food intake and a shift in the diurnal rhythms in the hypothalamic structures associated with metabolic functions and sleep regulation (Salgado-Delgado et al. 2008, Salgado-Delgado et al. 2010). However, SCN activity remained in phase with the light-dark cycle. The physiological and behavioral consequences observed in rats are similar to those observed in night shift workers (Salgado-Delgado et al. 2008), thus, these data suggest that the combination of working and eating at night are important factors leading to internal circadian desynchronization observed in shift workers (see Section 6 for a discussion of meal timing as a potential mechanism for shift work carcinogenicity).

## 2.4 Summary

Although modern electric lighting practices have clearly benefited humankind, electricity also has facilitated a shift in the natural diurnal human activity patterns towards a more nocturnal lifestyle, thus effectively forcing a misalignment with individual’s internal circadian clocks (i.e., circadian disruption). The extent of circadian disruption among night shift workers or people exposed to LAN can be evaluated using biomarkers such as melatonin, cortisol, body temperature, and clock gene expression. In normally entrained individuals, plasma melatonin levels are low during the day and start to increase in the evening, peak in the middle of the biological night, and then decrease rapidly. The peak of melatonin levels is before the nadir of the core body temperature rhythm (early morning) and approximately 4 to 6 hours before the crest of the cortisol rhythm.

LAN of sufficient intensity, duration, applicable wavelength, and appropriate timing can affect the circadian system. Circadian disruption is often measured by the timing and amount of nocturnal melatonin. Nighttime melatonin suppression can occur after exposure to light with wavelengths from 420 to 600 nm; however, short-wavelength or “blue” light wavelengths are more effective than longer wavelengths in reducing daily melatonin production. Modeling studies suggest that a potential threshold for melatonin suppression would be ~30 lux of white light at the cornea for 60 minutes. In contrast to polychromatic light, under controlled conditions exposure to less than 1 lux of monochromatic blue light has been shown to suppress melatonin. In addition, the total light experience and light exposure during the daytime as well as individual sensitivities can modify the circadian response to light. Children have been shown to be more sensitive to LAN-induced melatonin suppression than adults.

Studies of shift workers provide strong evidence that night shift work suppresses or disrupts nocturnal melatonin production and thus is associated with circadian disruption. Some studies have found that more “extensive” night work (i.e., higher frequency or longer duration) has a greater effect on suppressing melatonin levels. Studies evaluating the relationship between measured light and melatonin levels among shift workers or in simulated shift work experiments provide some evidence that light may contribute but is probably not the only factor related to melatonin suppression. Night shift workers also complain about reduced sleep quality, shortened sleep periods, and insomnia, especially following a night shift. Overall, the majority of permanent shift workers do not appear to tolerate shift work or adapt to shift work as evidenced by lack of entrainment of core body temperature, cortisol levels, and melatonin to a night schedule (i.e., cortisol continues to peak in the early morning and melatonin continues to peak at night regardless of the chronological sleep time). Sleep strategy, age, chronotype, and genetic susceptibility may influence adaptation to night shift work.

Studies in shift workers and experimental studies in humans provide some evidence that shift work and exposure to LAN can alter clock gene expression; however, the database is limited by small numbers of studies, differences in the genes evaluated and types of samples collected across studies. Sample timing and methodology appear to be key factors in interpreting the findings. Epigenetic mechanisms may be responsible for changes in clock gene expression; several studies found that long-term shift work was associated with epigenetic changes in clock genes.

Many studies of circadian disruption in animals used dim LAN, intermittent LAN, or constant light protocols as surrogates for LAN. These studies show a wide range of psychological effects and physiological biomarkers of LAN-induced circadian disruption including melatonin suppression, and altered clock gene expression. Similar to studies of LAN exposure, simulated jet lag and shift work animal models indicate that these exposures show altered patterns of clock gene that contribute to circadian disruption. Overall, behavioral modification studies show that feeding schedules are potent zeitgebers that uncouple the daily metabolic and clock gene oscillations in peripheral tissues from the SCN and can override the influence of the SCN on the peripheral oscillators.