# Methods

This report evaluates the available, relevant scientific information and assesses its quality, applies the RoC listing criteria to the scientific information, and recommends an overall cancer hazard assessment conclusion for night shift work and light at night. The scientific information came from publicly available sources.

This section outlines the framework for the report, the report contents, and key questions; it also provides a brief overview of the draft report’s methods.

## Framework and contents

As circadian disruption is a key intermediate in the pathway between exposure and potential cancer, this monograph uses a triangulation approach to review studies evaluating (1) exposure (night shift work and light at night) and circadian disruption, (2) studies on circadian disruption and cancer, and (3) studies of the exposure scenarios and cancer. Studies of exposure and biological effects (e.g., key characteristics of carcinogens) which may result from circadian disruption were also included in the evidence integration. The table below summarizes the evidence streams, exposures of interest, and outcomes. This is somewhat analogous to a “population, exposure, comparator, outcome” statement except that population has been replaced by evidence stream (e.g., humans, experimental animals, in vitro studies).

Report Framework

Evidence stream | Exposure (intermediate) | Comparison group | Cancer outcome or effect
Main effects
Human epidemiology studies | Night shift work | Day shift workers | Breast cancer, prostate cancer, colorectal cancer, lung cancer, hormonal cancers
Human epidemiology studies | LAN; Outdoor LAN; LAN in the sleeping area | Low exposure to LAN | Breast cancer
Human epidemiology studies | Transmeridian travel | Large number of trips vs. lower number of trips | Breast cancer
Supporting evidence
Experimental animals | LAN proxies: continuous light, dim light at night, interrupted light | Standard lighting, usually 12 hr light and 12 hr dark | Total neoplasms (usually combined); Primarily tumor proliferation, promotion, or latency; Cancer site is dependent on type of initiator and xenograft; Mammary gland or human breast (xenografts) is most studied site
Experimental animals | Shift work proxies; Simulated shift work Chronic jet lag | Standard lighting, usually 12 hr light and 12 hr dark | Spontaneous tumors in cancer-prone mouse model; Primarily tumor proliferation, growth or latency; cancer site is dependent on type of initiator and xenograft; Mammary gland or human breast (xenografts) is one of the studied sites
Intermediate effects^a^
Human molecular epidemiology | Night shift workers; Night shift among rotating shift workers | Day shift workers; Day shift among rotating shift workers | Circadian disruption: primarily melatonin and clock gene expression
Human experimental studies | Different types of light (e.g., wavelength, level, duration, timing) | Same individuals or comparisons of other subjects exposed to “control” lighting conditions | Circadian disruption: primarily melatonin and clock gene expression
Experimental animal studies | LAN proxies | Standard lighting, usually 12 hr light and 12 hr dark | Circadian disruption: primarily melatonin and clock gene expression
Experimental animal studies | Simulated shift work or chronic jet lag | Standard lighting, usually 12 hr light and 12 hr dark | Clock gene expression
Molecular epidemiology studies | Night shift work | Day shift workers | Biological effects related to cancer (e.g., 10 characteristics of carcinogens)
Experimental animal studies | LAN proxies; Simulated shift work or jet lag | Standard lighting, usually 12 hr light and 12 hr dark | Biological effects related to cancer
Human epidemiology studies | Circadian disruption; Melatonin or melatonin proxies (blind people) | General population (for blind people) or sighted people; Low vs. high levels | Breast cancer
Human epidemiology studies | Circadian disruption; Clock gene polymorphisms | Clock gene polymorphisms | Breast cancer susceptibility
Human, animal, & in vitro (reviews) | Melatonin, clock gene expression | Not relevant | Cancer and biological effects related to cancer

Evidence stream replaces population.

Blue = exposure; green = cancer outcome; purple = circadian disruption.

a Includes (1) studies of “exposure” and intermediates (circadian disruption or biological effects related to cancer) and (2) studies of the intermediate and cancer or biological effects related to cancer.

The process of reaching the cancer hazard assessment conclusions for night shift work and LAN included assessing the level of evidence from cancer studies of night shift work and LAN in humans. Human cancer studies of transmeridian travel were also reviewed as this involves exposure to both LAN and shift work; however, no overall cancer hazard conclusion was made for this exposure scenario. Most of the studies in experimental animals were mechanistic studies that examined growth of tumors after chemical or genetic initiation or after injection of tumor cells or implantation of tissue and were not designed to evaluate incidences of specific tumors as would be reported in chronic cancer studies. The assessment of circadian disruption as an intermediate between exposure and cancer included a review of (1) studies of LAN and shift work and biomarkers of circadian disruption and (2) studies of circadian disruption (primarily melatonin and clock gene desynchrony) and cancer (see Table above). The latter body of evidence is included in the discussion of mechanistic data. This approach informed the organization of the monograph (provided below). The overall cancer hazard evaluation is informed by an integration of the totality of the evidence. The sections of the monograph are as follows:

- Circadian Regulation and Disruption, Night Shift Work and Light at Night: Characterization and Exposure (Section 1)
- Light at Night and Night Shift Work: Circadian Disruption Studies (Section 2)
- Human Breast Cancer Studies (Night Shift Work, LAN, Transmeridian Travel) (Section 3)
- Other Human Cancer Studies (Night Shift Work) (Section 4)
- Studies of Cancer in Experimental Animals (Section 5)
- Mechanistic and Other Relevant Data (Section 6)
- Evidence Integration and Cancer Hazard Assessment Conclusions (Section 7)

The appendices in the report contain supplementary information, including the literature search strategy and the tables on the findings from human cancer studies.

## Key scientific questions for each type of evidence stream

The report provides information relevant to the following questions for each type of evidence stream or section topic.

### Overall questions

- Do a significant number of people residing in the United States work night shifts?
- Are a significant number of people residing in the United States exposed to LAN?
- Does night shift work pose a cancer hazard to humans?
  ○ If so, how should it be defined?
  ○ Can we define the underlying exposures related to circadian disruption?
- Does LAN pose a cancer hazard to humans?
  ○ If so, how should it be defined?

### Questions related to the evaluation of human cancer studies

- What are the methodological strengths and limitations of these studies?
- What are the potential confounding factors for cancer risk at the tumor sites of interest?
- Is there a credible association between exposure to LAN or working the night shift and cancer?
  ○ If so, can the relationship between cancer outcomes and exposure to LAN or working nights be explained by chance, bias, or confounding?

### Questions related to the evaluation of mechanistic data and other relevant data

- Do the animal cancer studies provide support for the findings in studies in humans?
- Are the animal studies informative for evaluating the potential carcinogenicity of LAN and night shift work?
- Do the mechanistic data provide support for a role of circadian disruption in the potential carcinogenicity of LAN or night shift work?
- Do the mechanistic data provide convincing relevant information that LAN and night shift work act through mechanisms indicating they would likely cause cancer in humans?

## Report preparation methods

The methods for preparing the NTP cancer hazard assessments for night shift work and LAN are described in the “Report on Carcinogens Protocol: Night Shift Work and Light at Night” (NTP 2018) (hereinafter referred to as “Protocol”), which incorporated a systematic review approach for identification and selection of the literature (see Appendix A), using inclusion/exclusion criteria, extraction of data and evaluation of study quality according to specific guidelines, and assessment of the level of evidence for carcinogenicity according to established criteria. Links are provided to the appendices within the document, and specific tables or sections can be selected from the table of contents.

### General procedures

The “Handbook for Preparing Report on Carcinogens Monographs” (hereinafter referred to as “Handbook”) provides a detailed description of the methods that were used (NTP 2015).

### Selection of the literature

Preparation of the monograph began with development of a literature search strategy to obtain information relevant to the topics listed above for Sections 1 through 6 using search terms outlined in the Protocol. Approximately 6,500 citations were identified from these searches and uploaded to web-based systematic review software for separate evaluation by two reviewers applying the inclusion/exclusion criteria. Based on these criteria, 722 references were selected for final inclusion in the cancer hazard assessment. Literature searches were updated on a monthly basis prior to posting the peer-review draft on August 24, 2018. References recommended by the peer reviewers were also considered for the final version. NTP has monitored the literature through September 2019 and did not identify any studies that would affect the overall cancer hazard conclusions. No studies from the updated monitoring have been included in this final assessment because these studies would not have been peer reviewed.

### Data extraction and quality assurance procedures

Information for the relevant cancer and mechanistic studies was systematically extracted in tabular format and/or summarized in the text from studies selected for inclusion in the monograph. All sections of the monograph underwent scientific review and quality assurance (i.e., assuring that all the relevant data and factual information extracted from the publications had been reported accurately) by a separate reviewer. Any discrepancies were resolved by the writer and the reviewer through discussion and reference to the original data source.

### Evaluation of studies on circadian disruption

This section used reviews as well as individual studies. It briefly reviews circadian disruption, and studies of night shift work and exposure to LAN and markers of circadian disruption. The literature is considered to be representative but not necessarily comprehensive. Data from key individual studies were extracted into tables. Although a formal quality assessment was not conducted, key limitations of studies were noted.

### Evaluation of human cancer studies

Two reviewers evaluated the quality of each study using a series of questions (and guidelines for answering the questions) related to risk of bias and to study sensitivity (as described in the Protocol). Any disagreements between the two reviewers were resolved through discussion or by consultation with a third reviewer and reference to the original data source. The approach to synthesizing the evidence across studies and reaching a conclusion on the level of evidence for carcinogenicity is also outlined in the Protocol. Level-of-evidence conclusions (inadequate, limited, or sufficient) were made by applying the RoC listing criteria (see below) to the body of evidence.

### Evaluation of cancer studies in experimental animals

As mentioned previously, most of the studies in experimental animals were mechanistic studies that examined growth of tumors after chemical or genetic initiation or after injection of tumor cells or implantation of tissue and were not designed to evaluate incidences of specific tumors as would be reported in chronic cancer studies. Thus, a systematic review of the studies was not conducted. The section provides an overview of the relevant findings and conclusions of the evidence across studies for LAN and night shift work.

### Evaluation of mechanistic and other relevant data

This section provides an overview of the key findings from studies of circadian disruption (primarily melatonin suppression and altered clock gene expression) and possible mechanisms of carcinogenicity. Due to the extensive literature and general acceptance of the oncostatic effects of melatonin, this information primarily comes from reviews. This section also reviews individual studies measuring exposure to LAN and shift work and biological effects related to cancer as well as key information related to the melatonin hypothesis. The purpose of the section is to integrate the relevant information to reach conclusions that inform the hazard evaluation.

### Overall cancer hazard assessment conclusions

The cancer hazard assessment involved integration of the relevant evidence from studies evaluating the pathway from exposure to circadian disruption to cancer. The level of evidence conclusions from studies in humans and overall NTP cancer hazard assessment were reached by applying the RoC listing criteria to these assessments. The section uses a series of evidence-based tables and figures that summarize the assessments from the entire report to provide transparency for the decision-making process for reaching the cancer hazard assessment conclusions for LAN and night shift work. The cancer hazard assessment conclusions are based on the RoC listing categories although different cancer hazard conclusions are used in order to avoid confusion with RoC listings as follows: (1) high confidence for a causal relationship with human cancer meets the criteria for known to be a human carcinogen and (2) moderate confidence for a causal relationship with human cancer meets the criteria for reasonably anticipated to be a human carcinogen.

RoC Listing Criteria

##### Known To Be Human Carcinogen

There is sufficient evidence of carcinogenicity from studies in humans^*^, which indicates a causal relationship between exposure to the agent, substance, or mixture, and human cancer.

##### Reasonably Anticipated To Be Human Carcinogen

There is limited evidence of carcinogenicity from studies in humans^*^, which indicates that causal interpretation is credible, but that alternative explanations, such as chance, bias, or confounding factors, could not adequately be excluded, OR

there is sufficient evidence of carcinogenicity from studies in experimental animals, which indicates there is an increased incidence of malignant and/or a combination of malignant and benign tumors (1) in multiple species or at multiple tissue sites, or (2) by multiple routes of exposure, or (3) to an unusual degree with regard to incidence, site, or type of tumor, or age at onset, OR

there is less than sufficient evidence of carcinogenicity in humans or laboratory animals; however, the agent, substance, or mixture belongs to a well-defined, structurally related class of substances whose members are listed in a previous Report on Carcinogens as either known to be a human carcinogen or reasonably anticipated to be a human carcinogen, or there is convincing relevant information that the agent acts through mechanisms indicating it would likely cause cancer in humans.

Conclusions regarding carcinogenicity in humans or experimental animals are based on scientific judgment, with consideration given to all relevant information. Relevant information includes, but is not limited to, dose response, route of exposure, chemical structure, metabolism, pharmacokinetics, sensitive sub-populations, genetic effects, or other data relating to mechanism of action or factors that may be unique to a given substance. For example, there may be substances for which there is evidence of carcinogenicity in laboratory animals, but there are compelling data indicating that the agent acts through mechanisms which do not operate in humans and would therefore not reasonably be anticipated to cause cancer in humans.

* This evidence can include traditional cancer epidemiology studies, data from clinical studies, and/or data derived from the study of tissues or cells from humans exposed to the substance in question that can be useful for evaluating whether a relevant cancer mechanism is operating in people.