# Units of Measurement

Area
cm^2^: square centimeter
m^2^: square meter

Concentration
kg/m^2^: kilogram per square meter

Light
cd: candela; the approximate luminous intensity of a standard candle
fc: foot-candle; the intensity of light cast on a surface by a 1-cd source 1 ft away
lumen: the SI unit of luminous flux, equal to the amount of light emitted per second in a unit solid angle of one steradian from a uniform source of one candela
lux: the SI unit of illuminance, equal to one lumen per square meter
nW·sr^-1^/cm^2^: unit of radiance; nanowatt(s) per steradian per square centimeter (also, nW/cm^2^/sr)
µW/cm^2^: unit of irradiance; microwatt(s) per centimeter squared

Solid angles
sr: steradian; the SI unit of solid angle, i.e., of a cone within a sphere

Time
d: day(s)
hr: hour(s)
hr/night: hours(s) per night
hr/week: hour(s) per week
hour/week: hour(s) per week
min: minute(s)
mo: month(s)
yr: year(s)

Wavelength
nm: nanometer(s)