# Abbreviations

ACF: aberrant colon crypt foci
ACS: American Cancer Prevention Study II
Akt: protein kinase B
ALAN: artificial light at night
AMOLED: active-matrix organic LEDs
aMT6s: 6-sulfatoxymelatonin
BCEES: Breast Cancer Employment and Environment Study
BLS: Bureau of Labor Statistics
BMAL1: brain and muscle aryl hydrocarbon receptor nuclear translocator [ARNT]-like
BMI: body mass index
CBCS: Canadian Breast Cancer Study
CDC: Centers for Disease Control and Prevention
CECILE: Cote d’Or and Ille-et-Vilaine, France
CFL: compact fluorescent light
CI: confidence intervals
CJL: chronic jet lag
CLA: circadian light
CLOCK: circadian locomotor output cycles kaput
CRC: colorectal cancer
CS: circadian stimulus
D: day
DD: continuous dark; 24-hour dark
DEN: diethylnitrosamine
DLMO: dim light melatonin onset
DMBA: dimethylbenzanthracene
DMH: 1,2 dimethylhydrazine
DMSO: dimethylsulfoxide
DMSP: U.S. Defense Meteorological Satellite Program
DMSP-OLS: Defense Meteorological Satellite Program-Operational Linescan System
DNA: deoxyribonucleic acid
DOE: U.S. Department of Energy
DSLR: digital single-lens reflex
DSW: day shift workers
EBCLIS: Electromagnetic Fields and Breast Cancer on Long Island Study
EPICAP: Epidemiology of Prostate Cancer (study)
ER: estrogen receptor
ERK 1/2: extracellular signal-regulated kinase
F: female
FSH: follicle-stimulating hormone
GENICA: Gene Environment Interaction and Breast Cancer (study)
GSH-Px: glutathione peroxidase
HAL: halogen
HAT: histone acetyltransferase
HeLa: Henrietta Lacks cell line (namesake)
HER2: human epidermal growth factor receptor-2
HHS: Department of Health and Human Services
HPA: hypothalamic-pituitary-adrenal axis
HPG: hypothalamic-pituitary-gonadal axis
hr: hour
HR: hazard ratio
hTERT: telomerase reverse transcriptase
HWSE: healthy-worker survivor effect
I: inconclusive conclusions
IARC: International Agency for Research on Cancer
INC: incandescent
ISS: International Space Station
JEM: job exposure matrix
JRK: Jerky protein homolog
LAN: light at night
LCDs: liquid crystal displays
LD cycles: light:dark
LED: light emitting diode
LH: luteinizing hormone
LINE 1: long interspersed element-1
LL: 24-hour light; constand light; continuous light
LPS: lipopolysaccharide
M: male
MAPK: mitogen-activated protein kinase
MCC-Spain: Multi Case-Control-Spain (study)
miRNAs: micro ribonucleic acid
mo: month
mRNA: messenger ribonucleic acid
MSI: melatonin suppression index
N: night; number of particpants; study population
NASA: National Aeronautics and Space Administration
NCTR/FDA: National Center for Toxicological Research of the Food and Drug Administration
NDI: National Death Index
NEU: N-nitrosoethylurea
NHANES: National Health and Nutritional Examination Survey
NHIS–OHS: National Health Interview Survey and Occupational Health Supplement
NHL: non-Hodgkin lymphoma
NHS: Nurses Health Study
NHS2: Nurses’ Health Study 2
NIEHS/NIH: National Institutes of Health
NIOSH/CDC: National Institute for Occupational Safety and Health of the Centers for Disease Control and Prevention
NK: natural killer (cell)
NMU: N-nitroso-N-methylurea
NOS: nitric oxide synthase
NR: not reported
ns: not statistically significant
NSW: night shift workers
NTP: National Toxicology Program
OLED: organic LED(s)
OR: odds ratio
ORDET: Hormones and Diet in the Etiology of Breast Cancer Risk
P: probability value
PHS: Public Health Service
PR: progesterone receptor
Pre: premenopausal women
PSA: prostate-specific antigen
Ptrend: probability value-test for trend
REM: rapid eye movement
RGB: red [R], green [G], blue [B]
RNA: ribonucleic acid
RNU: Rowett nude rats
RoC: Report on Carcinogens
ROS: reactive oxygen species
RR: relative risk ratio
SAS: Swedish Scandinavian Airline System
SCN: suprachiasmatic nucleus
SD: standard deviation
SEEM: Selective Estrogen Enzyme Modulator
SEER: Surveillance, Epidemiology, and End Results
SERM: selective estrogen receptor modulator
SHR: spontaneously hypertensive rat
sign.: statistically significant
SIR: standardized incidence rate
SIR study: Swedish Cancer Registry or Cause of Death Register
SIRT1: sirtuin 1
SIRT6: sirtuin 6
SNPs: single nucleotide polymorphisms
SNS: sympathetic nervous system
SOD: superoxide dismutase
SPDs: spectral power distributions
SRR: standardized relative risk
STAT: signal transducer and activator of transcription
TBARs: thiobarbituric acid reactive substances
UaMT6s: urinary 6-sulphatoxymelatonin
UV-B: ultraviolet B radiation
VDR: vitamin D receptor
VEGF: vascular endothelial growth factor
WHI: Women’s Health Initiative
WOLF: Work, Lipids, and Fibrinogen
YA: younger age
yr: year