# Introduction

Modern electric lighting practices have facilitated a society in which people may work, sleep, and receive goods and services at any time of the day. People are exposed to ill-timed, unnatural, electric light (such as light at night, or “LAN”) through lifestyle choice, necessity, the locations of their residences, and employment during the night shift. As light is the critical regulator for circadian rhythms, exposure to LAN can cause circadian disruption, which can be linked to potential adverse health effects such as cancer.

The objective of this report is to conduct cancer hazard assessments for night shift work and exposure to LAN and to adequately define these two exposure scenarios based on the cancer hazard assessment.

- Night shift work is defined as typically working at least 3 hours between midnight and 5:00 AM, which is the time period most likely to be associated with circadian disruption. It is a complex exposure scenario that includes exposure to electric LAN, sleep disturbances, or changes in meal timing, as well as other potential exposures (e.g., decreased exposure to sunlight, and lower vitamin D levels). Sleep disturbances and changes in meal timing are also related to circadian disruption.
- LAN refers to exposure to light during the biological night which is the time when the circadian clock promotes sleep.

## Cancer Hazard Assessments

NTP proposed review of the two exposure circumstances—night shift work and light at night—because of ubiquitous exposure and concern for potential health effects. After obtaining input from the public and the NTP Board of Scientific Counselors, NTP selected these two exposure circumstances for review. Because of the complexity of this topic, the NTP convened a public workshop on March 10-11, 2016, to obtain external scientific input on topics important for informing the literature-based cancer hazard assessments, including strategies for integrating data across evidence streams (for more information see, https://ntp.niehs.nih.gov/go/workshop_ALAN). The panel recommended that the topic could be viewed as modern electric lighting practices and several of these experts also provided input on the development of the document. This information was used to develop the protocol for preparing the draft report. The Draft RoC Monograph^2^ was developed to support the scientific assessment to determine whether night shift work and light at night should be listed in the RoC. As noted in the Preface, following peer review (see “Peer Review”), a decision was made not to move forward with these two exposure scenarios for listing in the RoC and the RoC listing category recommendations were changed to cancer hazard assessment conclusions to avoid confusion.

1 Available at https://ntp.niehs.nih.gov/go/717273.