# Appendix G Night Shift Work and Lung Cancer

## Lung Cancer Studies Tables

Appendix G encompasses tables related to human studies on shift work exposure and risk of lung cancer. Tables G-1a to G-1f provide ratings and the rationales for the domains of study quality and study sensitivity. Table G-2 gives detailed results for each evaluated epidemiological study.

Table G-1a Evaluation of selection bias in lung cancer studies

Table G-1b Evaluation of exposure assessment methods in lung cancer studies

Table G-1c Evaluation of outcome assessment in lung cancer studies

Table G-1d Evaluation of study sensitivity in lung cancer studies

Table G-1e Evaluation of the potential for confounding bias in lung cancer studies

Table G-1f Evaluation of analysis and selective reporting in lung cancer studies

Table G-2 Evidence from epidemiological cohort and case-control studies on lung cancer and exposure to night shift work

## References

1 Jørgensen JT, Karlsen S, Stayner L, Andersen J, Andersen ZJ. 2017. Shift work and overall and cause-specific mortality in the Danish nurse cohort. Scand J Work Environ Health 43(2): 117–126. (Support not reported. Authors affiliated with University of Copenhagen, Denmark; University of Illinois at Chicago School of Public Health, IL; Danish Cancer Society, Denmark.)28245504
2 Kwon P, Lundin J, Li W, Ray R, Littell C, Gao D, Thomas DB, Checkoway H. 2015. Night shift work and lung cancer risk among female textile workers in Shanghai, China. J Occup Environ Hyg 12(5): 334–341. (Supported by NIH. Authors affiliated with Bassett Army Community Hospital, Alaska; University of Washington, WA; Fred Hutchinson Cancer Research Center, WA; Walter Reed Army Institute of Research, MD; Fudan University, China; University of California San Diego, CA.)25616851
3 Parent ME, El-Zein M, Rousseau MC, Pintos J, Siemiatycki J. 2012. Night work and the risk of cancer among men. Am J Epidemiol 176(9): 751–759. (Supported by the Health Canada, the National Cancer Institute of Canada, the Institut de recherche en santé et sécurité au travail du Québec, the Fonds de la recherche en santé du Québec, and the Canadian Institutes of Health Research. Authors affiliated with INRS, Canada.)23035019
4 Schernhammer ES, Feskanich D, Liang G, Han J. 2013. Rotating night-shift work and lung cancer risk among female nurses in the United States. Am J Epidemiol 178(9): 1434–1441. (Supported by NIH. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; ACR-ITR, Austria; LBI-ACR, Austria; Southeast University, China; Tianjin Medical University Cancer Institute and Hospital, China.)24049158
5 Schwartzbaum J, Ahlbom A, Feychting M. 2007. Cohort study of cancer risk among male and female shift workers. Scand J Work Environ Health 33(5): 336–343. (Supported by the Swedish Council for Working Life. Authors affiliated with Ohio State University, OH; Karolinska Institutet, Sweden.)17973059
6 Taylor PJ, Pocock SJ. 1972. Mortality of shift and day workers 1956-68. Br J Ind Med 29(2): 201–207. (Support not reported. Authors affiliated with London School of Hygiene and Tropical Medicine, UK.)5021999
7 Yong M, Blettner M, Emrich K, Nasterlack M, Oberlinner C, Hammer GP. 2014. A retrospective cohort study of shift work and risk of incident cancer among German male chemical workers. Scand J Work Environ Health 40(5): 502–510. (Supported by the Deutsche Gesetzliche Unfallversicherung. Authors affiliated with BASF SE, Germany; Johannes Gutenberg University Mainz, Germany; Laboratoire National de Santé, Luxembourg.)24892305