# Appendix F Night Shift Work and Female Hormonal Cancer

## Female Hormonal Cancer Studies Tables

Appendix F encompasses tables related to human studies on shift work exposure and risk of female hormonal cancers, which include ovarian and endometrial cancers. Tables F-1a to F-1f provide ratings and the rationales for the domains of study quality and study sensitivity. Table F-2 gives detailed results for each evaluated epidemiological study.

Table F-1a Evaluation of selection bias in female hormonal cancer studies

Table F-1b Evaluation of exposure assessment methods in female hormonal cancer studies

Table F-1c Evaluation of outcome assessment in female hormonal cancer studies

Table F-1d Evaluation of study sensitivity in female hormonal cancer studies

Table F-1e Evaluation of the potential for confounding bias in female hormonal cancer studies

Table F-1f Evaluation of analysis and selective reporting in female hormonal cancer studies

Table F-2 Evidence from epidemiological cohort and case-control studies on female hormonal cancer and exposure to night shift work

## References

1 Bhatti P, Cushing-Haugen KL, Wicklund KG, Doherty JA, Rossing MA. 2013. Nightshift work and risk of ovarian cancer. Occup Environ Med 70(4): 231–237. (Supported by the US National Cancer Institute. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; Geisel School of Medicine at Dartmouth, NH.)23343856
2 Carter BD, Diver WR, Hildebrand JS, Patel AV, Gapstur SM. 2014. Circadian disruption and fatal ovarian cancer. Am J Prev Med 46(3 Suppl 1): S34–S41. (Supported by the American Cancer Society. Authors affiliated with American Cancer Society, GA.)24512929
3 Jørgensen JT, Karlsen S, Stayner L, Andersen J, Andersen ZJ. 2017. Shift work and overall and cause-specific mortality in the Danish nurse cohort. Scand J Work Environ Health 43(2): 117–126. (Support not reported. Authors affiliated with University of Copenhagen, Denmark; University of Illinois at Chicago School of Public Health, IL; Danish Cancer Society, Denmark.)28245504
4 Poole EM, Schernhammer ES, Tworoger SS. 2011. Rotating night shift work and risk of ovarian cancer. Cancer Epidemiol Biomarkers Prev 20(5): 934–938. (Supported by NCI. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA: Harvard School of Public Health, MA: LBI-ACR & ACR-ITR VIEnna/CEADDP, Austria.)21467237
5 Schwartzbaum J, Ahlbom A, Feychting M. 2007. Cohort study of cancer risk among male and female shift workers. Scand J Work Environ Health 33(5): 336–343. (Supported by the Swedish Council for Working Life. Authors affiliated with Ohio State University, OH; Karolinska Institutet, Sweden.)17973059
6 Viswanathan AN, Hankinson SE, Schernhammer ES. 2007. Night shift work and the risk of endometrial cancer. Cancer Res 67(21): 10618–10622. (Supported by NIH. Authors affiliated with Harvard Medical School, MA; Brigham and Women’s Hospital, MA; Applied Cancer Research-Institute for Translational Research Vienna, Austria.)17975006