# Appendix E Night Shift Work and Colorectal Cancer

## Colorectal Cancer Studies Tables

Appendix E encompasses tables related to human studies on shift work exposure and risk of colorectal cancer. Tables E-1a to E-1f provide ratings and the rationales for the domains of study quality and study sensitivity. Table E-2 gives detailed results for each evaluated epidemiological study.

Table E-1a Evaluation of selection bias in human colorectal cancer studies

Table E-1b Evaluation of exposure assessment methods in human colorectal cancer studies

Table E-1c Evaluation of outcome assessment in human colorectal cancer studies

Table E-1d Evaluation of study sensitivity for human colorectal cancer studies

Table E-1e Evaluation of potential for confounding bias in human colorectal cancer studies

Table E-1f Evaluation of analysis and selective reporting for human colorectal cancer studies

Table E-2 Evidence from epidemiological cohort and case-control studies on colorectal cancer and exposure to night shift work

## References

1 Australian Bureau of Statistics. 2013. Working Time Arrangements, Australia. https://www.abs.gov.au/AUSSTATS/abs@.nsf/mf/6342.0.
2 Hammer GP, Emrich K, Nasterlack M, Blettner M, Yong M. 2015. Shift work and prostate cancer incidence in industrial workers: A historical cohort study in a German chemical company. Dtsch Arztebl Int 112(27–28): 463–470. (Supported by the German Social Accident Insurance. Authors affiliated with Johannes Gutenberg University, Germany; Laboratoire National de Santé, Luxembourg; Occupational Medicine and Health Protection, BASF SE, Germany.)26214232
3 Jørgensen JT, Karlsen S, Stayner L, Andersen J, Andersen ZJ. 2017. Shift work and overall and cause-specific mortality in the Danish nurse cohort. Scand J Work Environ Health 43(2): 117–126. (Support not reported. Authors affiliated with University of Copenhagen, Denmark; University of Illinois at Chicago School of Public Health, IL; Danish Cancer Society, Denmark.)28245504
4 Papantoniou K, Castaño-Vinyals G, Espinosa A, Turner MC, Alonso-Aguado MH, Martin V, Aragonés N, Pérez-Gómez B, Pozo BM, Gómez-Acebo I, Ardanaz E, Altzibar JM, Peiro R, Tardon A, Lorca JA, Chirlaque MD, García-Palomo A, Jimenez-Moleon JJ, Ierssen T, Ederra M, Amiano P, Pollan M, Moreno V, Kogevinas M. 2017. Shift work and colorectal cancer risk in the MCC-Spain case-control study. Scand J Work Environ Health 43(3): 250–259. (Supported by the “Accion Transversal del Cancer”, approved on the Spanish Ministry Council on 11 October 2007, by the Instituto de Salud Carlos III-FEDER, by the Fundación Marqués de Valdecilla, by the ICGC International Cancer Genome Consortium CLL [The ICGC CLL-Genome Project is funded by Spanish Ministerio de Economía y Competitividad [MINECO] through the Instituto de Salud Carlos III [ISCIII] and Red Temática de Investigación del Cáncer [RTICC] del ISCIII], by the Junta de Castilla y León, by the Consejería de Salud of the Junta de Andalucía, by the Conselleria de Sanitat of the Generalitat Valenciana, by the Recercaixa, by the European Commission grants, by the Spanish Association Against Cancer [AECC] Scientific Foundation, by the Catalan Government DURSI grant, by a predoctoral grant PFIS, by FEDER, by the European Commission, by the the Catalan Government DURSI, and by the Canadian Institutes of Health Research. Authors affiliated with CREAL, Spain; Medical University of Vienna, Austria; IMIM, Spain; Universitat Pompeu Fabra, Spain; University of Ottawa, Canada; IDIBELL, Spain; Hospitalet de Llobregat, Spain; Universidad de León, Spain; Carlos III Health Institute, Spain; IIS Puerta de Hierro, Spain; Complejo Hospitales Universitarios de Granada, Spain; University of Cantabria, Spain; Instituto de Salud Publica de Navarra, Spain; Navarra Institute for Health Research, Spain; Public Health Division of Gipuzkoa, Spain; Biodonostia Research Institute, Spain; FISABIO, Spain; Universidad de Oviedo, Spain; CYSMA, Spain; Universidad de Huelva, Spain; IMIB-Arrixaca, Spain; Universidad Murcia, Spain; Universidad de Granada, Spain; University of Barcelona, Spain; CIBERESP, Spain.)28251241
5 Papantoniou K, Devore EE, Massa J, Strohmaier S, Vetter C, Yang L, Shi Y, Giovannucci E, Speizer F, Schernhammer ES. 2018. Rotating night shift work and colorectal cancer risk in the Nurses’ Health Studies. Int J Cancer 143(11): 2709–2717. (Supported by CDC/NIOSH and NIH. Authors affiliated with Medical University of Vienna, Austria; Brigham and Women’s Hospital, MA: Harvard Medical School, MA; Harvard T. H. Chan School of Public Health, MA; University of Colorado, CO; Chinese PLA General Hospital, China.)29978466
6 Parent ME, El-Zein M, Rousseau MC, Pintos J, Siemiatycki J. 2012. Night work and the risk of cancer among men. Am J Epidemiol 176(9): 751–759. (Supported by the Health Canada, the National Cancer Institute of Canada, the Institut de recherche en santé et sécurité au travail du Québec, the Fonds de la recherche en santé du Québec, and the Canadian Institutes of Health Research. Authors affiliated with INRS, Canada; University of Quebec, Canada; CRCHUM, Canada; University of Montreal, Canada.)23035019
7 Schwartzbaum J, Ahlbom A, Feychting M. 2007. Cohort study of cancer risk among male and female shift workers. Scand J Work Environ Health 33(5): 336–343. (Supported by the Swedish Council for Working Life. Authors affiliated with Ohio State University, OH; Karolinska Institutet, Sweden.)17973059
8 Walasa WM, Carey RN, Si S, Fritschi L, Heyworth JS, Fernandez RC, Boyle T. 2018. Association between shiftwork and the risk of colorectal cancer in females: a population-based case-control study. Occup Environ Med 75: 344–350. (Supported by the Australian National Health and Medical Research Council, the University of Adelaide, NHMRC, Canadian Institutes of Health Research, and the Cancer Council Western Australia. Authors affiliated with Curtin University, Australia; University of Western Australia, Australia; University of Adelaide, Australia; University of South Australia, Australia.)29438001
9 Yong M, Blettner M, Emrich K, Nasterlack M, Oberlinner C, Hammer GP. 2014. A retrospective cohort study of shift work and risk of incident cancer among German male chemical workers. Scand J Work Environ Health 40(5): 502–510. (Supported by the Deutsche Gesetzliche Unfallversicherung. Authors affiliated with BASF SE, Germany; Johannes Gutenberg University Mainz, Germany; Laboratoire National de Santé, Luxembourg.)24892305