# Appendix D Night Shift Work and Prostate Cancer

## Prostate Cancer Studies Tables

Appendix D encompasses tables related to human studies on shift work exposure and risk of prostate cancer. Tables D-1a to D-1f provide ratings and the rationales for the domains of study quality and study sensitivity. Table D-2 gives detailed results for each evaluated epidemiological study.

Table D-1a Evaluation of selection bias in human prostate cancer studies

Table D-1b Evaluation of exposure assessment methods in human prostate cancer studies

Table D-1c Evaluation of outcome assessment in human prostate cancer studies

Table D-1d Evaluation of study sensitivity in human prostate cancer studies

Table D-1e Evaluation of potential for confounding bias for human prostate cancer studies

Table D-1f Evaluation of analysis and selective reporting for human prostate cancer studies

Table D-2 Evidence from epidemiological cohort and case-control studies on prostate cancer and exposure to night shift work

## References

1 Åkerstedt T, Narusyte J, Svedberg P, Kecklund G, Alexanderson K. 2017. Night work and prostate cancer in men: a Swedish prospective cohort study. BMJ Open 7(6): e015751. (Supported by the AFA Insurance Company. Authors affiliated with Karolinska Institutet, Sweden; Stockholm University, Sweden; Radboud University, Netherlands.)
2 Behrens T, Rabstein S, Wichert K, Erbel R, Eisele L, Arendt M, Dragano N, Brüning T, Jöckel KH. 2017. Shift work and the incidence of prostate cancer: a 10-year follow-up of a German population-based cohort study. Scand J Work Environ Health 43(6): 560–568. (Supported by the German Social Accident Insurance, the Heinz Nixdorf Foundation, the German Ministry of Education and Science, the Kulturstiftung Essen, and the German Research Foundation. Authors affiliated with Institute of the Ruhr-Universität Bochum, Germany; University Hospital of Essen, Germany; Heinrich Heine University, Getmany.)28879368
3 Conlon M, Lightfoot N, Kreiger N. 2007. Rotating shift work and risk of prostate cancer. Epidemiology 18(1): 182–183. (Support not reported. Authors affiliated with Sudbury Regional Hospital, Canada; Ontario School of Medicine, Canada; University of Toronto, Canada.)17179764
4 Dickerman BA, Markt SC, Koskenvuo M, Hublin C, Pukkala E, Mucci LA, Kaprio J. 2016. Sleep disruption, chronotype, shift work, and prostate cancer risk and mortality: a 30-year prospective cohort study of Finnish twins. Cancer Causes Control 27(11): 1361–1370. (Suppored by NCI, NIH, and the Academy of Finland. Authors affiliated with Harvard T.H. Chan School of Public Health, MA; University of Helsinki, Finland; Finnish Institute of Occupational Health, Finland; Finnish Cancer Registry, Finland; University of Tampere, Finland; National Institute for Health and Welfare, Finland.)27734240
5 Gapstur SM, Diver WR, Stevens VL, Carter BD, Teras LR, Jacobs EJ. 2014. Work schedule, sleep duration, insomnia, and risk of fatal prostate cancer. Am J Prev Med 46(3 Suppl 1): S26–33. (Supported by the American Cancer Society. Authors affiliated with American Cancer Society, GA.)24512928
6 Hammer GP, Emrich K, Nasterlack M, Blettner M, Yong M. 2015. Shift work and prostate cancer incidence in industrial workers: A historical cohort study in a German chemical company. Dtsch Arztebl Int 112(27–28): 463–470. (Supported by the German Social Accident Insurance. Authors affiliated with Johannes Gutenberg University, Germany; Laboratoire National de Santé, Luxembourg; Occupational Medicine and Health Protection, BASF SE, Germany.)26214232
7 Kubo T, Ozasa K, Mikami K, Wakai K, Fujino Y, Watanabe Y, Miki T, Nakao M, Hayashi K, Suzuki K, Mori M, Washio M, Sakauchi F, Ito Y, Yoshimura T, Tamakoshi A. 2006. Prospective cohort study of the risk of prostate cancer among rotating-shift workers: findings from the Japan collaborative cohort study. Am J Epidemiol 164(6): 549–555. (Supported by the Ministry of Education, Science, Sports and Culture of Japan. Authors affiliated with University of Occupational and Environmental Health, Japan; Kyoto Prefectural University of Medicine, Japan; Aichi Cancer Center Research Institute, Japan; Fukuoka Institute of Occupational Health, Japan; Meiji University of Oriental Medicine, Japan; Fujita Health University School of Health Sciences, Japan; Sapporo Medical University School of Medicine, Japan; Nagoya University Graduate School of Medicine, Japan; Fukuoka Institute of Health and Environmental Sciences, Japan.)16829554
8 Kubo T, Oyama I, Nakamura T, Kunimoto M, Kadowaki K, Otomo H, Fujino Y, Fujimoto N, Matsumoto T, Matsuda S. 2011. Industry-based retrospective cohort study of the risk of prostate cancer among rotating-shift workers. Int J Urol 18(3): 206–211. (Supported by KAKENHI, the the Ministry of Education, Culture, Sports, Science and Technology, Japan, and the Occupational Health Promotion Foundation, Japan. Authors affiliated with University of Occupational and Environmental Health, Japan; Asahi Kasei Nobeoka Office Health Care Center, Japan; Asahi Kasei Chemicals Mizushima Works Health Care Center, Japan.)21332815
9 Papantoniou K, Castano-Vinyals G, Espinosa A, Aragones N, Perez-Gomez B, Burgos J, Gomez-Acebo I, Llorca J, Peiro R, Jimenez-Moleon JJ, Arredondo F, Tardon A, Pollan M, Kogevinas M. 2015. Night shift work, chronotype and prostate cancer risk in the MCC-Spain case-control study. Int J Cancer 137(5): 1147–1157. (Supported by the “Accion Transversal del Cancer,” Spanish Ministry Council, the Instituto de Salud Carlos III-FEDER, and a predoctoral grant PFIS. Authors affiliated with Centre for Research in Environmental Epidemiology [CREAL], Spain; IMIM [Hospital Del Mar Medical Research Institute], Spain; Universitat Pompeu Fabra [UPF], Spain; CIBER Epidemiologıa Y Salud Publica, Spain; Carlos III Health Institute, Spain; Cancer Epidemiology Research Group, Spain; Hospital Ramon Y Cajal, Spain; Instituto Ramon Y Cajal De Investigacion Sanitaria, Spain; Universidad De Alcala De Henares, Spain; University of Cantabria, Spain; IDIVAL, Spain; Fundacion Para El Fomento De La Investigacion Sanitaria Y Biomedica De La Comunidad Valenciana, Spain; Hospitales Universitarios De Granada/Universidad De Granada, Spain; Hospital Infanta Elena, Spain; Universidad De Huelva, Spain; Universidad De Oviedo, Spain; National School of Public Health, Greece.)25530021
10 Parent ME, El-Zein M, Rousseau MC, Pintos J, Siemiatycki J. 2012. Night work and therisk of cancer among men. Am J Epidemiol 176(9): 751–759. (Supported by the Health Canada, the National Cancer Institute of Canada, the Institut de recherche en santé et sécurité au travail du Québec, the Fonds de la recherche en santé du Québec, and the Canadian Institutes of Health Research. Authors affiliated with INRS, Canada.)23035019
11 Schwartzbaum J, Ahlbom A, Feychting M. 2007. Cohort study of cancer risk among male and female shift workers. Scand J Work Environ Health 33(5): 336–343. (Supported by the Swedish Council for Working Life. Authors affiliated with Ohio State University, OH; Karolinska Institutet, Sweden.)17973059
12 Tse LA, Lee PMY, Ho WM, Lam AT, Lee MK, Ng SSM, He Y, Leung KS, Hartle JC, Hu H, Kan H, Wang F, Ng CF. 2017. Bisphenol A and other environmental risk factors for prostate cancer in Hong Kong. Environ Int 107: 1–7. (Supported by the Health and Medical Research Fund, Hong Kong Special Administrative Region, China. Authors affiliated with Chinese University of Hong Kong, China; Prince of Wales Hospital, China; Guilin Medical College, China; Hong Kong Polytechnic University, China; San Jose State University, CA; University of Toronto, Canada; Fudan University, China.)28644961
13 Wendeu-Foyet MG, Bayon V, Cénée S, Trétarre B, Rébillard X, Cancel-Tassin G, Cussenot O, Lamy PJ, Faraut B, Kheder SB, Léger D, Menegaux F. 2018. Night work and prostate cancer risk: Results from the EPICAP study. OEM 75(8): 573–581. (Supported by the Institut National du Cancer, Fondation ARC, the Ligue nationale contre le cancer, the Ligue contre le cancer du Val-de-Marne, Fondation de France, Agence nationale de sécurité sanitaire de l’alimentation, de l’environnement et du travail [ANSES], and Paris-Sud University. Authors affiliated with INSERM, France; Hôtel Dieu, France; VIFASOM, France; Hérault Cancer Registry, France; Clinique Beau Soleil, France; Hopital Tenon, France; Sorbonne Université, France; Imagenome, France.)