# Appendix C Light at Night, Transmeridian Travel and Breast Cancer

## Quality rankings and results

Appendix C includes the rationales for quality rankings of studies of breast cancer and light at night reported in Section 3.3, Table 3-9. The rationales for the quality ratings of indoor and outdoor studies of breast cancer and light at night are shown in Tables C-1a-f. Results for the indoor and outdoor studies of breast cancer and light at night are shown in Appendix C: Table 2.

Appendix C also includes rationales for quality rankings of studies of breast cancer and transmeridian travel reported in Section 3.4, Table 3-13. The rationales for these rankings are shown in Appendix C: Table C-5. Results of the breast cancer and transmeridian travel studies are shown in Appendix C: Table C-6.

Table C-1a Breast cancer and lighting at night (LAN) – Indoor and Outdoor: Selection bias rationale

Table C-1b Breast cancer and lighting at night (LAN) – Indoor and Outdoor: Exposure assessment rationale

Table C-1c Breast cancer and lighting at night (LAN) – Indoor and Outdoor: Outcome assessment rationale

Table C-1d Breast cancer and lighting at night (LAN) – Indoor and outdoor: Sensitivity rationale

Table C-1e Breast cancer and lighting at night (LAN) – Indoor and outdoor: Confounding rationale

Table C-1f Breast cancer and lighting at night (LAN) – Indoor and outdoor: Analysis and selective reporting rationale

Table C-2 Breast cancer and light at night (LAN) study results – Indoor and outdoor

Table C-3a Breast cancer and transmeridian travel: Selection bias rationale

Table C-3b Breast cancer and transmeridian travel: Exposure assessment rationale

Table C-3c Breast cancer and transmeridian travel: Outcome assessment rationale

Table C-3d Breast cancer and transmeridian travel: Sensitivity rationale

Table C-3e Breast cancer and transmeridian travel: Confounding rationale

Table C-3f Breast cancer and transmeridian travel: Analysis and selective reporting rationale

Table C-4 Breast cancer and transmeridian travel study results

## References

1 Bauer SE, Wagner SE, Burch J, Bayakly R, Vena JE. 2013. A case-referent study: light at night and breast cancer risk in Georgia. Int J Health Geogr 12: 23. (Supported by the Georgia Cancer Coalition. Authors affiliated with University of Georgia, GA; University of South Carolina, SC; Georgia Comprehensive Cancer Registry, GA.)23594790
2 Davis S, Kaune WT, Mirick DK, Chen C, Stevens RG. 2001a. Residential magnetic fields, light-at-night, and nocturnal urinary 6-sulfatoxymelatonin concentration in women. Am J Epidemiol 154(7): 591–600. (Supported by the Electric Power Research Institute. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Washington, WA; EM Factors, WA; University of Connecticut Health Center, CT.)11581092
3 Davis S, Mirick DK, Stevens RG. 2001b. Night shift work, light at night, and risk of breast cancer. J Natl Cancer Inst 93(20): 1557–1562. (Supported by the National Cancer Institute, National Institutes of Health, Department of Health and Human Services. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Connecticut Health Center, CT.)11604479
4 Fritschi L, Erren TC, Glass DC, Girschik J, Thomson AK, Saunders C, Boyle T, El-Zaemey S, Rogers P, Peters S, Slevin T, D’Orsogna A, de Vocht F, Vermeulen R, Heyworth JS. 2013. The association between different night shiftwork factors and breast cancer: a case-control study. Br J Cancer 109(9): 2472–2480. (Supported by the National Health and Medical Research Council Australia, the Cancer Council Western Australia, the University of Western Australia, and the Lions Cancer Institute. Authors affiliated with University of Western Australia, Australia; University of Cologne, Germany; Monash University, Australia; Cancer Council Western Australia, Australia; Health Consumer Representative, Australia; University of Manchester, UK; Utrecht University, Netherlands.)24022188
5 Garcia-Saenz A, Sánchez de Miguel A, Espinosa A, Valentin A, Aragonés N, Llorca J, Amiano P, Martín Sánchez V, Guevara M, Capelo R, Tardón A, Peiró-Perez R, Jiménez-Moleón JJ, Roca-Barceló A, Pérez-Gómez B, Dierssen-Sotos T, Fernández-Villa T, Moreno-Iribas C, Moreno V, García-Pérez J, Castaño-Vinyals G, Pollán M, Aubé M, Kogevinas M. 2018. Evaluating the association between artificial light-at-night exposure and breast and prostate cancer risk in Spain (MCC-Spain Study). Environ Health Perspect 126(4): 047011. (Supported by the Accion Transversal del Cancer, Instituto de Salud Carlos III-FEDER, the Fundación Marqués de Valdecilla, the ICGC International Cancer Genome Consortium CLL, MINECO, RTICC, the Junta de Castillay León, Consejería de Salud of the Junta de Andalucía, the Conselleria de Sanitat of the Generalitat Valenciana, the Regional Government of the Basque Country, the Consejería de Sanidad de la Región de Murcia, the European Commission, AECC, the Catalan Government–Agency for Management of University and Research, the Fundación Caja de Ahorros de Asturias, the University of Oviedo, CERCA, the STARS4ALL project, the European Union, and the Cities at Night project. Authors affiliated with Barcelona Institute for Global Health, Spain; CIBER, Spain, CIBERESP, Spain; IAA, Spain; CSIC, Spain; Universidad Complutense de Madrid, Spain; Cégep de Sherbrooke, Canada; University Exeter, UK; IMIM, Spain; National Centre for Epidemiology, Spain; IDIVAL, Spain; Health Department of Basque Region, Spain; University of León, Spain; IdiSNA, Spain; CYSMA, Spain; IUOPA, Spain; FISABIO, Spain; University of Granada, Spain; ibs.GRANADA, Spain; Autonomous Government of Catalonia, Spain; REDISSEC, Spain; IDIBELL, Spain; University of Barcelona, Spain.)29687979
6 Gu F, Han JL, Hankinson S, Schernhammer E, Nurses’ Hlth Study G. 2014. Rotating night shift work and cancer mortality in the nurses’ health study. Cancer Research 74(19): 2.
7 Hurley S, Goldberg D, Nelson D, Hertz A, Horn-Ross PL, Bernstein L, Reynolds P. 2014. Light at night and breast cancer risk among California teachers. Epidemiology 25(5): 697–706. (Supported by the Regents of the University of California, California Breast Cancer Research Program and the National Cancer Institute. Authors affiliated with Cancer Prevention Institute of California, CA; Beckman Research Institute, CA; Stanford University School of Medicine, CA.)25061924
8 James P, Bertrand KA, Hart JE, Schernhammer ES, Tamimi RM, Laden F. 2017. Outdoor light at night and breast cancer incidence in the Nurses’ Health Study II. Environ Health Perspect 125(8): 087010. (Supported by the Harvard National Heart, Lung, and Blood Institute, NIH, NCI, and the Susan G. Komen for the Cure® organization. Authors affiliated with Harvard T. H. Chan School of Public Health, MA; Brigham and Women’s Hospital and Harvard Medical School, MA; Boston University, MA; Medical University of Vienna, Austria; University of California Los Angeles, CA.)28886600
9 Johns LE, Jones ME, Schoemaker MJ, McFadden E, Ashworth A, Swerdlow AJ. 2018. Domestic light at night and breast cancer risk: a prospective analysis of 105 000 UK women in the Generations Study. Br J Cancer 118(4): 600–606. (Supported by Breast Cancer Now, The Institute of Cancer Research, and NHS. Authors affiliated with Institute of Cancer Research, UK; Breast Cancer Now Research Centre, UK.)29360812
10 Keshet-Sitton A, Or-Chen K, Yitzhak S, Tzabary I, Haim A. 2016. Can avoiding light at night reduce the risk of breast cancer? Integr Cancer Ther 15(2): 145–152. (No financial support received. Authors affiliated with University of Haifa, Israel; Poria Medical Center, Israel; Soroka University Medical Center, Israel.)26631258
11 Kloog I, Portnov BA, Rennert HS, Haim A. 2011. Does the modern urbanized sleeping habitat pose a breast cancer risk? Chronobiol Int 28(1): 76–80. (Support not reported. Authors affiliated with University of Haifa, Israel; Technion–Israel Institute of Technology and Clalit Health Services National Cancer Control Center, Israel; Harvard School of Public Health, MA.)21182407
12 Kwon P, Lundin J, Li W, Ray R, Littell C, Gao D, Thomas DB, Checkoway H. 2015. Night shift work and lung cancer risk among female textile workers in Shanghai, China. J Occup Environ Hyg 12(5): 334–341. (Supported by NIH. Authors affiliated with Bassett Army Community Hospital, Alaska; University of Washington, WA; Fred Hutchinson Cancer Research Center, WA; Walter Reed Army Institute of Research, MD; Fudan University, China; University of California San Diego, CA.)25616851
13 Lash TL, Fox MP, Fink AK. 2009. Applying Quantitative Bias Analysis to Epidemiologic Data, New York, NY: Springer-Verlag. 192 pp.
14 Li Q, Zheng T, Holford TR, Boyle P, Zhang Y, Dai M. 2010. Light at night and breast cancer risk: results from a population-based case-control study in Connecticut, USA. Cancer Causes Control 21(12): 2281–2285. (Supported by the National Cancer Institute/National Institute of Environmental Health Science. Authors affiliated with Huazhong University of Science and Technology, China; Yale School of Public Health, CT; International Prevention Research Institute, France; Chinese Academy of Medical Sciences, China.)20927578
15 Linnersjö A, Hammar N, Dammström BG, Johansson M, Eliasch H. 2003. Cancer incidence in airline cabin crew: experience from Sweden. Occup Environ Med 60(11): 810–814. (Supported by the Swedish Council for Work Life Research. Authors affiliated with Stockholm Center of Public Health, Sweden; Swedish SAS, Sweden; Swedish Air Force, Sweden.)14573710
16 O’Leary ES, Schoenfeld ER, Stevens RG, Kabat GC, Henderson K, Grimson R, Gammon MD, Leske MC, for the Electromagnetic Fields Breast Cancer on Long Island Study Group. 2006. Shift work, light at night, and breast cancer on Long Island, New York. Am J Epidemiol 164(4): 358–366. (Supported by NCI and NIEHS. Authors affiliated with Stony Brook University, NY; University of Connecticut Health Center, CT; University of North Carolina at Chapel Hill, NC.)16777931
17 Parent ME, El-Zein M, Rousseau MC, Pintos J, Siemiatycki J. 2012. Night work and the risk of cancer among men. Am J Epidemiol 176(9): 751–759. (Supported by the Health Canada, the National Cancer Institute of Canada, the Institut de recherche en santé et sécurité au travail du Québec, the Fonds de la recherche en santé du Québec, and the Canadian Institutes of Health Research. Authors affiliated with INRS, Canada; University of Quebec, Canada; CRCHUM, Canada; University of Montreal, Canada.)23035019
18 Pinkerton LE, Waters MA, Hein MJ, Zivkovich Z, Schubauer-Berigan MK, Grajewski B. 2012. Cause-specific mortality among a cohort of U.S. flight attendants. Am J Ind Med 55(1): 25–36. (Supported by the Office of Women’s Health of the U.S. Department of Health and Human Services. Authors affiliated with NIOSH, OH.)21987391
19 Pinkerton LE, Hein MJ, Anderson JL, Little MP, Sigurdson AJ, Schubauer-Berigan MK. 2016. Breast cancer incidence among female flight attendants: exposure-response analyses. Scand J Work Environ Health 42(6): 538–546. (Supported by NCI, USDHHS, and NIOSH. Authors affiliated with NIOSH, OH; CACI, Inc., OH; NCI, MD.)27551752
20 Pukkala E, Helminen M, Haldorsen T, Hammar N, Kojo K, Linnersjö A, Rafnsson V, Tulinius H, Tveten U, Auvinen A. 2012. Cancer incidence among Nordic airline cabin crew. Int J Cancer 131(12): 2886–2897. (Supported by the Nordic Cancer Union. Authors affiliated with Finnish Cancer Registry, Finland; University of Tampere, Finland; Cancer Registry of Norway, Norway; Karolinska Institutet, Sweden; STUK-Radiation and Nuclear Safety Authority, Finland; University of Iceland, Iceland; Icelandic Cancer Registry, Iceland; Institute for Energy Technology, Norway.)22447246
21 Reynolds P, Cone J, Layefsky M, Goldberg DE, Hurley S. 2002. Cancer incidence in California flight attendants (United States). Cancer Causes Control 13(4): 317–324. (Supported by the California Breast Cancer Research Program. Authors affiliated with California Department of Health Services, CA; Public Health Institute, CA.)12074501
22 Schernhammer ES, Feskanich D, Liang G, Han J. 2013. Rotating night-shift work and lung cancer risk among female nurses in the United States. Am J Epidemiol 178(9): 1434–1441. (Supported by NIH. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; ACR-ITR, Austria; LBI-ACR, Austria; Southeast University, China; Tianjin Medical University Cancer Institute and Hospital, China.)24049158
23 Schubauer-Berigan MK, Anderson JL, Hein MJ, Little MP, Sigurdson AJ, Pinkerton LE. 2015. Breast cancer incidence in a cohort of U.S. flight attendants. Am J Ind Med 58(3): 252–266. (Supported by the National Cancer Institute and the Office of Women’s Health of the U.S. Department of Health and Human Services. Authors affiliated with NIOSH, OH; NCI, MD.)25678455
24 Wacholder S, Silverman DT, McLaughlin JK, Mandel JS. 1992. Selection of controls in case-control studies. II. Types of controls. Am J Epidemiol 135(9): 1029–1041. (Support not reported. Authors affiliated with NCI, MD; University of Minnesota, MN.)1595689
25 White AJ, Weinberg CR, Park YM, D’Aloisio AA, Vogtmann E, Nichols HB, Sandler DP. 2017. Sleep characteristics, light at night and breast cancer risk in a prospective cohort. Int J Cancer 141(11): 2204–2214. (Supported by NIH. Authors affiliated with NIEHS, NC; NIH, NC; Social & Scientific Systems, Inc., NC; University of North Carolina, NC.)28791684
26 Yong M, Blettner M, Emrich K, Nasterlack M, Oberlinner C, Hammer GP. 2014. A retrospective cohort study of shift work and risk of incident cancer among German male chemical workers. Scand J Work Environ Health 40(5): 502–510. (Supported by the Deutsche Gesetzliche Unfallversicherung. Authors affiliated with BASF SE, Germany; Johannes Gutenberg University Mainz, Germany; Laboratoire National de Santé, Luxembourg.)24892305