# Appendix B Night Shift Work and Breast Cancer

## Quality rankings and results

This appendix includes the rationales for quality rankings of studies of breast cancer and shift work reported in Section 3.2 by type of quality criteria (e.g., (a) selection bias, (b) exposure assessment, (c) outcome assessment, (d) sensitivity, (e) potential confounding, (f) analysis rating).

Quality rankings are reported in Section 3.2 in Tables 3-2 and 3-3; their rationales are shown in Appendix B: Table B-1a-f for cohort studies of breast cancer and shift work; and in Appendix B: Table B-2a-f for case-control studies of breast cancer and shift work.

Results for the cohort studies of breast cancer and shift work are found in Appendix B, Table B-3; results for case-control studies of breast cancer and shift work are found in Appendix B: Table B-4.

Table B-1a Breast cancer and shiftwork COHORT studies: Selection bias rationale

Table B-1b Breast cancer and shiftwork COHORT studies: Exposure assessment rationale

Table B-1c Breast cancer and shiftwork COHORT Studies: Outcome assessment rationale

Table B-1d Breast cancer and shiftwork COHORT Studies: Sensitivity rationale

Table B-1e Breast cancer and shiftwork COHORT studies: Confounding rationale

Table B-1f Breast cancer and shiftwork COHORT studies: Analysis and selective reporting rationales

Table B-2a Breast cancer and shiftwork CASE-CONTROL studies: Selection bias rationale

Table B-2b Breast cancer and shiftwork CASE-CONTROL studies: Exposure assessment rationale

Table B-2c Breast cancer and shiftwork CASE-CONTROL studies: Outcome assessment rationale

Table B-2d Breast cancer and shiftwork CASE-CONTROL studies: Sensitivity rationale

Table B-2e Breast cancer and shiftwork CASE-CONTROL studies: Confounding rationale

Table B-2f Breast cancer and shiftwork CASE-CONTROL studies: Analysis and selective reporting rationale

Table B-3 Breast cancer and shiftwork COHORT study results

Table B-4 Breast cancer and shiftwork CASE-CONTROL study results

## References

1 Åkerstedt T, Knutsson A, Narusyte J, Svedberg P, Kecklund G, Alexanderson K. 2015. Night work and breast cancer in women: a Swedish cohort study. BMJ Open 5(4): e008127. (Supported by the AFA Insurance Company. Authors affiliated with Karolinska Institutet, Sweden; Stockholm University, Sweden; Mid Sweden University, Sweden; Radboud University, Netherlands.)
2 Cordina-Duverger E, Koudou Y, Truong T, Arveux P, Kerbrat P, Menegaux F, Guénel P. 2016. Night work and breast cancer risk defined by human epidermal growth factor receptor-2 (HER2) and hormone receptor status: A population-based case-control study in France. Chronobiol Int 33(6): 783–787. (Supported by the Agence nationale de sécurité sanitaire de l’alimentation, de l’environnement et du travail [ANSES], the Agence Nationale de la Recherche [ANR]; Fondation de France, the Institut National du Cancer [INCA], and the Ligue contre le Cancer. Authors affiliated with INSERM, France; Centre Georges-François Leclerc, France; Centre Eugène Marquis, France.)27078711
3 Cordina-Duverger E, Menegaux F, Popa A, Rabstein S, Harth V, Pesch B, Brüning T, Fritschi L, Glass DC, Heyworth JS, Erren TC, Castaño-Vinyals G, Papantoniou K, Espinosa A, Kogevinas M, Grundy A, Spinelli JJ, Aronson KJ, Guénel P. 2018. Night shift work and breast cancer: a pooled analysis of population-based case-control studies with complete work history. Eur J Epidemiol. (Support not reported. Authors affiliated with INSERM, France; Institute of the Ruhr-Universität Bochum, Germany; University Medical Center Hamburg-Eppendorf, Germany; Curtin University, Australia; Monash University, Australia; University of Western Australia, Australia; University of Cologne, Germany; CREAL, Spain; IMIM, Spain; Universitat Pompeu Fabra, Spain; CIBERESP, Spain; Medical University of Vienna, Austria; CRCHUM, Canada; Universite´ de Montréal, Canada; BC Cancer, Canada; University of British Columbia, Canada; Queen’s University, Canada.)
4 Davis S, Mirick DK, Stevens RG. 2001. Night shift work, light at night, and risk of breast cancer. J Natl Cancer Inst 93(20): 1557–1562. (Supported by the National Cancer Institute, National Institutes of Health, Department of Health and Human Services. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Connecticut Health Center, CT.)11604479
5 Fritschi L, Erren TC, Glass DC, Girschik J, Thomson AK, Saunders C, Boyle T, El-Zaemey S, Rogers P, Peters S, Slevin T, D’Orsogna A, de Vocht F, Vermeulen R, Heyworth JS. 2013. The association between different night shiftwork factors and breast cancer: a case-control study. Br J Cancer 109(9): 2472–2480. (Supported by the National Health and Medical Research Council Australia, the Cancer Council Western Australia, the University of Western Australia, and the Lions Cancer Institute. Authors affiliated with University of Western Australia, Australia; University of Cologne, Germany; Monash University, Australia; Cancer Council Western Australia, Australia; Health Consumer Representative, Australia; University of Manchester, UK; Utrecht University, Netherlands.)24022188
6 Grundy A, Richardson H, Burstyn I, Lohrisch C, SenGupta SK, Lai AS, Lee D, Spinelli JJ, Aronson KJ. 2013. Increased risk of breast cancer associated with long-term shift work in Canada. Occup Environ Med 70(12): 831–838. (Supported by the Canadian Institutes of Health Research. Authors affiliated with Queen’s University, Canada; Drexel University, PA; British Columbia Cancer Agency, Canada; University of British Columbia, Canada.)23817841
7 Gu F, Han J, Laden F, Pan A, Caporaso NE, Stampfer MJ, Kawachi I, Rexrode KM, Willett WC, Hankinson SE, Speizer FE, Schernhammer ES. 2015. Total and cause-specific mortality of U.S. nurses working rotating night shifts. Am J Prev Med 48(3): 241–252. (Supported by NCI, NIH Heart, Lung and Blood Institute, and the CDC/The National Institute for Occupational Safety and Health. Authors affiliated with NCI, MD; Brigham and Women’s Hospital, MA; Harvard Medical School, MA; University of Massachusetts, MA; Indiana University, IN; National University of Singapore, Singapore; National University Health System, Singapore; Applied Cancer Research–Institution for Translational Research Vienna, Austria.)25576495
8 Hansen J. 2001. Increased breast cancer risk among women who work predominantly at night. Epidemiology 12(1): 74–77. (Support not reported. Author affiliated with Danish Cancer Society, Denmark.)11138824
9 Hansen J, Lassen CF. 2012. Nested case-control study of night shift work and breast cancer risk among women in the Danish military. Occup Environ Med 69(8): 551–556. (Supported by the Danish Ministry of Defence. Authors affiliated with Danish Cancer Society, Denmark.)22645325
10 Hansen J, Stevens RG. 2012. Case-control study of shift-work and breast cancer risk in Danish nurses: impact of shift systems. Eur J Cancer 48(11): 1722–1729. (Supported by the Danish Cancer Society and from the National Programme of Environmental Health Research. Authors affiliated with Danish Cancer Society, Denmark; University of Connecticut Health Center, CT.)21852111
11 Jørgensen JT, Karlsen S, Stayner L, Andersen J, Andersen ZJ. 2017. Shift work and overall and cause-specific mortality in the Danish nurse cohort. Scand J Work Environ Health 43(2): 117–126. (Support not reported. Authors affiliated with University of Copenhagen, Denmark; University of Illinois at Chicago School of Public Health, IL; Danish Cancer Society, Denmark.)28245504
12 Knutsson A, Alfredsson L, Karlsson B, Åkerstedt T, Fransson EI, Westerholm P, Westerlund H. 2013. Breast cancer among shift workers: results of the WOLF longitudinal cohort study. Scand J Work Environ Health 39(2): 170–177. (Support not reported. Authors affiliated with Mid Sweden University, Sweden; Karolinska Institutet, Sweden; Norrlands University Hospital, Sweden; Stockholm University, Sweden; Jönköping University, Sweden; Uppsala University, Sweden.)23007867
13 Koppes LL, Geuskens GA, Pronk A, Vermeulen RC, de Vroome EM. 2014. Night work and breast cancer risk in a general population prospective cohort study in The Netherlands. Eur J Epidemiol 29(8): 577–584. (Supported by the Dutch Ministry of Social Affairs and Employment. Authors affiliated with Netherlands Organization for Applied Scientific Research, Netherlands; Utrecht University, Netherlands.)25012051
14 Li W, Ray RM, Thomas DB, Davis S, Yost M, Breslow N, Gao DL, Fitzgibbons ED, Camp JE, Wong E, Wernli KJ, Checkoway H. 2015. Shift work and breast cancer among women textile workers in Shanghai, China. Cancer Causes Control 26(1): 143–150. (Supported by NIOSH, NCI, and NIH. Authors affiliated with Fred Hutchinson Cancer Research Center, WA; University of Washington, WA; Zhong Shan Hospital Branch, China; Group Health Research Institute, WA; University of California - San Diego, CA.)25421377
15 Lie JA, Kjuus H, Zienolddiny S, Haugen A, Stevens RG, Kjaerheim K. 2011. Night work and breast cancer risk among Norwegian nurses: assessment by different exposure metrics. Am J Epidemiol 173(11): 1272–1279. (Supported by the Research Council of Norway, the South-Eastern Norway Regional Health Authority, and the Norwegian Cancer Society. Authors affiliated with National Institute of Occupational Health, Norway; University of Connecticut Health Center, CT; Cancer Registry of Norway, Norway.)21454824
16 Lie JA, Kjuus H, Zienolddiny S, Haugen A, Kjaerheim K. 2013. Breast cancer among nurses: is the intensity of night work related to hormone receptor status? Am J Epidemiol 178(1): 110–117. (Supported by the Research Council of Norway, the South-Eastern Norway Regional Health Authority, the Norwegian Cancer Society, and the “Raagholtstiftelsen” foundation. Authors affiliated with National Institute of Occupational Health, Norway; Cancer Registry of Norway, Norway.)23788666
17 Menegaux F, Truong T, Anger A, Cordina-Duverger E, Lamkarkach F, Arveux P, Kerbrat P, Fevotte J, Guenel P. 2013. Night work and breast cancer: a population-based case-control study in France (the CECILE study). Int J Cancer 132(4): 924–931. (Supported by the Agence Nationale de securite sanitaire de l’alimentation, de l’environnement et du travail [ANSES], the Agence Nationale de la Recherche [ANR], the Fondation de France, the Institut National du Cancer [INCA]; Ligue contre le Cancer Grand Ouest, and the Association pour le recherche contre le cancer [ARC]. Authors affiliated with INSERM, France; Univ Paris-Sud, France; Center Georges-Francois Leclerc, France; Center Eugene Marquis, France; Institut de Veille Sanitaire [InVS], France.)22689255
18 O’Leary ES, Schoenfeld ER, Stevens RG, Kabat GC, Henderson K, Grimson R, Gammon MD, Leske MC, for the Electromagnetic Fields Breast Cancer on Long Island Study Group. 2006. Shift work, light at night, and breast cancer on Long Island, New York. Am J Epidemiol 164(4): 358–366. (Supported by NCI and NIEHS. Authors affiliated with Stony Brook University, NY; University of Connecticut Health Center, CT; University of North Carolina at Chapel Hill, NC.)16777931
19 Papantoniou K, Castano-Vinyals G, Espinosa A, Aragones N, Perez-Gomez B, Ardanaz E, Altzibar JM, Sanchez VM, Gomez-Acebo I, Llorca J, Munoz D, Tardon A, Peiro R, Marcos-Gragera R, Pollan M, Kogevinas M. 2015. Breast cancer risk and night shift work in a case-control study in a Spanish population. Eur J Epidemiol. (Supported by the ‘‘Accion Transversal del Cancer,’’ approved on the Spanish Ministry Council on the 11th October 2007, by the Instituto de Salud Carlos III-FEDER, the Fundacio´n Marque´s de Valdecilla, the ICGC International Cancer Genome Consortium CLL, the Spanish Ministerio de Economía y Competitividad, the Red Temática de Investigación del Cáncer, the Junta de Castilla y León, the the Consejería de Salud of the Junta de Andalucía, the Conselleria de Sanitat of the Generalitat Valenciana, the Recercaixa, the European Commission, the Spanish Association Against Cancer, the Scientific Foundation, the Catalan Government DURSI Grant and a predoctoral Grant PFIS. Authors affiliated with Centre for Research in Environmental Epidemiology, Spain; IMIM [Hospital del Mar Medical Research Institute], Spain; Universitat Pompeu Fabra, Spain; Carlos III Health Institute, Spain; Cancer Epidemiology Research Group, Spain; Instituto de Salud Publica de Navarra, Spain; Basque Regional Health Department, Spain; Universidad de León, Spain; University of Cantabria, Spain; IDIVAL, Spain; Universidad de Huelva, Spain; Universidad de Oviedo, Spain; Fundación para el Fomento de la Investigación Sanitaria y Biomédica de la Comunidad Valenciana, Spain; Girona Biomedical Research Institute, Spain; CIBER Epidemiologıía y Salud Pública, Spain; National School of Public Health, Greece.)
20 Pesch B, Harth V, Rabstein S, Baisch C, Schiffermann M, Pallapies D, Bonberg N, Heinze E, Spickenheuer A, Justenhoven C, Brauch H, Hamann U, Ko Y, Straif K, Brüning T. 2010. Night work and breast cancer - results from the German GENICA study. Scand J Work Environ Health 36(2): 134–141. (Supported by the German Federal Ministry of Education and Research, the Research Institute of Occupational Medicine of the German Social Accident Insurance, the Robert Bosch Foundation of Medical Research, the Evangelische Kliniken Bonn GmbH, and the Deutsches Krebsforschungszentrum. Authors affiliated with Ruhr University Bochum, Germany; Evangelische Kliniken Bonn gGmbH, Germany; University Tübingen, Germany; Deutsches Krebsforschungszentrum, Germany; IARC, France.)20039012
21 Pronk A, Ji BT, Shu XO, Xue S, Yang G, Li HL, Rothman N, Gao YT, Zheng W, Chow WH. 2010. Night-shift work and breast cancer risk in a cohort of Chinese women. Am J Epidemiol 171(9): 953–959. (Supoprted by NIH. Authors affiliated with NCI. MD; Vanderbilt University School of Medicine, TN; Shanghai Cancer Institute, China.)20375193
22 Rabstein S, Harth V, Pesch B, Pallapies D, Lotz A, Justenhoven C, Baisch C, Schiffermann M, Haas S, Fischer HP, Heinze E, Pierl C, Brauch H, Hamann U, Ko Y, Bruning T, Consortium G. 2013. Night work and breast cancer estrogen receptor status--results from the German GENICA study. Scand J Work Environ Health 39(5): 448–455. (Supported by the German Federal Ministry of Education and Research, the Institute for Prevention and Occupational Medicine of the German Social Accident Insurance, Ruhr-University Bochum, the Robert Bosch Foundation, Stuttgart, EvangelischeKliniken Bonn GmbH, and the Deutsches Krebsforschungszentrum. Authors affiliated with Institute of the Ruhr-Universität Bochum, Germany; University Medical Centre Hamburg-Eppendorf, Germany; Dr Margarete Fischer-Bosch-Institute of Clinical Pharmacology, Germany; University of Tübingen, Germany; Medical Faculty of the University of Bonn, Germany; Deutsches Krebsforschungszentrum, Germany; Evangelische Kliniken Bonn gGmbH, Germany.)23543199
23 Schernhammer ES, Laden F, Speizer FE, Willett WC, Hunter DJ, Kawachi I, Colditz GA. 2001. Rotating night shifts and risk of breast cancer in women participating in the nurses’ health study. J Natl Cancer Inst 93(20): 1563–1568. (Supported by NCI, NIH, and the Austrian Federal Ministry of Education, Science and Culture. Authors affiliated with Harvard Medical School, MA; Brigham and Women’s Hospital, MA; Harvard Center for Cancer Prevention, MA; Dana-Faber/Harvard Cancer Center, MA.)11604480
24 Schernhammer ES, Kroenke CH, Laden F, Hankinson SE. 2006. Night work and risk of breast cancer. Epidemiology 17(1): 108–111. (Support not reported. Authors affiliated with Harvard Medical School, MA; LBI-ACR VIEnna & ACR-ITR VIEnna, Austria.)16357603
25 Schwartzbaum J, Ahlbom A, Feychting M. 2007. Cohort study of cancer risk among male and female shift workers. Scand J Work Environ Health 33(5): 336–343. (Supported by the Swedish Council for Working Life. Authors affiliated with Ohio State University, OH; Karolinska Institutet, Sweden.)17973059
26 Travis RC, Balkwill A, Fensom GK, Appleby PN, Reeves GK, Wang XS, Roddam AW, Gathani T, Peto R, Green J, Key TJ, Beral V. 2016. Night shift work and breast cancer incidence: Three prospective studies and meta-analysis of published studies. J Natl Cancer Inst 108(12): djw169. (Supported by the UK Health and Safety Executive, Cancer Research UK, and the Medical Research Council. Authors affiliated with University of Oxford, UK; GlaxoSmithKline R&D, UK; Oxford University Hospitals NHS Trust, UK.)27758828
27 Tynes T, Hannevik M, Andersen A, Vistnes AI, Haldorsen T. 1996. Incidence of breast cancer in Norwegian female radio and telegraph operators. Cancer Causes Control 7(2): 197–204. (Support not reported. Authors affiliated with Cancer Registry of Norway, Norway; Radiation Protection Authority, Norway; University of Oslo, Norway.)8740732
28 Vistisen HT, Garde AH, Frydenberg M, Christiansen P, Hansen AM, Andersen J, Bonde JP, Kolstad HA. 2017. Short-term effects of night shift work on breast cancer risk: a cohort study of payroll data. Scand J Work Environ Health 43(1): 59–67. (Supported by the Danish Work Environment Research Fund and NordForsk, Nordic Program on Health and Welfare. Authors affiliated with Aarhus University Hospital, Denmark; National Research Centre for the Working Environment, Denmark; Aarhus University, Denmark; Danish Breast Cancer Corporative Group, Denmark; University of Copenhagen, Denmark; Danish Cancer Society Research Center, Denmark; Bispebjerg University Hospital, Denmark.)27841916
29 Wang P, Ren FM, Lin Y, Su FX, Jia WH, Su XF, Tang LY, Ren ZF. 2015. Night-shift work, sleep duration, daytime napping, and breast cancer risk. Sleep Med 16(4): 462–468. (Supported by the National Natural Science Foundation of China and the Guangdong Provincial Natural Science Foundation. Authors affiliated with Sun Yat-sen University, China; Chinese University of Hong Kong, China; CUHK Shenzhen Research Institute, China.)25794454
30 Wegrzyn LR, Tamimi RM, Rosner BA, Brown SB, Stevens RG, Eliassen AH, Laden F, Willett WC, Hankinson SE, Schernhammer ES. 2017. Rotating night shift work and risk of breast cancer in the nurses’ health studies. Am J Epidemiol. (Supported by the CDC, NIOSH, and NIH. Authors affiliated with Brigham and Women’s Hospital, MA; Harvard Medical School, MA; Harvard T.H. Chan School of Public Health, MA; University of Massachusetts, MA; University of Connecticut Health Center, CT; Medical University of Vienna, Austria; Applied Cancer Research-Institution for Translational Research Vienna, Austria.)