# Appendix A Literature Search Strategy

## Introduction

The objective of the literature search is to identify published literature that is relevant for evaluating the potential carcinogenicity of circadian disruption and/or light at night. As discussed in the Concept Document for shift work, light at night, and circadian disruption (NTP 2014), the goal of the literature search strategy is to identify information on environmental exposures associated with circadian disruption and/or light at night for the broad range of subjects covered by a NTP report, as listed below:

- Properties and Human Exposure (focusing on the U.S. population)
- Human Cancer Studies
- Studies of Cancer in Experimental Animals
- Mechanisms and Other Relevant Effects

## A.1 General approach

Database searching encompasses selecting databases and search terms and conducting the searches. Searches of several citation databases are generally conducted using search terms for the individual environmental exposures, combined with search terms for cancer and/or specific topics, including epidemiological and mechanistic studies. A critical step in the process involves consultation with an information specialist to develop relevant search terms. These terms are used to search bibliographic databases.

Citation databases, including PubMed, Scopus, and Web of Science, were searched up until December 2017 for epidemiological studies evaluating cancer and shift work, light at night, or transmeridian travel using the strategy outlined in the table below. In addition, searches were conducted to identify other types of unnatural light exposures (such as the use of consumer electronics or exposure scenarios associated with social jet lag). Because this exposure scenario is less defined than the other exposure scenarios, these search terms were limited (e.g., combined using the word “and”) by terms focused for circadian disruption before being combined with epidemiological and cancer search strings. Cancer studies measuring biomarker-related circadian disruption or among shift workers or people exposed to LAN were retrieved by these searches. Approximately 6,500 citations were identified from these searches and uploaded to web-based systematic review software for separate evaluation by two reviewers applying the inclusion/exclusion criteria. Based on these criteria, 722 references were selected for final inclusion in the cancer hazard assessment. Literature searches were updated on a monthly basis prior to posting the peer-review draft on August 24, 2018. References recommended by the peer reviewers were also considered for the final version. NTP has continued to monitor the literature through August 2019 but has not identified any studies would affect the overall cancer hazard conclusions. No studies from the updated monitoring have been included in this final assessment because these studies would not have been peer reviewed.

The results for the Human Cancer, Animal Cancer, Specific Biomarkers, and Mechanisms searches were then processed in EndNote to remove duplicates before being transferred to Health Assessment Workplace Collaborative (https://hawcproject.org/) (HAWC) for screening. Review at Level 1 identifies studies that should be included in the next level of review for (1) Exposure, (2) Human Cancer/Biomarkers, (3) and (4) Mechanisms (including animal cancer studies). Review at Level 2 includes more detailed tagging for specific topics covered by a particular section of the report The HAWC assessments for Human/Biomarkers (HAWC 2018a) and Mechanisms (HAWC 2018b) are publiclly available.

Figure A-1 illustrates the overall approach to the searches and screening and the numbers of citations identified. Table A-1 highlights the general concepts searched and databases consulted. To review all the terms used, please refer to the full search strings below.

Figure A-1 Literature search strategy and review

This figure depicts the literature search strategy and review. First, topic-specific and general and exposure-related literature searches in the different databases were merged. The first level review had 6520 citations, and 2365 of them were included for the second level of review. Then, papers were assigned to topics for second level review. Note that some references were assigned to more than one topic. The numbers were as follows: Exposure: 326; Human/biomarkers: 1925; Mechanisms: 1471. Next, secondary citations and other sources were added and then the second level review was conducted separately by topic. Excluded citations were removed, and 660 citations remained for all monograph sections. Finally, additional search terms and topics were added along the way, and searches were updated and the resulting citations followed the process just described above.

Table A-1 Major topics searched

Topic | Search Method | Databases searched
Human Cancer Studies | (shift work OR shiftwork OR night work OR “light at night” OR jet lag) AND (cancer OR tumor) | PubMed
Experimental Animal Studies | (Shift Work String OR Light String) AND Experimental Animals Studies Search AND ORoC Cancer Search | PubMed, Scopus, Web of Science
Biomarkers Studies | ORoC Cancer Search AND (Shift Work String OR Light String) AND Specific Biomarkers String AND (Humans & Epidemiology Combined String OR Experimental Animals Studies Search) | PubMed
Mechanism | (Shift Work String OR Light String) AND ORoC Characteristics of Carcinogens Search AND ORoC Cancer Search | PubMed, Scopus, Web of Science

## A.2 Standard Searches

### A.2.1 Shift Work

#### PubMed

(work-schedule*[tiab] OR Alternative-shift*[tiab] OR duty-shift*[tiab] OR Midnight-shift*[tiab] OR night-call[tiab] OR night-shift*[tiab] OR nightshift*[tiab] OR night-work*[tiab] OR nightwork*[tiab] OR rotating-schedule*[tiab] OR rotating-shift*[tiab] OR shift-work*[tiab] OR shiftwork*[tiab] OR split-shift*[tiab] OR swing-shift*[tiab] OR third-shift*[tiab]) OR ((“personnel staffing and scheduling”[mh] OR “work schedule tolerance”[mh]) AND (shift* OR schedul*[tiab] OR hours[tiab] OR night[tiab] OR evening[tiab] OR duty-hour*[tiab] OR duty-period*[tiab] OR night-float*[tiab] OR overtime[tiab] OR on-call[tiab] OR 12-hour[tiab] OR twelve-hour[tiab] OR “long working hours”[tiab] OR “working long hours”[tiab] OR sleep[tiab] OR fatigue[tiab]))

#### Web of Science

(TS=(“work schedule*” OR “Alternative shift*” OR “duty shift*” OR “Midnight shift*” OR “night call” OR “night shift*” OR “nightshift*” OR “night work*” OR “nightwork*” OR “rotating schedule*” OR “rotating shift*” OR “shift work*” OR “shiftwork*” OR “split shift*” OR “swing shift*” OR “third shift*”)) OR ((TS=(“personnel OR “staffing” OR “work schedule tolerance”)) AND (TS=(“shift*” OR “schedul*” OR “hours” OR “night” OR “evening” OR “duty hour*” OR “duty period*” OR “night float*” OR “overtime” OR “on-call” OR “12-hour” OR “twelve-hour” OR “long working hours” OR “working long hours” OR “sleep” OR “fatigue”)))

#### Scopus

( TITLE-ABS-KEY ( “work schedule*” OR “Alternative shift*” OR “duty shift*” OR “Midnight shift*” OR “night call” OR “night shift*” OR “nightshift*” OR “night work*” OR “nightwork*” OR “rotating schedule*” OR “rotating shift*” OR “shift work*” OR “shiftwork*” OR “split shift*” OR “swing shift*” OR “third shift*” ) ) OR ( ( KEY ( “personnel staffing and scheduling” OR “work schedule tolerance” ) ) AND ( TITLE-ABS-KEY ( “shift*” OR “schedul*” OR “hours” OR “night” OR “evening” OR “duty hour*” OR “duty period*” OR “night float*” OR “overtime” OR “on-call” OR “12-hour” OR “twelve-hour” OR “long working hours” OR “working long hours” OR “sleep” OR “fatigue” ) ) )

### A.2.2 Light at Night

#### PubMed

(light-dark-cycle*[tiab] OR light-cycle[tiab] OR light-cycles[tiab] OR dark-light-cycle*[tiab] OR Evening-light* OR Light-at-night OR Light-pollut* OR Night-light* OR Night-time-ligt* OR Nocturnal-light* OR bedroom-light* OR Sleeping-habitat*)

#### Web of Science

TS=(“light-dark cycle*” OR “light cycle” OR “light cycles” OR “dark-light cycle*” OR “Evening light*” OR “Light at night” OR “Light pollut*” OR “Night light*” OR “Night time light*” OR “Nocturnal light*” OR (bedroom NEAR/3 light*) OR “Sleeping habitat*”)

#### Scopus

(TITLE-ABS-KEY(“light-dark cycle*” OR “light cycle” OR “light cycles” OR “dark-light cycle*” OR “Evening light*” OR “Light at night” OR “Light pollut*” OR “Night light*” OR “Night time light*” OR “Nocturnal light*” OR (bedroom w/3 light*) OR “Sleeping habitat*”))

### A.2.3 Animal Studies

The PubMed, Web of Science, and Scopus Strings are the same as described in the Handbook Appendix (NTP 2016).

### A.2.4 Humans & Epidemiology Combined

#### PubMed

((humans[mh] OR human development[mh] OR household*[tiab] OR public[tiab] OR neighborhood*[tiab] OR human*[tiab] OR person*[tiab] OR people[tiab] OR age groups[mh] OR pediatric*[tiab] OR paediatric*[tiab] OR baby[tiab] OR babies[tiab] OR newborn*[tiab] OR infant*[tiab] OR toddler*[tiab] OR child*[tiab] OR youth*[tiab] OR youngster*[tiab] OR tween*[tiab] OR teen[tiab] OR teens[tiab] OR teenager*[tiab] ) OR ((“in utero”[tiab] OR prenat*[tiab] OR perinat*[tiab] OR neonat*[tiab] OR postnat*[tiab] OR adult*[tiab] OR juvenile*[tiab]) NOT (mice[tiab] OR mouse[tiab] OR rat[tiab] OR rats[tiab])) OR preschool*[tiab] OR pre-school*[tiab] OR kindergarten*[tiab] OR schoolchild*[tiab] OR student*[tiab] OR middle-age*[tiab] OR aged[tiab] OR elder*[tiab] OR senior-citizen*[tiab] OR seniors[tiab] OR retiree*[tiab] OR septuagenarian*[tiab] OR octagenarian*[tiab] OR sexagenarian*[tiab] OR nonagenarian*[tiab] OR centenarian*[tiab] OR nuclear family[mh] OR parent[tiab] OR parents[tiab] OR father*[tiab] OR mother*[tiab] OR sibling*[tiab] OR brother*[tiab] OR sister*[tiab] OR twin[tiab] OR twins[tiab] OR step-father*[tiab] OR step-mother*[tiab] OR step-daughter*[tiab] OR step-son*[tiab] OR aunt*[tiab] OR uncle*[tiab] OR niece*[tiab] OR nephew*[tiab] OR grandparent*[tiab] OR grandfather*[tiab] OR grand-father*[tiab] OR grandmother*[tiab] OR grand-mother*[tiab] OR grandchild*[tiab] OR granddaughter*[tiab] OR grandson*[tiab] OR spouse*[tiab] OR partner*[tiab] OR husband*[tiab] OR wife[tiab] OR wives[tiab] OR guardian*[tiab] OR caregiver*[tiab] OR care-giver*[tiab] OR men[mh] OR women[mh] OR men[tiab] OR man[tiab] OR boy[tiab] OR boys[tiab] OR boyhood[tiab] OR women[tiab] OR woman[tiab] OR girl[tiab] OR girls[tiab] OR girlhood[tiab] OR population groups[mh] OR vulnerable populations[mh] OR African-American*[tiab] OR Asian-American*[tiab] OR hispanic*[tiab] OR latina*[tiab] OR latino*[tiab] OR Mexican-American*[tiab] OR underserved[tiab] OR disadvantaged[tiab] OR underprivileged[tiab]) OR (epidemiolog*[tiab] OR epidemiology[sh] OR “epidemiologic studies”[mh] OR “double-blind method”[mh] OR “single-blind method”[mh] OR epidemiology[sh] OR case-control*[tiab] OR cohort[tiab] OR “cross sectional”[tiab] OR “follow-up study”[tiab] OR longitudinal[tiab] OR prospective[tiab] OR retrospective[tiab] OR case-reports[pt] OR “clinical trial”[pt] OR “observational study”[pt] OR “randomized controlled trial”[pt] OR “twin study”[pt] OR case-report*[tiab] OR clinical-trial*[tiab] OR observational[tiab] OR randomized-control-trial*[tiab]) OR (“research subjects”[mh] OR “human experimentation”[mh] OR patients[mh] OR “patient participation”[mh] OR human-subject*[tiab] OR research-subject*[tiab] OR client*[tiab] OR patient*[tiab] OR inpatient*[tiab] OR outpatient*[tiab] OR participant*[tiab] OR volunteer*[tiab] OR “occupational groups”[mh] OR “occupational exposure”[mh] OR occupation*[tiab] OR workplace[tiab] OR “work place”[tiab] OR work-related[tiab] OR administrator*[tiab] OR aides[tiab] OR assistant*[tiab] OR crew[tiab] OR crews[tiab] OR employee*[tiab] OR personnel[tiab] OR professional*[tiab] OR staff[tiab] OR technician*[tiab] OR worker*[tiab] OR educator*[tiab] OR instructor*[tiab] OR teacher*[tiab] OR clinician*[tiab] OR doctor*[tiab] OR physician*[tiab] OR pharmacist*[tiab] OR nurse*[tiab] OR residents[tiab] OR veterinarian*[tiab] OR adolescent[tiab]) OR “meta-analysis”[pt] OR workmen*[tiab] OR seroepidemiologic-stud*[tiab] OR ecological-study[tiab] OR ecological-studies[tiab] OR correlation-stud*[tiab] OR case-series[tiab] OR case-referent[tiab] OR record-link*[tiab])

### A.2.5 Specific Biomarkers

#### PubMed

(corticosterone[tiab] OR cortisol[mh] OR cortisol[tiab] OR melatonin[mh] OR melatonin[tiab] OR “body temperature”[mh] OR body-temperature*[tiab])

### A.2.6 Characteristics of Carcinogens

The PubMed, Web of Science, and Scopus Strings are the same as described in the Appendix to the RoC Handbook (NTP 2016).

### A.2.7 RoC Cancer String

The PubMed, Web of Science, and Scopus Strings are the same as described in the Appendix to the RoC Handbook (NTP 2016).

## References

1 HAWC. 2018a. HAWC: Health Assessment Workspace Collaborative. Public Assessment of LAN Level 2 Human/Biomarkers. https://hawcproject.org/assessment/390/.
2 HAWC. 2018b. HAWC: Health Assessment Workspace Collaborative. Public Assessment of LAN Level 2 Mechanistic. https://hawcproject.org/assessment/393/.
3 NTP. 2014. Report on Carcinogens (RoC) Concept: Shiftwork at Night, Light at Night, and Circadian Disruption. National Toxicology Program. 12 pp. https://ntp.niehs.nih.gov/ntp/roc/concept_docs/2014/shiftworkconcept_508.pdf.
4 NTP. 2016. Standard Search Strings for Literature Database Searches: Appendix to the Draft Handbook for Preparing Report on Carcinogens Monographs. National Toxicology Program. 32 pp. https://ntp.niehs.nih.gov/ntp/roc/handbook/rochandbookappendix_508.pdf.