# Publication Details

Publisher: National Institute of Environmental Health Sciences

Publishing Location: Research Triangle Park, NC

ISSN: 2768-5632

DOI: https://doi.org/10.22427/NIEHS-09

Report Series: NIEHS Report Series

Report Series Number: 09

Official citation: Auerbach SS, Aillon KL, Ballin JD, Collins BJ, Cora MC, Duncan NS, Fostel JM, Kerns SP, Liu YF, Luh J, Machesky NJ, Pickett SJ, Prince LM, Roberts GK, Shipkowski KA, Skowronek AJ, Sparrow BR, Toy H, Waidyanatha S, Watson ATD. 2023. NIEHS report on the in vivo repeat dose biological potency study of 2,3-benzofluorene (CASRN 243-17-4) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (gavage studies). Research Triangle Park, NC: National Institute of Environmental Health Sciences. NIEHS Report 09.