# Summary

2,3-Benzofluorene (2,3-BF) is a member of the polycyclic aromatic hydrocarbon class of compounds to which humans are widely exposed. A review of the literature did not identify toxicological data for estimating the potential adverse health effects of 2,3-BF. This study used a transcriptomic approach and standard toxicological endpoints to estimate the in vivo biological potency of 2,3-BF.

A subset of standard toxicological endpoints (absolute liver weight, relative liver weight, and eosinophil count in male rats; eosinophil count in female rats) exhibited benchmark dose (BMD) values much lower than would be expected given the endpoint-specific no-observed-effect level and lowest-observed-effect level values. Expert review of the data suggests that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and were likely an anomalous product of the BMD modeling approach.

Taking this into account, the most sensitive apical endpoint in male rats was a decrease in reticulocyte count with an estimated BMD and benchmark dose lower confidence limit (BMD_L_) of 11.837 (6.978) mg/kg. An increase in thyroid stimulating hormone concentration and a decrease in total thyroxine concentration were the next most sensitive apical endpoint changes observed in male rats with BMDs (BMD_L_s) of 44.526 (19.298) and 61.426 (24.276) mg/kg, respectively. In female rats, the most sensitive apical endpoint was an increase in thyroid stimulating hormone concentration with a BMD (BMD_L_) of 1.078 (0.267) mg/kg. The next most sensitive apical endpoints observed were an increase in absolute liver weight and an increase in cholesterol concentration with BMDs (BMD_L_s) of 24.928 (7.768) and 288.242 (226.543) mg/kg, respectively.

Gene set-level transcriptional changes in the liver following 2,3-BF exposure were estimated to occur at a BMD (BMD_L_) as low as 5.660 (2.158) mg/kg in male rats, corresponding to regulation of ossification (GO:0030278), and as low as 1.874 (0.497) mg/kg in female rats, corresponding to DNA conformation change (GO:0071103) and chromosome organization (GO:0051276). The most sensitive liver gene for which a reliable BMD could be determined was Zfp354a, with a BMD (BMD_L_) of 3.267 (1.720) mg/kg in male rats, and Kif22, with a BMD (BMD_L_) of 0.962 (0.282) mg/kg, in female rats.

Gene set-level transcriptional changes in the kidney were estimated to occur at a BMD (BMD_L_) as low as 6.167 (1.732) mg/kg in male rats, corresponding to brain development (GO:0007420), and as low as 14.574 (7.161) mg/kg in female rats, corresponding to regulation of fibroblast proliferation (GO:0048145). One kidney gene in male rats had a BMD estimate below the lower limit of extrapolation (<0.050 mg/kg). The most sensitive kidney gene for which a reliable BMD could be determined was Top2a, with a BMD (BMD_L_) of 12.334 (3.464) mg/kg, in male rats and Cyp1a1, with a BMD (BMD_L_) of 12.886 (9.131) mg/kg, in female rats.

Under the conditions of this short-duration transcriptomic study in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats, the most sensitive point of departure with a reliable estimate in male rats was a transcriptional change in a gene, Zfp354a, with a BMD (BMD_L_) of 3.267 (1.720) mg/kg. Gene set transcriptional changes and apical endpoints provided potency estimates slightly higher than Zfp354a. In female rats, the most sensitive point of departure with a reliable estimate was a transcriptional change in a gene, Kif22, with a BMD (BMD_L_) of 0.962 (0.282) mg/kg. Gene set transcriptional changes provided potency estimates that were slightly higher, whereas apical endpoints provided potency estimates in the same range as Kif22.