# Results

## Animal Condition, Body Weights, and Organ Weights

All male and female rats administered 2,3-benzofluorene (2,3-BF) survived to the end of the study. One male rat in the 12 mg/kg body weight (mg/kg) group and one male rat in the 333 mg/kg group were noted to have soft feces on study day 0; no other clinical observations were noted (Appendix F). There were no significant changes in terminal body weight for male or female rats administered 2,3-BF (Table 2).

Table 2 Summary of Body Weights of Male and Female Rats Administered 2,3-Benzofluorene for Five Days

Study Day^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
0 | 307.8 ± 5.7 | 306.6 ± 3.9 | 313.6 ± 4.8 | 311.9 ± 3.0 | 305.7 ± 7.4 | 307.4 ± 6.7 | 302.4 ± 9.4 | 302.0 ± 5.4 | 305.6 ± 5.7 | 305.4 ± 5.6 | ND | ND
5 | 324.0 ± 6.3 | 320.2 ± 3.9 | 325.9 ± 3.2 | 328.0 ± 3.4 | 326.4 ± 8.4 | 319.0 ± 7.6 | 315.9 ± 9.2 | 310.8 ± 6.0 | 318.8 ± 6.7 | 316.2 ± 6.6 | ND | ND
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
0 | 210.5 ± 5.9 | 210.1 ± 7.4 | 211.2 ± 4.4 | 220.8 ± 5.4 | 211.6 ± 7.7 | 214.8 ± 6.4 | 211.4 ± 6.1 | 214.0 ± 0.9 | 206.5 ± 4.2 | 209.6 ± 3.0 | ND | ND
5 | 215.4 ± 5.7 | 213.2 ± 8.4 | 216.0 ± 6.7 | 228.2 ± 4.9 | 216.3 ± 9.2 | 218.6 ± 5.9 | 215.5 ± 5.6 | 220.7 ± 3.3 | 210.1 ± 5.8 | 211.2 ± 2.1 | ND | ND

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; ND = not determined.

^a^ Data are displayed as mean ± standard error of the mean; body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

In male rats at study termination, absolute and relative liver weights had significant trend and pairwise comparisons. Although a benchmark dose (BMD) was estimated for each of these endpoints, its value was much lower (approximately 85- to 260-fold and 30- to 90-fold for absolute and relative liver weights, respectively) than would be expected given the endpoint-specific no-observed-effect level (NOEL) and lowest-observed-effect level (LOEL) values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach (Table 3). The BMDs for all organ weights were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the estimated BMD values). Significant trend and pairwise comparisons were not observed in absolute or relative heart, right kidney, or left kidney weights (Appendix F).

Table 3 Summary of Liver Weights of Male and Female Rats Administered 2,3-Benzofluorene for Five Days

Endpoint^a,b,c^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Terminal Body Wt. (g) | 324.0 ± 6.3 | 320.2 ± 3.9 | 325.9 ± 3.2 | 328.0 ± 3.4 | 326.4 ± 8.4 | 319.0 ± 7.6 | 315.9 ± 9.2 | 310.8 ± 6.0 | 318.8 ± 6.7 | 316.2 ± 6.6 | ND | ND
Liver
Absolute (g) | 12.68 ± 0.38** | 12.46 ± 0.43 | 12.14 ± 0.33 | 14.42 ± 0.39 | 13.16 ± 0.46 | 12.84 ± 0.73 | 12.82 ± 0.58 | 13.19 ± 0.23 | 15.48 ± 0.51** | 14.89 ± 0.66** | 1.283^d^ | 0.821^d^
Relative (mg/g)^e^ | 39.11 ± 0.75** | 38.88 ± 0.98 | 37.25 ± 0.87 | 43.96 ± 1.16 | 40.33 ± 0.86 | 40.14 ± 1.40 | 40.51 ± 0.84 | 42.47 ± 0.45* | 48.53 ± 0.78** | 47.02 ± 1.31** | 1.254^d^ | 0.844^d^
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Terminal Body Wt. (g) | 215.4 ± 5.7 | 213.2 ± 8.4 | 216.0 ± 6.7 | 228.2 ± 4.9 | 216.3 ± 9.2 | 218.6 ± 5.9 | 215.5 ± 5.6 | 220.7 ± 3.3 | 210.1 ± 5.8 | 211.2 ± 2.1 | ND | ND
Liver
Absolute (g) | 7.66 ± 0.25** | 7.63 ± 0.63 | 7.90 ± 0.36 | 8.44 ± 0.38 | 7.99 ± 0.44 | 8.05 ± 0.31 | 8.92 ± 0.48* | 9.28 ± 0.28** | 8.73 ± 0.37** | 9.38 ± 0.12** | 24.928 | 7.768
Relative (mg/g) | 35.55 ± 0.51** | 35.56 ± 1.72 | 36.53 ± 0.64 | 36.91 ± 1.13 | 36.88 ± 0.69 | 36.80 ± 0.50 | 41.39 ± 1.99** | 42.01 ± 0.68** | 41.53 ± 1.17** | 44.40 ± 0.36** | NVM | NVM

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; ND = not determined; NVM = nonviable model.

^a^ Descriptions of organ weight endpoints and changes are provided in Appendix E.

^b^ Data are displayed as mean ± standard error of the mean.

^c^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

^e^ Relative organ weights (organ weight-to-body weight ratios) are given as mg organ weight/g body weight.

In female rats at study termination, a significant increase in absolute and relative liver weights occurred in dose groups ≥37 mg/kg; both endpoints had positive trends (Table 3). The BMD and benchmark dose lower confidence limit (BMD_L_) for increased absolute liver weight was 24.928 (7.768) mg/kg. A BMD (BMD_L_) for increased relative liver weights was not determined because no viable model was available. Significant trend and pairwise comparisons were not observed in absolute or relative heart, right kidney, or left kidney weights (Appendix F).

## Clinical Pathology

Cholesterol concentration in male and female rats had a positive trend with significant pairwise comparisons in the ≥333 mg/kg and the 1,000 mg/kg groups, respectively, with a BMD (BMD_L_) of 288.242 (226.534) mg/kg in female rats (Table 4). In male rats, a BMD (BMD_L_) was not determined because no viable model was available. Globulin concentration had a positive trend with significant pairwise comparisons in the ≥333 mg/kg male rats; a BMD (BMD_L_) was not determined because no viable model was available. In female rats, alkaline phosphatase activity had a positive trend with significant pairwise comparisons in dose groups ≥111 mg/kg; a BMD (BMD_L_) was not determined because no viable model was available. In female rats, globulin concentration had a positive trend with a significant decrease in the lowest dose group; these changes were minimal and considered to be due to biological variability. The BMDs for all clinical pathology endpoints were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the estimated BMD values).

Table 4 Summary of Select Clinical Chemistry Data for Male and Female Rats Administered 2,3-Benzofluorene for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Globulin (g/dL) | 2.15 ± 0.07** | 2.16 ± 0.05 | 2.24 ± 0.15 | 2.12 ± 0.10 | 2.18 ± 0.02 | 2.20 ± 0.04 | 2.26 ± 0.04 | 2.26 ± 0.07 | 2.30 ± 0.06* | 2.30 ± 0.04* | NVM | NVM
Cholesterol (mg/dL) | 114.9 ± 5.9** | 115.2 ± 2.2 | 119.6 ± 13.6 | 112.2 ± 8.0 | 123.0 ± 4.8 | 114.2 ± 3.4 | 117.8 ± 9.3 | 123.4 ± 5.9 | 131.0 ± 3.4* | 163.6 ± 7.1** | NVM | NVM
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Globulin (g/dL) | 1.93 ± 0.07* | 1.66 ± 0.02* | 1.88 ± 0.05 | 1.88 ± 0.04 | 1.86 ± 0.08 | 1.84 ± 0.05 | 2.04 ± 0.09 | 1.94 ± 0.05 | 1.90 ± 0.09 | 1.98 ± 0.05 | 36.678 | 13.695
Cholesterol (mg/dL) | 105.0 ± 5.3** | 97.8 ± 5.8 | 100.8 ± 7.1 | 88.6 ± 4.7 | 101.0 ± 3.8 | 109.0 ± 12.2 | 123.8 ± 10.4 | 105.6 ± 5.5 | 120.8 ± 6.0 | 162.4 ± 8.5** | 288.242 | 226.543
Alkaline Phosphatase (IU/L) | 201.3 ± 13.1** | 198.8 ± 11.9 | 216.2 ± 38.8 | 210.0 ± 19.9 | 218.4 ± 10.1 | 208.4 ± 7.4 | 222.8 ± 25.0 | 240.0 ± 9.3* | 241.4 ± 5.7* | 272.2 ± 18.2** | NVM | NVM

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; NVM = nonviable model.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

In both male and female rats, the reticulocyte count had a negative trend and significant pairwise comparisons in dose groups ≥37 mg/kg and ≥111 mg/kg, respectively, with a BMD (BMD_L_) of 11.837 (6.978) mg/kg in male rats (Table 5). In female rats, a BMD (BMD_L_) was not determined because no viable model was available. In addition, platelet count had a positive trend with a significant pairwise comparison in the 1,000 mg/kg male rats; a BMD (BMD_L_) was not determined because no viable model was available. Eosinophil counts in both male and female rats had significant trend and pairwise comparisons. Although a BMD was estimated for each of these endpoints, these values were much lower (approximately 90- to 280-fold and 25- to 75-fold in male and female rats, respectively) than would be expected given the endpoint-specific NOEL and LOEL values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach.

Table 5 Summary of Select Hematology Data for Male and Female Rats Administered 2,3-Benzofluorene for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 9^c^ | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 4^d^ | NA | NA
Reticulocytes (10^3^/μL) | 244.7 ± 7.2** | 247.2 ± 21.3 | 232.6 ± 12.8 | 212.3 ± 12.5 | 258.3 ± 14.2 | 210.8 ± 14.1 | 168.7 ± 8.8** | 147.0 ± 11.0** | 138.5 ± 6.7** | 122.4 ± 14.9** | 11.837 | 6.978
Platelets (10^3^/μL) | 869 ± 50* | 1,029 ± 59 | 926 ± 24 | 954 ± 80 | 904 ± 159 | 975 ± 27 | 877 ± 85 | 883 ± 65 | 1,061 ± 42^e^ | 1,178 ± 30** | NVM | NVM
Eosinophils (10^3^/μL) | 0.10 ± 0.02** | 0.07 ± 0.01 | 0.09 ± 0.02 | 0.22 ± 0.14^f^ | 0.10 ± 0.01 | 0.06 ± 0.01 | 0.08 ± 0.03 | 0.06 ± 0.02 | 0.05 ± 0.01* | 0.04 ± 0.00** | 1.194^g^ | 0.522^g^
Female
n | 8^h^ | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 4^c^ | 5 | NA | NA
Reticulocytes (10^3^/μL) | 227.2 ± 15.8** | 254.5 ± 12.1 | 210.6 ± 15.5 | 210.8 ± 25.0 | 225.4 ± 17.0 | 209.2 ± 3.8 | 188.0 ± 11.4 | 177.3 ± 10.9* | 134.5 ± 16.0** | 138.8 ± 15.9** | NVM | NVM
Eosinophils (10^3^/μL) | 0.08 ± 0.01** | 0.08 ± 0.02 | 0.08 ± 0.01 | 0.09 ± 0.02 | 0.07 ± 0.02 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.08 ± 0.02 | 0.03 ± 0.01** | 0.04 ± 0.01* | 4.428^g^ | 1.564^g^

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; NVM = nonviable model.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample from the indicated dose groups had a clot present and was not analyzed.

^d^ One sample in the indicated dose group was empty.

^e^ One value for platelets in the 333 mg/kg group was excluded; it was an outlier.

^f^ One value for eosinophils in the 1.4 mg/kg group was excluded due to analysis concerns.

^g^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

^h^ Two samples in the indicated dose group had a clot present and were not analyzed.

In male rats, total thyroxine concentration had a negative trend and significant pairwise comparisons in the ≥333 mg/kg groups with a BMD (BMD_L_) of 61.426 (24.276) mg/kg (Table 6). Thyroid stimulating hormone concentration (TSH) had a positive trend and significant pairwise comparisons in dose groups ≥111 mg/kg with a BMD (BMD_L_) of 44.526 (19.298) mg/kg. In female rats, TSH had a positive trend and significant pairwise comparisons in the ≥37 mg/kg groups with a BMD (BMD_L_) of 1.078 (0.267) mg/kg.

Table 6 Summary of Select Hormone Data for Male and Female Rats Administered 2,3-Benzofluorene for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 8^c^ | 5 | 5 | 4^d^ | 5 | 5 | 4^d^ | 3^c^ | 4^d^ | 3^c^ | NA | NA
TSH (ng/mL) | 2.950 ± 0.617** | 3.760 ± 1.448 | 4.260 ± 0.701 | 3.275 ± 1.121 | 2.760 ± 0.354 | 3.900 ± 1.020 | 4.525 ± 0.945 | 7.033 ± 0.639** | 7.500 ± 1.073** | 7.233 ± 1.011* | 44.526 | 19.298
Total T4 (μg/dL) | 2.80 ± 0.20** | 2.59 ± 0.24 | 2.71 ± 0.22 | 3.16 ± 0.25 | 2.82 ± 0.39 | 2.72 ± 0.28 | 2.53 ± 0.35 | 1.97 ± 0.23 | 1.65 ± 0.12** | 1.72 ± 0.16* | 61.426 | 24.276
Female
n | 6^e^ | 5 | 5 | 5 | 4^d^ | 5 | 4^d^ | 5 | 4^d^ | 5 | NA | NA
TSH (ng/mL) | 2.783 ± 0.326** | 3.360 ± 0.853 | 2.940 ± 0.687 | 4.200 ± 0.476 | 4.025 ± 0.333 | 4.260 ± 0.493 | 4.475 ± 0.239* | 5.480 ± 1.102* | 4.900 ± 1.360* | 8.600 ± 1.762** | 1.078 | 0.267

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; TSH = thyroid stimulating hormone; total T4 = total thyroxine.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Two samples in the indicated dose groups did not have sufficient specimen volume available for analysis.

^d^ One sample in the indicated dose groups did not have sufficient specimen volume available for analysis.

^e^ Four samples in the indicated dose group did not have sufficient specimen volume available for analysis.

## Internal Dose Assessment

For the 4 and 37 mg/kg groups, 2,3-BF plasma concentrations were determined at 2 and 24 hours following the last dose administered on study day 4 to male and female rats. Average 2,3-BF concentrations are given in Table 7. In general, average plasma concentrations in male rats were higher than those in female rats, demonstrating some sex differences. At 2 hours following administration to male and female rats—as the administered dose increased from 4 to 37 mg/kg (a ninefold increase)—there was a less-than-proportional increase (approximately four- to sixfold) in the average 2,3-BF plasma concentration, suggesting changes in the absorption, distribution, metabolism, and excretion processes (e.g., lower absorption and/or induction of metabolism and clearance pathways) as the dose increased. At 24 hours postdose, the concentration decreased across each dosed group, with values falling below or close to the limit of detection (LOD = 1.8 ng/mL) of the analytical method in female and male rats, respectively. Half-lives estimated using the data from these two time points for male rats were 25.3 and 4.4 hours, respectively, for the 4 and 37 mg/kg groups. Half-lives could not be estimated for female rats because the concentration at 24 hours in both dosed groups was below LOD.

Table 7 Summary of Plasma Concentration Data for Male and Female Rats Administered 2,3-Benzofluorene for Five Days^a^

| 4 mg/kg | 37 mg/kg
n | 3 | 3
Male
2 Hours Postdose (ng/mL) | 8.52 ± 1.64 | 49.3 ± 17.5
24 Hours Postdose (ng/mL) | 4.67 ± 3.77 | 1.53 ± 0.630
Female
2 Hours Postdose (ng/mL) | 3.62 ± 1.27 | 15.5 ± 3.20
24 Hours Postdose (ng/mL) | BD | BD

If over 20% of the animals in a group are above the limit of detection, then half the limit of detection value is substituted for values that are below it.

BD = below detection; group did not have over 20% of its values above the limit of detection so mean and standard error were not calculated.

^a^ Data are displayed as mean ± standard error of the mean.

## Apical Endpoint Benchmark Dose Summary

A summary of the calculated BMDs for each toxicological endpoint is provided in Table 8. The endpoint-specific LOEL and NOEL are included and could be informative for endpoints that lack a calculated BMD either because no viable model was available or because the estimated BMD was below the lower limit of extrapolation (<0.050 mg/kg).

Table 8 BMD, BMD_L_, LOEL, and NOEL Summary for Apical Endpoints, Sorted by BMD or LOEL from Low to High

Endpoint | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg) | LOEL (mg/kg)^a^ | NOEL (mg/kg) | Direction of Change
Male
Reticulocytes | 11.837 | 6.978 | 37 | 12 | DOWN
Thyroid Stimulating Hormone | 44.526 | 19.298 | 111 | 37 | UP
Total Thyroxine | 61.426 | 24.276 | 333 | 111 | DOWN
Relative Liver Weight | UREP^b^ | UREP^b^ | 111 | 37 | –^b^
Absolute Liver Weight | UREP | UREP | 333 | 111 | –
Cholesterol | NVM | NVM | 333 | 111 | UP
Eosinophils | UREP | UREP | 333 | 111 | –
Globulin | NVM | NVM | 333 | 111 | UP
Platelets | NVM | NVM | 1,000 | 333 | UP
Female
Thyroid Stimulating Hormone | 1.078 | 0.267 | 37 | 12 | UP
Absolute Liver Weight | 24.928 | 7.768 | 37 | 12 | UP
Globulin | 36.678 | 13.695 | 0.15 | ND | –^c^
Cholesterol | 288.242 | 226.543 | 1,000 | 333 | UP
Relative Liver Weight | NVM | NVM | 37 | 12 | UP
Alkaline Phosphatase | NVM | NVM | 111 | 37 | UP
Reticulocytes | NVM | NVM | 111 | 37 | DOWN
Eosinophils | UREP | UREP | 333 | 111 | –

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; LOEL = lowest-observed-effect level; NOEL = no-observed-effect level; UREP = unreliable estimate of potency is a label based on review by a subject matter expert and rejection of BMD modeling results; NVM = nonviable model, defined as a modeling result that does not meet prespecified fit criteria and hence is deemed unreliable; ND = not determined.

^a^ Values in bold text indicate the LOEL of endpoints for which a BMD could not be calculated.

^b^ BMD values are much lower than would be expected given the endpoint-specific LOEL and NOEL values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

^c^ Statistically significant finding was not attributed to chemical exposure.

## Gene Set Benchmark Dose Analysis

Chemical-induced alterations in liver and kidney gene transcript expression were examined to determine those gene sets most sensitive to 2,3-BF exposure. To that end, BMD analysis of transcripts and gene sets (Gene Ontology [GO] biological process) was conducted to determine the potency of the chemical to elicit gene expression changes in the liver and kidney. This analysis used transcript-level BMD data to assess an aggregate score of gene set potency (median transcript BMD) and enrichment.

The “active” gene sets in the liver and kidney with the lowest BMD median values are shown in Table 9 and Table 10, respectively. The gene sets in Table 9 and Table 10 should be interpreted with caution from the standpoint of the underlying biological mechanism and any relationship to toxicity or toxic agents referenced in the GO term definitions. The data primarily should be considered a metric of potency for chemical-induced transcriptional changes (i.e., a concerted biological change) that could serve as a surrogate of estimated biological potency and, by extension, toxicological potency when more definitive toxicological data are unavailable.

Table 9 Top 10 Liver Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Category Name | No. of Active Genes/ Platform Genes in Gene Set | % Gene Set Coverage | Active Genes | BMD_1std_ Median of Gene Set Transcripts (mg/kg) | Median BMD_L1Std_–BMD_U1Std_ (mg/kg) | Genes with Changed Direction Up | Genes with Changed Direction Down
Male
GO:0030278 regulation of ossification | 3/58 | 5% | Mgp; Id2; Cebpd | 5.660 | 2.158–16.350 | 1 | 2
GO:0001822 kidney development | 4/53 | 8% | Zfp354a; Id2; Egr1; Aldh1a1 | 5.765 | 1.618–28.410 | 2 | 2
GO:1903707 negative regulation of hemopoiesis | 3/48 | 6% | Pf4; Nfe2l2; Id2 | 6.642 | 3.406–13.468 | 3 | 0
GO:0071372 cellular response to follicle-stimulating hormone stimulus | 3/19 | 16% | Inhba; Id2; Egr1 | 8.263 | 1.517–45.905 | 1 | 2
GO:0014910 regulation of smooth muscle cell migration | 3/50 | 6% | Nfe2l2; Igfbp3; Egr1 | 8.263 | 3.406–45.905 | 1 | 2
GO:0097237 cellular response to toxic substance | 4/80 | 5% | Ugt2b1; Nqo1; Nfe2l2; Egr1 | 16.188 | 7.373–41.474 | 3 | 1
GO:0045598 regulation of fat cell differentiation | 3/42 | 7% | Trib3; Lpl; Id2 | 16.895 | 6.465–58.991 | 2 | 1
GO:0034976 response to endoplasmic reticulum stress | 3/58 | 5% | Trib3; Nfe2l2; Ccnd1 | 16.895 | 6.465–58.991 | 2 | 1
GO:0009404 toxin metabolic process | 3/17 | 18% | Nfe2l2; Cyp1a1; Akr7a3 | 19.850 | 12.797–32.354 | 3 | 0
GO:0098754 detoxification | 5/58 | 9% | Nqo1; Nfe2l2; Gstm2; Gsr; Akr7a3 | 19.850 | 12.797–32.354 | 5 | 0
Female
GO:0071103 DNA conformation change | 3/32 | 9% | Top2a; Mcm6; Mcm2 | 1.874 | 0.497–9.530 | 3 | 0
GO:0051276 chromosome organization | 5/90 | 6% | Top2a; Mcm6; Mcm2; Kif22; Gar1 | 1.874 | 0.497–9.530 | 5 | 0
GO:0006281 DNA repair | 4/74 | 5% | Mms22l; Mcm6; Mcm2; Kif22 | 2.822 | 0.727–15.213 | 4 | 0
GO:0000724 double-strand break repair via homologous recombination | 3/15 | 20% | Mms22l; Mcm6; Mcm2 | 3.769 | 0.956–20.896 | 3 | 0
GO:0006259 DNA metabolic process | 7/119 | 6% | Top2a; Mms22l; Mcm6; Mcm2; Kif22; Gar1; Cyp1b1 | 3.769 | 0.956–20.896 | 7 | 0
GO:0009066 aspartate family amino acid metabolic process | 4/14 | 29% | Phgdh; Bhmt; Asns; Aass | 5.933 | 2.674–26.084 | 2 | 2
GO: 0042178 xenobiotic catabolic process | 5/60 | 8% | Pck2; Hba-A1; Hba-A2; Gpx1; Aass | 8.004 | 2.700–37.943 | 1 | 4
GO:0010639 negative regulation of organelle organization | 5/89 | 6% | Top2a; Mcm2; Insig1; Gpx1; Gclc | 8.004 | 2.700–25.225 | 4 | 1
GO:0045833 negative regulation of lipid metabolic process | 3/34 | 9% | Insig1; Esr1; Apoc3 | 12.540 | 3.750–51.297 | 1 | 2
GO:1901607 alpha-amino acid biosynthetic process | 6/19 | 32% | Pycr1; Psat1; Phgdh; Bhmt; Asns; Aass | 16.607 | 6.379–70.854 | 4 | 2

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^27^ Official gene symbols from the Rat Genome Database^28^ are shown in the “Active Genes” column.

GO process description version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

GO:0030278 regulation of ossification: Any process that modulates the frequency, rate, or extent of ossification, the formation of bone or of a bony substance or the conversion of fibrous tissue or of cartilage into bone or a bony substance.

GO:0001822 kidney development: The process whose specific outcome is the progression of the kidney over time, from its formation to the mature structure. The kidney is an organ that filters the blood and/or excretes the end products of body metabolism in the form of urine.

GO:1903707 negative regulation of hemopoiesis: Any process that stops, prevents, or reduces the frequency, rate, or extent of hemopoiesis.

GO:0071372 cellular response to follicle-stimulating hormone stimulus: Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a follicle-stimulating hormone stimulus.

GO:0014910 regulation of smooth muscle cell migration: Any process that modulates the frequency, rate, or extent of smooth muscle cell migration.

GO:0097237 cellular response to toxic substance: Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a toxic stimulus.

GO:0045598 regulation of fat cell differentiation: Any process that modulates the frequency, rate, or extent of adipocyte differentiation.

GO:0034976 response to endoplasmic reticulum stress: Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a stress acting at the endoplasmic reticulum. ER stress usually results from the accumulation of unfolded or misfolded proteins in the ER lumen.

GO:0009404 toxin metabolic process: The chemical reactions and pathways involving a toxin, a poisonous compound (typically a protein) that is produced by cells or organisms and that can cause disease when introduced into the body or tissues of an organism.

GO:0098754 detoxification: Any process that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.

GO:0071103 DNA conformation change: A cellular process that results in a change in the spatial configuration of a DNA molecule. A conformation change can bend DNA, or alter the twist, writhe, or linking number of a DNA molecule.

GO:0051276 chromosome organization: A process that is carried out at the cellular level that results in the assembly, arrangement of constituent parts, or disassembly of chromosomes, structures composed of a very long molecule of DNA and associated proteins that carries hereditary information. This term covers covalent modifications at the molecular level as well as spatial relationships among the major components of a chromosome.

GO:0006281 DNA repair: The process of restoring DNA after damage. Genomes are subject to damage by chemical and physical agents in the environment (e.g., UV and ionizing radiations, chemical mutagens, fungal and bacterial toxins) and by free radicals or alkylating agents endogenously generated in metabolism. DNA is also damaged because of errors during its replication. A variety of different DNA repair pathways have been reported that include direct reversal, base excision repair, nucleotide excision repair, photoreactivation, bypass, double-strand break repair pathway, and mismatch repair pathway.

GO:0000724 double-strand break repair via homologous recombination: The error-free repair of a double-strand break in DNA in which the broken DNA molecule is repaired using homologous sequences. A strand in the broken DNA searches for a homologous region in an intact chromosome to serve as the template for DNA synthesis. The restoration of two intact DNA molecules results in the exchange, reciprocal or nonreciprocal, of genetic material between the intact DNA molecule and the broken DNA molecule.

GO:0006259 DNA metabolic process: Any cellular metabolic process involving deoxyribonucleic acid. This is one of the two main types of nucleic acid, consisting of a long, unbranched macromolecule formed from one, or more commonly, two, strands of linked deoxyribonucleotides.

GO:0009066 aspartate family amino acid metabolic process: The chemical reactions and pathways involving amino acids of the aspartate family, comprising asparagine, aspartate, lysine, methionine and threonine.

GO: 0042178 xenobiotic catabolic process: The chemical reactions and pathways resulting in the breakdown of a xenobiotic compound (a compound foreign to the organism exposed to it). It may be synthesized by another organism (like ampicillin) or it can be a synthetic chemical.

GO:0010639 negative regulation of organelle organization: Any process that decreases the frequency, rate, or extent of a process involved in the formation, arrangement of constituent parts, or disassembly of an organelle.

GO:0045833 negative regulation of lipid metabolic process: Any process that stops, prevents, or reduces the frequency, rate, or extent of the chemical reactions and pathways involving lipids.

GO:1901607 alpha-amino acid biosynthetic process: The chemical reactions and pathways resulting in the formation of an alpha-amino acid.

Table 10 Top 10 Kidney Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Category Name | No. of Active Genes/ Platform Genes in Gene Set | % Gene Set Coverage | Active Genes | BMD_1std_ Median of Gene Set Transcripts (mg/kg) | Median BMD_L1Std_–BMD_U1Std_ (mg/kg) | Genes with Changed Direction Up | Genes with Changed Direction Down
Male
GO:0007420 brain development | 4/79 | 5% | Top2a; Nefh; Hmgcs2; Cxcr4 | 6.167 | 1.732–23.263 | 0 | 4
GO:0022412 cellular process involved in reproduction in multicellular organism | 3/60 | 5% | Top2a; Kif20a; Cxcr4 | 12.334 | 3.464–46.527 | 0 | 3
GO:1903046 meiotic cell-cycle process | 3/29 | 10% | Top2a; Nuf2; Kif20a | 12.334 | 4.279–46.527 | 0 | 3
GO:0051301 cell division | 4/79 | 5% | Top2a; Nuf2; Mcm5; Kif20a | 12.417 | 6.977–42.166 | 0 | 4
GO:0000281 mitotic cytokinesis | 3/16 | 19% | Kif23; Kif20a; Ect2 | 31.232 | 15.546–67.195 | 0 | 3
GO:0046685 response to arsenic-containing substance | 3/20 | 15% | Zfand2a; Nefh; Cyp1a1 | 49.045 | 39.236–64.853 | 2 | 1
GO:0098754 detoxification | 3/58 | 5% | Nqo1; Mt1; Akr7a3 | 62.795 | 48.749–87.647 | 2 | 1
GO:0001822 kidney development | 4/53 | 8% | Zfp354a; Rgn; Hmgcs2; Cyp4a8 | 102.787 | 65.463–185.933 | 1 | 3
GO:1901570 fatty acid derivative biosynthetic process | 3/23 | 13% | Hmgcs2; Cyp4a8; Cyp2c11 | 106.351 | 59.870–208.329 | 1 | 2
GO:0031099 regeneration | 7/120 | 6% | Socs3; Rgn; Nrep; Nefh; Dmbt1; Cebpb; Alas2 | 114.178 | 79.082–204.229 | 2 | 5
Female
GO:0048145 regulation of fibroblast proliferation | 4/41 | 10% | Thy1; Mmp9; Gstp1; Ccna2 | 14.574 | 7.161–41.985 | 1 | 3
GO:0048147 negative regulation of fibroblast proliferation | 3/11 | 27% | Thy1; Mmp9; Gstp1 | 14.763 | 9.430–25.720 | 1 | 2
GO:0001523 retinoid metabolic process | 4/19 | 21% | Ppard; Cyp26b1; Cyp1a1; Ces1d | 15.537 | 9.574–28.025 | 2 | 2
GO:0006694 steroid biosynthetic process | 4/49 | 8% | Dhcr7; Cyp26b1; Cyp1a1; Ces1d | 15.537 | 9.574–28.025 | 2 | 2
GO:0031100 animal organ regeneration | 4/80 | 5% | Vwf; Mki67; Gstp1; Ccna2 | 17.220 | 5.859–67.215 | 1 | 3
GO:0008610 lipid biosynthetic process | 7/122 | 6% | Ppard; Gstp1; Dhcr7; Cyp26b1; Cyp1a1; Ces1d; Alox15 | 18.187 | 10.018–36.727 | 3 | 4
GO:0016101 diterpenoid metabolic process | 5/26 | 19% | Ppard; Pgr; Cyp26b1; Cyp1a1; Ces1d | 18.187 | 10.018–36.727 | 2 | 3
GO:0034754 cellular hormone metabolic process | 3/41 | 7% | Ugt2b7; Cyp26b1; Cyp1a1 | 18.187 | 10.018–36.727 | 3 | 0
GO:1902653 secondary alcohol biosynthetic process | 3/22 | 14% | Dhcr7; Cyp26b1; Ces1d | 18.187 | 10.018–36.727 | 1 | 2
GO:0071241 cellular response to inorganic substance | 6/113 | 5% | Nqo1; Mmp9; Ect2; Cyp1a1; Ccna2; Alox15 | 20.033 | 8.435–72.186 | 2 | 4

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^27^ Official gene symbols from the Rat Genome Database^28^ are shown in the “Active Genes” column.

GO process description version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

GO:0007420 brain development: The process whose specific outcome is the progression of the brain over time, from its formation to the mature structure. Brain development begins with patterning events in the neural tube and ends with the mature structure that is the center of thought and emotion. The brain is responsible for the coordination and control of bodily activities and the interpretation of information from the senses (sight, hearing, smell, etc.).

GO:0022412 cellular process involved in reproduction in multicellular organism: A process, occurring at the cellular level, which is involved in the reproductive function of a multicellular organism.

GO:1903046 meiotic cell-cycle process: A process that is part of the meiotic cell cycle.

GO:0051301 cell division: The process resulting in division and partitioning of components of a cell to form more cells; may or may not be accompanied by the physical separation of a cell into distinct, individually membrane-bounded daughter cells.

GO:0000281 mitotic cytokinesis: A cell-cycle process that results in the division of the cytoplasm of a cell after mitosis, resulting in the separation of the original cell into two daughter cells.

GO:0046685 response to arsenic-containing substance: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an arsenic stimulus from compounds containing arsenic, including arsenates, arsenites, and arsenides.

GO:0098754 detoxification: Any process that reduces or removes the toxicity of a toxic substance. These may include transport of the toxic substance away from sensitive areas and to compartments or complexes whose purpose is sequestration of the toxic substance.

GO:0001822 kidney development: The process whose specific outcome is the progression of the kidney over time, from its formation to the mature structure. The kidney is an organ that filters the blood and/or excretes the end products of body metabolism in the form of urine.

GO:1901570 fatty acid derivative biosynthetic process: The chemical reactions and pathways resulting in the formation of fatty acid derivative.

GO:0031099 regeneration: The regrowth of a lost or destroyed body part, such as an organ or tissue. This process may occur via renewal, repair, and/or growth alone (i.e., increase in size or mass).

GO:0048145 regulation of fibroblast proliferation: Any process that modulates the frequency, rate, or extent of multiplication or reproduction of fibroblast cells.

GO:0048147 negative regulation of fibroblast proliferation: Any process that stops, prevents, or reduces the frequency, rate, or extent of multiplication or reproduction of fibroblast cells.

GO:0001523 retinoid metabolic process: The chemical reactions and pathways involving retinoids, any member of a class of isoprenoids that contain or are derived from four prenyl groups linked head-to-tail. Retinoids include retinol and retinal and structurally similar natural derivatives or synthetic compounds but need not have vitamin A activity.

GO:0006694 steroid biosynthetic process: The chemical reactions and pathways resulting in the formation of steroids, compounds with a 1,2,cyclopentanoperhydrophenanthrene nucleus; includes de novo formation and steroid interconversion by modification.

GO:0031100 animal organ regeneration: The regrowth of a lost or destroyed animal organ.

GO:0008610 lipid biosynthetic process: The chemical reactions and pathways resulting in the formation of lipids, compounds soluble in an organic solvent but not, or sparingly, in an aqueous solvent.

GO:0016101 diterpenoid metabolic process: The chemical reactions and pathways involving diterpenoid compounds, which are terpenoids with four isoprene units.

GO:0034754 cellular hormone metabolic process: The chemical reactions and pathways involving any hormone, naturally occurring substances secreted by specialized cells that affect the metabolism or behavior of other cells possessing functional receptors for the hormone, as carried out by individual cells.

GO:1902653 secondary alcohol biosynthetic process: The chemical reactions and pathways resulting in the formation of secondary alcohol.

GO:0071241 cellular response to inorganic substance: Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an inorganic substance stimulus.

No gene sets in the liver of male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were regulation of ossification (GO:0030278) and kidney development (GO:0001822) with median BMDs (BMD_L_s) of 5.660 (2.158) and 5.765 (1.618) mg/kg, respectively. In female rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were DNA conformation change (GO:0071103) and chromosome organization (GO:0051276), both with a median BMD (BMD_L_) of 1.874 (0.497) mg/kg.

No gene sets in the kidney of male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were brain development (GO:0007420) and cellular process involved in reproduction in multicellular organism (GO:0022412) with median BMDs (BMD_L_s) of 6.167 (1.732) and 12.334 (3.464) mg/kg, respectively. In female rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were regulation of fibroblast proliferation (GO:0048145) and negative regulation of fibroblast proliferation (GO:0048147) with median BMDs (BMD_L_s) of 14.574 (7.161) and 14.763 (9.430) mg/kg, respectively. The full list of affected gene sets in the liver and kidney of male and female rats can be found in Appendix F[underlined: .]

## Gene Benchmark Dose Analysis

The top 10 genes based on BMD potency in the liver and kidney (fold change >|2|, significant Williams trend test, global goodness-of-fit p value >0.1, and BMD_U_/BMD_L_ ≤40) are shown in Table 11 and Table 12. As with the GO analysis, the biological or toxicological significance of the changes in gene expression shown in Table 11 and Table 12 should be interpreted with caution. The data primarily should be considered a metric of potency for chemical-induced transcriptional changes that could serve as a conservative surrogate of estimated biological potency, and by extension toxicological potency, when more definitive toxicological data are unavailable.

Table 11 Top 10 Liver Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | BMD_1Std_ (BMD_L1std_–BMD_U1std_) in mg/kg | Maximum Fold Change | Direction of Expression Change
Male
Zfp354a | 24522 | ZFP354A_10203 | 3.267 (1.720–6.668) | 6.5 | DOWN
G0s2 | 289388 | G0S2_32729 | 3.451 (1.074–14.322) | 2.1 | UP
Tsku | 308843 | TSKU_10094 | 6.126 (1.466–41.334) | 2.4 | DOWN
Egr1 | 24330 | EGR1_8533 | 8.263 (1.517–45.905) | 5.3 | DOWN
C7 | 117517 | C7_8179 | 13.843 (5.329–41.896) | 2.5 | DOWN
Trib3 | 246273 | TRIB3_10079 | 16.895 (6.465–58.991) | 2.3 | UP
Akr7a3 | 26760 | AKR7A3_8015 | 19.850 (12.797–32.354) | 4.1 | UP
Nqo1 | 24314 | NQO1_33055 | 24.112 (16.415–37.043) | 4.8 | UP
Ephx1 | 25315 | EPHX1_8567 | 24.878 (15.487–41.380) | 2.6 | UP
Loc100911558/Spink1l | 100911558 | SPINK1_32461 | 26.630 (12.428–61.587) | 2.0 | DOWN
Female
Kif22 | 293502 | KIF22_8963 | 0.962 (0.282–4.473) | 2.1 | UP
Anln | 363031 | ANLN_32599 | 3.325 (1.105–12.281) | 2.1 | UP
Anlnl1 | 307056 | ANLN_32599 | 3.325 (1.105–12.281) | 2.1 | UP
Car3 | 54232 | CAR3_8196 | 3.449 (2.131–6.021) | 6.8 | DOWN
Aass | 296925 | AASS_7936 | 5.811 (2.605–14.079) | 2.3 | DOWN
Asns | 25612 | ASNS_8091 | 6.056 (2.744–14.335) | 3.5 | UP
A2m | 24153 | A2M_7932 | 8.459 (1.870–42.023) | 2.8 | DOWN
Loc100911545/A2m | 100911545 | A2M_7932 | 8.459 (1.870–42.023) | 2.8 | DOWN
Nr1d2 | 259241 | NR1D2_9358 | 9.460 (2.213–49.422) | 2.2 | UP
Sez6 | 192247 | SEZ6_9819 | 10.639 (3.960–29.500) | 3.7 | DOWN

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean.

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^29^ and Entrez Gene.^30^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Zfp354a: Rat Uniprot function (Human ZNF354A): It may play a role in renal development and may also be involved in the repair of the kidney after ischemia-reperfusion or folic acid administration.

G0s2: Human Uniprot function (Human G0S2): Promotes apoptosis by binding to BCL2, hence preventing the formation of protective BCL2-BAX heterodimers. {ECO0000269|PubMed19706769}.

Tsku: Human Uniprot function (Human TSKU): Contributes to various developmental events and other processes such as wound healing and cholesterol homeostasis through its interactions with multiple signaling pathways. Wnt signaling inhibitor, which competes with WNT2B for binding to Wnt receptor FZD4 and represses WNT2B-dependent development of the peripheral eye. Plays a role in regulating the hair cycle by controlling TGFB1 signaling. Required for the development of the anterior commissure in the brain by inhibiting neurite outgrowth. Essential for terminal differentiation of hippocampal neural stem cells. Plays a role in regulating bone elongation and bone mass by modulating growth plate chondrocyte function and overall body size. Required for development of the inner ear through its involvement in stereocilia formation in inner hair cells. Facilitates wound healing by inhibiting secretion of TGFB1 from macrophages, which prevents myofibroblast differentiation, maintaining inflammatory cell quiescence. Plays a role in cholesterol homeostasis by reducing circulating high-density lipoprotein cholesterol, lowering cholesterol efflux capacity and decreasing cholesterol-to-bile acid conversion in the liver. In one study, shown to negatively regulate sympathetic innervation in brown fat, leading to reduced energy expenditure. In another study, shown not to affect brown fat thermogenic capacity, body weight gain, or glucose homeostasis.

Egr1: Human Uniprot function (Human EGR1): Transcriptional regulator (PubMed20121949). Recognizes and binds to the DNA sequence 5’-GCG(T/G)GGGCG-3’(EGR-site) in the promoter region of target genes (by similarity). Binds double-stranded target DNA, irrespective of the cytosine methylation status (PubMed25258363, PubMed25999311). Regulates the transcription of numerous target genes, and thereby plays an important role in regulating the response to growth factors, DNA damage, and ischemia. Plays a role in the regulation of cell survival, proliferation and cell death. Activates expression of p53/TP53 and TGFB1, and thereby helps prevent tumor formation. Required for normal progress through mitosis and normal proliferation of hepatocytes after partial hepatectomy. Mediates responses to ischemia and hypoxia; regulates the expression of proteins such as IL1B and CXCL2 that are involved in inflammatory processes and development of tissue damage after ischemia. Regulates biosynthesis of luteinizing hormone (LHB) in the pituitary (by similarity). Regulates the amplitude of the expression rhythms of clock genes ARNTL/BMAL1, PER2 and NR1D1 in the liver via the activation of PER1 (clock repressor) transcription. Regulates the rhythmic expression of core clock gene ARNTL/BMAL1 in the suprachiasmatic nucleus (SCN) (by similarity). {ECO0000250|UniProtKBP08046, ECO0000269|PubMed20121949, ECO0000269|PubMed25258363, ECO0000269|PubMed25999311}.

C7: Human Uniprot function (Human C7): Constituent of the membrane attack complex (MAC) that plays a key role in the innate and adaptive immune response by forming pores in the plasma membrane of target cells. C7 serves as a membrane anchor.

Trib3: Human Uniprot function (Human TRIB3): Inactive protein kinase which acts as a regulator of the integrated stress response (ISR), a process for adaptation to various stress (PubMed15781252, PubMed15775988). Inhibits the transcriptional activity of DDIT3/CHOP and is involved in DDIT3/CHOP-dependent cell death during ER stress (PubMed15781252, PubMed15775988). May play a role in programmed neuronal cell death but does not appear to affect nonneuronal cells (PubMed15781252, PubMed15775988). Acts as a negative feedback regulator of the ATF4-dependent transcription during the ISR, while TRIB3 expression is promoted by ATF4, TRIB3 protein interacts with ATF4 and inhibits ATF4 transcription activity (by similarity). Disrupts insulin signaling by binding directly to Akt kinases and blocking their activation (by similarity). May bind directly to and mask the ‘Thr-308’ phosphorylation site in AKT1 (by similarity). Interacts with the NF-kappa-B transactivator p65 RELA and inhibits its phosphorylation and thus its transcriptional activation activity (PubMed12736262). Interacts with MAPK kinases and regulates activation of MAP kinases (PubMed15299019). Can inhibit APOBEC3A editing of nuclear DNA (PubMed22977230). {ECO0000250|UniProtKBQ8K4K2, ECO0000269|PubMed12736262, ECO0000269|PubMed15299019, ECO0000269|PubMed15775988, ECO0000269|PubMed15781252, ECO0000269|PubMed22977230}.

Akr7a3: Human Uniprot function (Human AKR7A3): Can reduce the dialdehyde protein-binding form of aflatoxin B1 (AFB1) to the nonbinding AFB1 dialcohol. May be involved in protection of liver against the toxic and carcinogenic effects of AFB1, a potent hepatocarcinogen. {ECO0000269|PubMed18416522}.

Nqo1: Human Uniprot function (Human NQO1): The enzyme apparently serves as a quinone reductase in connection with conjugation reactions of hydroquinons involved in detoxification pathways as well as in biosynthetic processes such as the vitamin K-dependent gamma-carboxylation of glutamate residues in prothrombin synthesis.

Ephx1: Human Uniprot function (Human EPHX1): Biotransformation enzyme that catalyzes the hydrolysis of arene and aliphatic epoxides to less reactive and more water soluble dihydrodiols by the trans addition of water (by similarity). Plays a role in the metabolism of endogenous lipids such as epoxide-containing fatty acids (PubMed22798687). Metabolizes the abundant endocannabinoid 2-arachidonoylglycerol (2-AG) to free arachidonic acid (AA) and glycerol (PubMed24958911). {ECO0000250|UniProtKBP07687, ECO0000269|PubMed22798687, ECO0000269|PubMed24958911}.

LOC100911558/Spink1l: Human Uniprot function (Human SPINK1): Serine protease inhibitor which exhibits anti-trypsin activity (PubMed7142173). In the pancreas, protects against trypsin-catalyzed premature activation of zymogens (by similarity). {ECO0000250|UniProtKBP09036, ECO0000269|PubMed7142173}. FUNCTION In the male reproductive tract, binds to sperm heads where it modulates sperm capacitance by inhibiting calcium uptake and nitrogen oxide (NO) production. {ECO0000250|UniProtKBP09036}.

Kif22: Human Uniprot function (Human KIF22): Kinesin family member that is involved in spindle formation and the movements of chromosomes during mitosis and meiosis. Binds to microtubules and to DNA (by similarity). Plays a role in congression of laterally attached chromosomes in NDC80-depleted cells (PubMed25743205). {ECO0000250|UniProtKBQ9I869, ECO0000269|PubMed25743205}.

Anln: Human Uniprot function (Human ANLN): Required for cytokinesis (PubMed16040610). Essential for the structural integrity of the cleavage furrow and for completion of cleavage furrow ingression. Plays a role in bleb assembly during metaphase and anaphase of mitosis (PubMed23870127). May play a significant role in podocyte cell migration (PubMed24676636). {ECO0000269|PubMed10931866, ECO0000269|PubMed12479805, ECO0000269|PubMed15496454, ECO0000269|PubMed16040610, ECO0000269|PubMed16357138, ECO0000269|PubMed23870127, ECO0000269|PubMed24676636}.

Anlnl1: Human Uniprot function (Human ANLN): Required for cytokinesis (PubMed16040610). Essential for the structural integrity of the cleavage furrow and for completion of cleavage furrow ingression. Plays a role in bleb assembly during metaphase and anaphase of mitosis (PubMed23870127). May play a significant role in podocyte cell migration (PubMed24676636). {ECO0000269|PubMed10931866, ECO0000269|PubMed12479805, ECO0000269|PubMed15496454, ECO0000269|PubMed16040610, ECO0000269|PubMed16357138, ECO0000269|PubMed23870127, ECO0000269|PubMed24676636}.

Car3: Human Uniprot function (Human CA3): Reversible hydration of carbon dioxide.

Aass: Human Uniprot function (Human AASS): Bifunctional enzyme that catalyzes the first two steps in lysine degradation. The N-terminal and the C-terminal contain lysine-ketoglutarate reductase and saccharopine dehydrogenase activity, respectively.

Asns: Human Entrez Gene Summary (Human ASNS): The protein encoded by this gene is involved in the synthesis of asparagine. This gene complements a mutation in the temperature-sensitive hamster mutant ts11, which blocks progression through the G1 phase of the cell cycle at nonpermissive temperature. Alternatively spliced transcript variants have been described for this gene. [provided by RefSeq, May 2010]

A2m: Human Uniprot function (Human A2M): Is able to inhibit all four classes of proteinases by a unique ‘trapping’ mechanism. This protein has a peptide stretch, called the ‘bait region’ which contains specific cleavage sites for different proteinases. When a proteinase cleaves the bait region, a conformational change is induced in the protein which traps the proteinase. The entrapped enzyme remains active against low molecular weight substrates (activity against high molecular weight substrates is greatly reduced). Following cleavage in the bait region, a thioester bond is hydrolyzed and mediates the covalent binding of the protein to the proteinase.

LOC100911545/A2m: Human Uniprot function (Human A2M): Is able to inhibit all four classes of proteinases by a unique ‘trapping’ mechanism. This protein has a peptide stretch, called the ‘bait region’ which contains specific cleavage sites for different proteinases. When a proteinase cleaves the bait region, a conformational change is induced in the protein which traps the proteinase. The entrapped enzyme remains active against low molecular weight substrates (activity against high molecular weight substrates is greatly reduced). Following cleavage in the bait region, a thioester bond is hydrolyzed and mediates the covalent binding of the protein to the proteinase.

Nr1d2: Human Uniprot function (Human NR1D2): Transcriptional repressor which coordinates circadian rhythm and metabolic pathways in a heme-dependent manner. Integral component of the complex transcription machinery that governs circadian rhythmicity and forms a critical negative limb of the circadian clock by directly repressing the expression of core clock components ARNTL/BMAL1 and CLOCK. Also regulates genes involved in metabolic functions, including lipid metabolism and the inflammatory response. Acts as a receptor for heme which stimulates its interaction with the NCOR1/HDAC3 corepressor complex, enhancing transcriptional repression. Recognizes two classes of DNA response elements within the promoter of its target genes and can bind to DNA as either monomers or homodimers, depending on the nature of the response element. Binds as a monomer to a response element composed of the consensus half-site motif 5’-[A/G]GGTCA-3’ preceded by an A/T-rich 5’ sequence (RevRE), or as a homodimer to a direct repeat of the core motif spaced by two nuclegotides (RevDR-2). Acts as a potent competitive repressor of ROR alpha (RORA) function and also negatively regulates the expression of NR1D1. Regulates lipid and energy homeostasis in the skeletal muscle via repression of genes involved in lipid metabolism and myogenesis including CD36, FABP3, FABP4, UCP3, SCD1 and MSTN. Regulates hepatic lipid metabolism via the repression of APOC3. Represses gene expression at a distance in macrophages by inhibiting the transcription of enhancer-derived RNAs (eRNAs). In addition to its activity as a repressor, can also act as a transcriptional activator. Acts as a transcriptional activator of the sterol regulatory element-binding protein 1 (SREBF1) and the inflammatory mediator interleukin-6 (IL6) in the skeletal muscle (by similarity). Plays a role in the regulation of circadian sleep/wake cycle; essential for maintaining wakefulness during the dark phase or active period (by similarity). Key regulator of skeletal muscle mitochondrial function; negatively regulates the skeletal muscle expression of core clock genes and genes involved in mitochondrial biogenesis, fatty acid beta-oxidation and lipid metabolism (by similarity). May play a role in the circadian control of neutrophilic inflammation in the lung (by similarity). {ECO0000250|UniProtKBQ60674, ECO0000269|PubMed17892483, ECO0000269|PubMed17996965}.

Sez6: Human Uniprot function (Human SEZ6): May play a role in cell-cell recognition and in neuronal membrane signaling. Seems to be important for the achievement of the necessary balance between dendrite elongation and branching during the elaboration of a complex dendritic arbor. Involved in the development of appropriate excitatory synaptic connectivity (by similarity). {ECO0000250}.

Table 12 Top 10 Kidney Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Gene Symbol | Entrez Gene IDs | Probe IDs | BMD_1Std_ (BMD_L1std_–BMD_U1std_) in mg/kg | Maximum Fold Change | Direction of Expression Change
Male
Nefh | 24587 | NEFH_33218 | <0.050^b^ (NR) | 2.4 | DOWN
Top2a | 360243 | TOP2A_10059 | 12.334 (3.464-46.527) | 2.8 | DOWN
Ect2 | 361921 | ECT2_8523 | 31.232 (16.473-67.195) | 2.2 | DOWN
Nqo1 | 24314 | NQO1_33055 | 40.551 (21.583-79.355) | 2.6 | UP
Cyp1a1 | 24296 | CYP1A1_8415 | 49.045 (39.236-64.853) | 8.8 | UP
Hmgcs2 | 24450 | HMGCS2_8812 | 106.351 (59.870-208.329) | 2.6 | DOWN
Nfil3 | 114519 | NFIL3_9304 | 121.321 (82.552-229.790) | 2.2 | DOWN
Mt1 | 24567 | MT1A_9255 | 168.588 (103.554-1208.950) | 2.1 | DOWN
Cyp2c11 | 29277 | CYP2C11_32593 | 216.743 (139.563-368.944) | 8.4 | DOWN
Rassf1 | 363140 | RASSF1_32475 | 903.848 (608.514-1171.720) | 2.7 | UP
Female
Cyp1a1 | 24296 | CYP1A1_8415 | 12.886 (9.131-19.323) | 15.5 | UP
Gstp1 | 24426 | GSTP1_8762 | 14.763 (9.430-25.720) | 3.5 | UP
Cyp26b1 | 312495 | CYP26B1_8418 | 18.187 (10.018-36.727) | 2.1 | UP
Vwf | 116669 | VWF_32396 | 19.676 (4.116-94.078) | 2.1 | DOWN
Abcb1b | 24646 | ABCB1B_7939 | 20.794 (8.254-57.212) | 6.2 | DOWN
Npas2 | 316351 | NPAS2_9350 | 21.088 (11.331-43.562) | 3.1 | DOWN
Arntl | 29657 | ARNTL_8086 | 22.913 (11.412-50.159) | 3.4 | DOWN
C4a | 24233 | C4A_8176 | 24.209 (8.100-89.537) | 2.3 | DOWN
Loc103689965/C4a | 103689965 | C4A_8176 | 24.209 (8.100-89.537) | 2.3 | DOWN
Nqo1 | 24314 | NQO1_33055 | 25.681 (7.739-86.121) | 2.2 | UP

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NR = the BMD_L1Std_–BMD_U1Std_ range is not reportable because the BMD median is below the lower limit of extrapolation (<1/3 of the lowest nonzero dose tested).

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^29^ and Entrez Gene.^30^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ <0.050 = a best-fit model was identified and a BMD was estimated that was <1/3 of the lowest nonzero dose tested.

Gene definition version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Nefh: Human Uniprot function (Human NEFH): Neurofilaments usually contain three intermediate filament proteins NEFL, NEFM, and NEFH which are involved in the maintenance of neuronal caliber. NEFH has an important function in mature axons that is not subserved by the two smaller NF proteins. May additionally cooperate with the neuronal intermediate filament proteins PRPH and INA to form neuronal filamentous networks (by similarity). {ECO0000250|UniProtKBP19246}.

Top2a: Human Uniprot function (Human TOP2A): Key decatenating enzyme that alters DNA topology by binding to two double-stranded DNA molecules, generating a double-stranded break in one of the strands, passing the intact strand through the broken strand, and religating the broken strand (PubMed17567603, PubMed18790802, PubMed22013166, PubMed22323612). May play a role in regulating the period length of ARNTL/BMAL1 transcriptional oscillation (by similarity). {ECO0000250|UniProtKBQ01320, ECO0000269|PubMed17567603, ECO0000269|PubMed18790802, ECO0000269|PubMed22013166, ECO0000269|PubMed22323612}.

Ect2: Human Uniprot function (Human ECT2): Guanine nucleotide exchange factor (GEF) that catalyzes the exchange of GDP for GTP. Promotes guanine nucleotide exchange on the Rho family members of small GTPases, like RHOA, RHOC, RAC1, and CDC42. Required for signal transduction pathways involved in the regulation of cytokinesis. Component of the centralspindlin complex that serves as a microtubule-dependent and Rho-mediated signaling required for the myosin contractile ring formation during the cell-cycle cytokinesis. Regulates the translocation of RHOA from the central spindle to the equatorial region. Plays a role in the control of mitotic spindle assembly; regulates the activation of CDC42 in metaphase for the process of spindle fibers attachment to kinetochores before chromosome congression. Involved in the regulation of epithelial cell polarity; participates in the formation of epithelial tight junctions in a polarity complex PARD3-PARD6-protein kinase PRKCQ-dependent manner. Plays a role in the regulation of neurite outgrowth. Inhibits phenobarbital (PB)-induced NR1I3 nuclear translocation. Stimulates the activity of RAC1 through its association with the oncogenic PARD6A-PRKCI complex in cancer cells, thereby acting to coordinately drive tumor cell proliferation and invasion. Also stimulates genotoxic stress-induced RHOB activity in breast cancer cells leading to their cell death. {ECO0000269|PubMed10579713, ECO0000269|PubMed14645260, ECO0000269|PubMed15254234, ECO0000269|PubMed15545273, ECO0000269|PubMed15642749, ECO0000269|PubMed16103226, ECO0000269|PubMed16170345, ECO0000269|PubMed16236794, ECO0000269|PubMed16495035, ECO0000269|PubMed19129481, ECO0000269|PubMed19468300, ECO0000269|PubMed19617897, ECO0000269|PubMed21189248, ECO0000269|PubMed21373644, ECO0000269|PubMed25068414, ECO0000269|PubMed31888991}.

Nqo1: Human Uniprot function (Human NQO1): The enzyme apparently serves as a quinone reductase in connection with conjugation reactions of hydroquinons involved in detoxification pathways as well as in biosynthetic processes, such as the vitamin K-dependent gamma-carboxylation of glutamate residues in prothrombin synthesis.

Cyp1a1: Human Uniprot function (Human CYP1A1): A cytochrome P450 monooxygenase involved in the metabolism of various endogenous substrates, including fatty acids, steroid hormones and vitamins (PubMed11555828, PubMed14559847, PubMed12865317, PubMed15805301, PubMed15041462, PubMed18577768, PubMed19965576, PubMed20972997, PubMed10681376). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH–hemoprotein reductase) (PubMed11555828, PubMed14559847, PubMed12865317, PubMed15805301, PubMed15041462, PubMed18577768, PubMed19965576, PubMed20972997, PubMed10681376). Catalyzes the hydroxylation of carbon-hydrogen bonds. Exhibits high catalytic activity for the formation of hydroxyestrogens from estrone (E1) and 17beta-estradiol (E2), namely 2-hydroxy E1 and E2, as well as D-ring hydroxylated E1 and E2 at the C15-alpha and C16-alpha positions (PubMed11555828, PubMed14559847, PubMed12865317, PubMed15805301). Displays different regioselectivities for polyunsaturated fatty acids (PUFA) hydroxylation (PubMed15041462, PubMed18577768). Catalyzes the epoxidation of double bonds of certain PUFA (PubMed15041462, PubMed19965576, PubMed20972997). Converts arachidonic acid toward epoxyeicosatrienoic acid (EET) regioisomers, 8,9-, 11,12-, and 14,15-EET that function as lipid mediators in the vascular system (PubMed20972997). Displays an absolute stereoselectivity in the epoxidation of eicosapentaenoic acid producing the 17(R),18(S) enantiomer (PubMed15041462). May play an important role in all-trans retinoic acid biosynthesis in extrahepatic tissues. Catalyzes two successive oxidative transformation of all-trans-retinol to all-trans-retinal and then to the active form all-trans retinoic acid (PubMed10681376). May also participate in eicosanoids metabolism by converting hydroperoxide species into oxo metabolites (lipoxygenase-like reaction, NADPH-independent) (PubMed21068195). {ECO0000269|PubMed10681376, ECO0000269|PubMed11555828, ECO0000269|PubMed12865317, ECO0000269|PubMed14559847, ECO0000269|PubMed15041462, ECO0000269|PubMed15805301, ECO0000269|PubMed18577768, ECO0000269|PubMed19965576, ECO0000269|PubMed20972997, ECO0000269|PubMed21068195}.

Hmgcs2: Human Uniprot function (Human HMGCS2): Catalyzes the first irreversible step in ketogenesis, condensing acetyl-CoA to acetoacetyl-CoA to form HMG-CoA, which is converted by HMG-CoA reductase (HMGCR) into mevalonate. {ECO0000269|PubMed11228257, ECO0000269|PubMed23751782, ECO0000269|PubMed29597274}.

Nfil3: Human Uniprot function (Human NFIL3): Acts as a transcriptional regulator that recognizes and binds to the sequence 5’-[GA]TTA[CT]GTAA[CT]-3’, a sequence present in many cellular and viral promoters. Represses transcription from promoters with activating transcription factor (ATF) sites. Represses promoter activity in osteoblasts (by similarity). Represses transcriptional activity of PER1 (by similarity). Represses transcriptional activity of PER2 via the B-site on the promoter (by similarity). Activates transcription from the interleukin-3 promoter in T-cells. Competes for the same consensus-binding site with PAR DNA-binding factors (DBP, HLF, and TEF) (by similarity). Component of the circadian clock that acts as a negative regulator for the circadian expression of PER2 oscillation in the cell-autonomous core clock (by similarity). Protects pro-B cells from programmed cell death (by similarity). Represses the transcription of CYP2A5 (by similarity). Positively regulates the expression and activity of CES2 by antagonizing the repressive action of NR1D1 on CES2 (by similarity). {ECO0000250|UniProtKBO08750, ECO0000269|PubMed1620116, ECO0000269|PubMed7565758, ECO0000269|PubMed8836190}.

Mt1: Human Uniprot function (Human MT1A): Metallothioneins have a high content of cysteine residues that bind various heavy metals; these proteins are transcriptionally regulated by both heavy metals and glucocorticoids.

Cyp2c11: Human Uniprot function (Human CYP2C9): A cytochrome P450 monooxygenase involved in the metabolism of various endogenous substrates, including fatty acids and steroids (PubMed7574697, PubMed9866708, PubMed9435160, PubMed12865317, PubMed15766564, PubMed19965576, PubMed21576599). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH--hemoprotein reductase) (PubMed7574697, PubMed9866708, PubMed9435160, PubMed12865317, PubMed15766564, PubMed19965576, PubMed21576599). Catalyzes the epoxidation of double bonds of polyunsaturated fatty acids (PUFA) (PubMed7574697, PubMed15766564, PubMed19965576, PubMed9866708). Catalyzes the hydroxylation of carbon-hydrogen bonds. Metabolizes cholesterol toward 25-hydroxycholesterol, a physiological regulator of cellular cholesterol homeostasis (PubMed21576599). Exhibits low catalytic activity for the formation of catechol estrogens from 17beta-estradiol (E2) and estrone (E1), namely 2-hydroxy E1 and E2 (PubMed12865317). Catalyzes bisallylic hydroxylation and hydroxylation with double-bond migration of polyunsaturated fatty acids (PUFA) (PubMed9866708, PubMed9435160). Also metabolizes plant monoterpenes such as limonene. Oxygenates (R)- and (S)-limonene to produce carveol and perillyl alcohol (PubMed11950794). Contributes to the wide pharmacokinetics variability of the metabolism of drugs such as S-warfarin, diclofenac, phenytoin, tolbutamide, and losartan (PubMed25994031). {ECO0000269|PubMed11950794, ECO0000269|PubMed12865317, ECO0000269|PubMed15766564, ECO0000269|PubMed19965576, ECO0000269|PubMed21576599, ECO0000269|PubMed25994031, ECO0000269|PubMed7574697, ECO0000269|PubMed9435160, ECO0000269|PubMed9866708}.

Rassf1: Human Uniprot function (Human RASSF1): Potential tumor suppressor. Required for death receptor-dependent apoptosis. Mediates activation of STK3/MST2 and STK4/MST1 during Fas-induced apoptosis by preventing their dephosphorylation. When associated with MOAP1, promotes BAX conformational change and translocation to mitochondrial membranes in response to TNF and TNFSF10 stimulation. Isoform A interacts with CDC20, an activator of the anaphase-promoting complex, APC, resulting in the inhibition of APC activity and mitotic progression. Inhibits proliferation by negatively regulating cell-cycle progression at the level of G1/S-phase transition by regulating accumulation of cyclin D1 protein. Isoform C has been shown not to perform these roles, no function has been identified for this isoform. Isoform A disrupts interactions among MDM2, DAXX, and USP7, thus contributing to the efficient activation of TP53 by promoting MDM2 self-ubiquitination in cell-cycle checkpoint control in response to DNA damage. {ECO0000269|PubMed10888881, ECO0000269|PubMed11333291, ECO0000269|PubMed12024041, ECO0000269|PubMed14743218, ECO0000269|PubMed15109305, ECO0000269|PubMed15949439, ECO0000269|PubMed16510573, ECO0000269|PubMed18566590, ECO0000269|PubMed21199877}.

Gstp1: Human Uniprot function (Human GSTP1): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles. Involved in the formation of glutathione conjugates of both prostaglandin A2 (PGA2) and prostaglandin J2 (PGJ2) (PubMed9084911). Participates in the formation of novel hepoxilin regioisomers (PubMed21046276). Regulates negatively CDK5 activity via p25/p35 translocation to prevent neurodegeneration. {ECO0000269|PubMed21046276, ECO0000269|PubMed21668448, ECO0000269|PubMed9084911}.

Cyp26b1: Human Uniprot function (Human CYP26B1): Involved in the metabolism of retinoic acid (RA), rendering this classical morphogen inactive through oxidation (PubMed10823918, PubMed22020119). Involved in the specific inactivation of all-trans retinoic acid (all-trans RA), with a preference for the following substrates all-trans RA > 9-cis RA > 13-cis RA (PubMed10823918, PubMed22020119). Generates several hydroxylated forms of RA, including 4-OH-RA, 4-oxo-RA, and 18-OH-RA (PubMed10823918). Catalyzes the hydroxylation of carbon-hydrogen bonds of atRA primarily at C-4 (PubMed10823918, PubMed22020119). Essential for postnatal survival (by similarity). Plays a central role in germ cell development acts by degrading RA in the developing testis, preventing STRA8 expression, thereby leading to delay of meiosis (by similarity). Required for the maintenance of the undifferentiated state of male germ cells during embryonic development in Sertoli cells, inducing arrest in G0 phase of the cell cycle and preventing meiotic entry (by similarity). Plays a role in skeletal development, both at the level of patterning and in the ossification of bone and the establishment of some synovial joints (PubMed22019272). {ECO0000250|UniProtKBQ811W2, ECO0000269|PubMed10823918, ECO0000269|PubMed22019272, ECO0000269|PubMed22020119}. FUNCTION Has also a significant activity in oxidation of tazarotenic acid and may therefore metabolize that xenobiotic in vivo. {ECO0000269|PubMed26937021}.

Vwf: Human Uniprot function (Human VWF): Important in the maintenance of hemostasis, it promotes adhesion of platelets to the sites of vascular injury by forming a molecular bridge between sub-endothelial collagen matrix and platelet-surface receptor complex GPIb-IX-V. Also acts as a chaperone for coagulation factor VIII, delivering it to the site of injury, stabilizing its heterodimeric structure, and protecting it from premature clearance from plasma.

Abcb1b: Human Uniprot function (Human ABCB1): Translocates drugs and phospholipids across the membrane (PubMed8898203, PubMed2897240, PubMed9038218). Catalyzes the flop of phospholipids from the cytoplasmic to the exoplasmic leaflet of the apical membrane. Participates mainly to the flop of phosphatidylcholine, phosphatidylethanolamine, beta-D-glucosylceramides, and sphingomyelins (PubMed8898203). Energy-dependent efflux pump responsible for decreased drug accumulation in multidrug-resistant cells (PubMed2897240, PubMed9038218). {ECO0000269|PubMed2897240, ECO0000269|PubMed8898203, ECO0000269|PubMed9038218}.

Npas2: Human Uniprot function (Human NPAS2): Transcriptional activator that forms a core component of the circadian clock. The circadian clock, an internal time-keeping system, regulates various physiological processes through the generation of approximately 24-hour circadian rhythms in gene expression, which are translated into rhythms in metabolism and behavior. It is derived from the Latin roots ‘circa’ (about) and ‘diem’ (day) and acts as an important regulator of a wide array of physiological functions including metabolism, sleep, body temperature, blood pressure, endocrine, immune, cardiovascular, and renal function. Consists of two major components the central clock, residing in the suprachiasmatic nucleus (SCN) of the brain, and the peripheral clocks that are present in nearly every tissue and organ system. Both the central and peripheral clocks can be reset by environmental cues, also known as Zeitgebers (German for “timegivers”). The predominant Zeitgeber for the central clock is light, which is sensed by retina and signals directly to the SCN. The central clock entrains the peripheral clocks through neuronal and hormonal signals, body temperature and feeding-related cues, aligning all clocks with the external light/dark cycle. Circadian rhythms allow an organism to achieve temporal homeostasis with its environment at the molecular level by regulating gene expression to create a peak of protein expression once every 24 hours to control when a particular physiological process is most active with respect to the solar day. Transcription and translation of core clock components (CLOCK, NPAS2, ARNTL/BMAL1, ARNTL2/BMAL2, PER1, PER2, PER3, CRY1, and CRY2) plays a critical role in rhythm generation, whereas delays imposed by post-translational modifications (PTMs) are important for determining the period (tau) of the rhythms (tau refers to the period of a rhythm and is the length, in time, of one complete cycle). A diurnal rhythm is synchronized with the day/night cycle, while the ultradian and infradian rhythms have a period shorter and longer than 24 hours, respectively. Disruptions in the circadian rhythms contribute to the pathology of cardiovascular diseases, cancer, metabolic syndromes, and aging. A transcription/translation feedback loop (TTFL) forms the core of the molecular circadian clock mechanism. Transcription factors, CLOCK or NPAS2 and ARNTL/BMAL1 or ARNTL2/BMAL2, form the positive limb of the feedback loop, act in the form of a heterodimer, and activate the transcription of core clock genes and clock-controlled genes (involved in key metabolic processes), harboring E-box elements (5’-CACGTG-3’) within their promoters. The core clock genes PER1/2/3 and CRY1/2, which are transcriptional repressors, form the negative limb of the feedback loop and interact with the CLOCK|NPAS2-ARNTL/BMAL1|ARNTL2/BMAL2 heterodimer inhibiting its activity and thereby negatively regulating their own expression. This heterodimer also activates nuclear receptors NR1D1/2 and RORA/B/G, which form a second feedback loop and which activate and repress ARNTL/BMAL1 transcription, respectively. The NPAS2-ARNTL/BMAL1 heterodimer positively regulates the expression of MAOA, F7, and LDHA and modulates the circadian rhythm of daytime contrast sensitivity by regulating the rhythmic expression of adenylate cyclase type 1 (ADCY1) in the retina. NPAS2 plays an important role in sleep homeostasis and in maintaining circadian behaviors in normal light/dark and feeding conditions and in the effective synchronization of feeding behavior with scheduled food availability. Regulates the gene transcription of key metabolic pathways in the liver and is involved in DNA damage response by regulating several cell cycle and DNA repair genes. Controls the circadian rhythm of NR0B2 expression by binding rhythmically to its promoter (by similarity). Mediates the diurnal variation in the expression of GABARA1 receptor in the brain and contributes to the regulation of anxiety-like behaviors and GABAergic neurotransmission in the ventral striatum (by similarity). {ECO0000250|UniProtKBP97460, ECO0000269|PubMed11441146, ECO0000269|PubMed11441147, ECO0000269|PubMed14645221, ECO0000269|PubMed18439826, ECO0000269|PubMed18819933}.

Arntl: Human Uniprot function (Human ARNTL): Transcriptional activator that forms a core component of the circadian clock. The circadian clock, an internal time-keeping system, regulates various physiological processes through the generation of approximately 24-hour circadian rhythms in gene expression, which are translated into rhythms in metabolism and behavior. It is derived from the Latin roots ‘circa’ (about) and ‘diem’ (day) and acts as an important regulator of a wide array of physiological functions including metabolism, sleep, body temperature, blood pressure, endocrine, immune, cardiovascular, and renal function. Consists of two major components the central clock, residing in the suprachiasmatic nucleus (SCN) of the brain, and the peripheral clocks that are present in nearly every tissue and organ system. Both the central and peripheral clocks can be reset by environmental cues, also known as Zeitgebers (German for ‘timegivers’). The predominant Zeitgeber for the central clock is light, which is sensed by retina and signals directly to the SCN. The central clock entrains the peripheral clocks through neuronal and hormonal signals, body temperature, and feeding-related cues, aligning all clocks with the external light/dark cycle. Circadian rhythms allow an organism to achieve temporal homeostasis with its environment at the molecular level by regulating gene expression to create a peak of protein expression once every 24 hours to control when a particular physiological process is most active with respect to the solar day. Transcription and translation of core clock components (CLOCK, NPAS2, ARNTL/BMAL1, ARNTL2/BMAL2, PER1, PER2, PER3, CRY1, and CRY2) plays a critical role in rhythm generation, whereas delays imposed by post-translational modifications (PTMs) are important for determining the period (tau) of the rhythms (tau refers to the period of a rhythm and is the length, in time, of one complete cycle). A diurnal rhythm is synchronized with the day/night cycle, while the ultradian and infradian rhythms have a period shorter and longer than 24 hours, respectively. Disruptions in the circadian rhythms contribute to the pathology of cardiovascular diseases, cancer, metabolic syndromes, and aging. A transcription/translation feedback loop (TTFL) forms the core of the molecular circadian clock mechanism. Transcription factors, CLOCK or NPAS2 and ARNTL/BMAL1 or ARNTL2/BMAL2, form the positive limb of the feedback loop, act in the form of a heterodimer, and activate the transcription of core clock genes and clock-controlled genes (involved in key metabolic processes), harboring E-box elements (5’-CACGTG-3’) within their promoters. The core clock genes PER1/2/3 and CRY1/2, which are transcriptional repressors, form the negative limb of the feedback loop and interact with the CLOCK|NPAS2-ARNTL/BMAL1|ARNTL2/BMAL2 heterodimer inhibiting its activity and thereby negatively regulating their own expression. This heterodimer also activates nuclear receptors NR1D1/2 and RORA/B/G, which form a second feedback loop and which activate and repress ARNTL/BMAL1 transcription, respectively. ARNTL/BMAL1 positively regulates myogenesis and negatively regulates adipogenesis via the transcriptional control of the genes of the canonical Wnt signaling pathway. Plays a role in normal pancreatic beta-cell function; regulates glucose-stimulated insulin secretion via the regulation of antioxidant genes NFE2L2/NRF2 and its targets SESN2, PRDX3, CCLC, and CCLM. Negatively regulates the mTORC1 signaling pathway; regulates the expression of MTOR and DEPTOR. Controls diurnal oscillations of Ly6C inflammatory monocytes; rhythmic recruitment of the PRC2 complex imparts diurnal variation to chemokine expression that is necessary to sustain Ly6C monocyte rhythms. Regulates the expression of HSD3B2, STAR, PTGS2, CYP11A1, CYP19A1, and LHCGR in the ovary and also the genes involved in hair growth. Plays an important role in adult hippocampal neurogenesis by regulating the timely entry of neural stem/progenitor cells (NSPCs) into the cell cycle and the number of cell divisions that take place prior to cell-cycle exit. Regulates the circadian expression of CIART and KLF11. The CLOCK-ARNTL/BMAL1 heterodimer regulates the circadian expression of SERPINE1/PAI1, VWF, B3, CCRN4L/NOC, NAMPT, DBP, MYOD1, PPARGC1A, PPARGC1B, SIRT1, GYS2, F7, NGFR, GNRHR, BHLHE40/DEC1, ATF4, MTA1, KLF10, and also genes implicated in glucose and lipid metabolism. Promotes rhythmic chromatin opening, regulating the DNA accessibility of other transcription factors. The NPAS2-ARNTL/BMAL1 heterodimer positively regulates the expression of MAOA, F7, and LDHA and modulates the circadian rhythm of daytime contrast sensitivity by regulating the rhythmic expression of adenylate cyclase type 1 (ADCY1) in the retina. The preferred binding motif for the CLOCK-ARNTL/BMAL1 heterodimer is 5’-CACGTGA-3’, which contains a flanking Ala residue in addition to the canonical 6-nucleotide E-box sequence (PubMed23229515). CLOCK specifically binds to the half-site 5’-CAC-3’, while ARNTL binds to the half-site 5’-GTGA-3’ (PubMed23229515). The CLOCK-ARNTL/BMAL1 heterodimer also recognizes the noncanonical E-box motifs 5’-AACGTGA-3’ and 5’-CATGTGA-3’ (PubMed23229515). Essential for the rhythmic interaction of CLOCK with ASS1 and plays a critical role in positively regulating CLOCK-mediated acetylation of ASS1 (PubMed28985504). Plays a role in protecting against lethal sepsis by limiting the expression of immune checkpoint protein CD274 in macrophages in a PKM2-dependent manner (by similarity). Regulates the diurnal rhythms of skeletal muscle metabolism via transcriptional activation of genes promoting triglyceride synthesis (DGAT2) and metabolic efficiency (COQ10B) (by similarity). {ECO0000250|UniProtKBQ9WTL8, ECO0000269|PubMed11441146, ECO0000269|PubMed12738229, ECO0000269|PubMed18587630, ECO0000269|PubMed23785138, ECO0000269|PubMed23955654, ECO0000269|PubMed24005054, ECO0000269|PubMed28985504}.

C4a: Human Uniprot function (Human C4A): Nonenzymatic component of C3 and C5 convertases and thus essential for the propagation of the classical complement pathway. Covalently binds to immunoglobulins and immune complexes and enhances the solubilization of immune aggregates and the clearance of IC through CR1 on erythrocytes. C4A isotype is responsible for effective binding to form amide bonds with immune aggregates or protein antigens, while C4B isotype catalyzes the transacylation of the thioester carbonyl group to form ester bonds with carbohydrate antigens. Derived from proteolytic degradation of complement C4, C4a anaphylatoxin is a mediator of local inflammatory process. It induces the contraction of smooth muscle, increases vascular permeability, and causes histamine release from mast cells and basophilic leukocytes.

LOC103689965/C4a: Human Uniprot function (Human C4A): Nonenzymatic component of C3 and C5 convertases and thus essential for the propagation of the classical complement pathway. Covalently binds to immunoglobulins and immune complexes and enhances the solubilization of immune aggregates and the clearance of IC through CR1 on erythrocytes. C4A isotype is responsible for effective binding to form amide bonds with immune aggregates or protein antigens, while C4B isotype catalyzes the transacylation of the thioester carbonyl group to form ester bonds with carbohydrate antigens. Derived from proteolytic degradation of complement C4, C4a anaphylatoxin is a mediator of local inflammatory process. It induces the contraction of smooth muscle, increases vascular permeability and causes histamine release from mast cells and basophilic leukocytes.

No liver genes in male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive upregulated genes with a calculated BMD were G0s2 (G0/G1switch 2), Trib3 (tribbles pseudokinase 3), Akr7a3 (aldo-keto reductase family 7 member A3), Nqo1 (NAD(P)H quinone dehydrogenase 1), and Ephx1 (epoxide hydrolase 1) with BMDs (BMD_L_s) of 3.451 (1.074), 16.895 (6.465), 19.850 (12.797), 24.112 (16.415), and 24.878 (15.487) mg/kg, respectively. The most sensitive genes exhibiting a decrease in expression were Zfp354a (zinc finger protein 354A), Tsku (tsukushi, small leucine rich proteoglycan), Egr1 (early growth response 1), C7 (complement C7), and Loc100911558/Spink1l (serine peptidase inhibitor, Kazal type 1-like) with BMDs (BMD_L_s) of 3.267 (1.720), 6.126 (1.466), 8.263 (1.517), 13.843 (5.329), and 26.630 (12.428) mg/kg, respectively.

In female rats, the most sensitive upregulated liver genes with a calculated BMD were Kif22 (kinesin family member 22), Anln (anillin, actin binding protein), Anlnl1 (anillin, actin binding protein-like 1), Asns (asparagine synthetase [glutamine-hydrolyzing]), and Nr1d2 (nuclear receptor subfamily 1, group D, member 2) with BMDs (BMD_L_s) of 0.962 (0.282), 3.325 (1.105), 3.325 (1.105), 6.056 (2.744), and 9.460 (2.213) mg/kg, respectively. The most sensitive genes exhibiting a decrease in expression were Car3 (carbonic anhydrase 3), Aass (aminoadipate-semialdehyde synthase), A2m (alpha-2-macroglobulin), Loc100911545/A2m (alpha-2-macroglobulin), and Sez6 (seizure-related 6 homolog) with BMDs (BMD_L_s) of 3.449 (2.131), 5.811 (2.605), 8.459 (1.870), 8.459 (1.870), and 10.639 (3.960) mg/kg, respectively.

The most sensitive kidney gene in male rats, exhibiting a decrease in expression, was Nefh (neurofilament heavy chain) with an estimated BMD median value <0.050 mg/kg. The most sensitive downregulated genes with a calculated BMD were Top2a (DNA topoisomerase II alpha), Ect2 (epithelial cell transforming 2), Hmgcs2 (3-hydroxy-3-methylglutaryl-CoA synthase 2), Nfil3 (nuclear factor, interleukin 3 regulated), Mt1 (metallothionein 1), and Cyp2c11 (cytochrome P450, subfamily 2, polypeptide 11) with BMDs (BMD_L_s) of 12.334 (3.464), 31.232 (16.473), 106.351 (59.870), 121.321 (82.552), 168.588 (103.554), and 216.743 (139.563) mg/kg, respectively. The most sensitive upregulated genes with a calculated BMD were Nqo1 (NAD(P)H quinone dehydrogenase 1), Cyp1a1 (cytochrome P450, family 1, subfamily a, polypeptide 1), and Rassf1 (Ras association domain family member 1) with BMDs (BMD_L_s) of 40.551 (21.583), 49.045 (39.236), and 903.848 (608.514) mg/kg, respectively.

None of the top 10 most sensitive kidney genes in female rats had estimated BMD median values <0.050 mg/kg. The most sensitive upregulated genes with a calculated BMD were Cyp1a1 (cytochrome P450, family 1, subfamily a, polypeptide 1), Gstp1 (glutathione S-transferase pi 1), Cyp26b1 (cytochrome P450, family 26, subfamily b, polypeptide 1), and Nqo1 (NAD(P)H quinone dehydrogenase 1) with BMDs (BMD_L_s) of 12.886 (9.131), 14.763 (9.430), 18.187 (10.018), and 25.681 (7.739) mg/kg, respectively. The most sensitive genes exhibiting a decrease in expression were Vwf (von Willebrand factor), Abcb1b (ATP-binding cassette, subfamily B (MDR/TAP), member 1B), Npas2 (neuronal PAS domain protein 2), Arntl (aryl hydrocarbon receptor nuclear translocator-like), C4a (complement C4A), and Loc103689965/C4a (complement C4A) with BMDs (BMD_L_s) of 19.676 (4.116), 20.794 (8.254), 21.088 (11.331), 22.913 (11.412), 24.209 (8.100), and 24.209 (8.100) mg/kg, respectively.