# Background

2,3-Benzofluorene (2,3-BF) (CASRN: 243-17-4, U.S. Environmental Protection Agency [EPA] Chemical Dashboard: DTXSID1022477,^1^ PubChem CID: 9201,^2^ European Committee Number: 205-952-2^3^) is a member of the polycyclic aromatic hydrocarbon class of compounds that are associated with numerous toxicological effects.^4^ There is widespread human exposure to this class of compounds.^4^ No exposure information was available for 2,3-BF. A review of the existing literature failed to identify any in vivo toxicological information on 2,3-BF, and according to the EPA Chemical Dashboard, no quantitative risk assessment values or quantitative hazard values exist for this test article.^5^ Consistent with the absence of data on 2,3-BF, it is listed in Group 3 (not classifiable as to its carcinogenicity to humans) in the International Agency for Research on Cancer (IARC) Carcinogenicity Classification.^6^ Publicly available information on 2,3-BF can be found in PubChem^2^ and the EPA Chemical Dashboard.^1^

Recent studies have demonstrated that short-term in vivo gavage studies coupled with transcriptomics on select target organs can be used to estimate a biological potency that provides a reasonable approximation of toxicological potency in long-term guideline toxicological assessments.^7^ To estimate biological potency and gain insight into the nature of biological changes elicited by 2,3-BF, the National Institute of Environmental Health Sciences performed a short-term in vivo biological potency study of male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. The results of this study are presented in this report.