# Acknowledgments

This work was supported by the Intramural Research Program (ES103316, ES103318, ES103319, and ES102505) at the National Institute of Environmental Health Sciences (NIEHS), National Institutes of Health and performed for NIEHS under contracts HHSN273201800006C, HHSN273201700005C, HHSN273201700001C, GS00Q14OADU417 (Order No. HHSN273201600015U), HHSN273201500006C, HHSN273201400020C, HHSN273201400022C, HHSN273201300004C, and HHSN316201200054W.