# Appendix B Animal Identifiers

Table B-1 Animal Numbers and FASTQ Data File Names

Animal Number | Sex | Group | Dose (mg/kg) | Survived to Study Termination | Tissue | FASTQ File ID
431 | Male | Vehicle control | 0 | Yes | Kidney | Plate7-431
431 | Male | Vehicle control | 0 | Yes | Liver | Plate3-431
432 | Male | Vehicle control | 0 | Yes | Kidney | Plate8-432^a^
432 | Male | Vehicle control | 0 | Yes | Liver | Plate3-432
433 | Male | Vehicle control | 0 | Yes | Kidney | Plate7-433
433 | Male | Vehicle control | 0 | Yes | Liver | Plate4-433
434 | Male | Vehicle control | 0 | Yes | Kidney | Plate8-434^a^
434 | Male | Vehicle control | 0 | Yes | Liver | Plate3-434
435 | Male | Vehicle control | 0 | Yes | Kidney | Plate8-435^a^
435 | Male | Vehicle control | 0 | Yes | Liver | Plate3-435
436 | Male | Vehicle control | 0 | Yes | Kidney | Plate8-436^a^
436 | Male | Vehicle control | 0 | Yes | Liver | Plate3-436
437 | Male | Vehicle control | 0 | Yes | Kidney | Plate7-437
437 | Male | Vehicle control | 0 | Yes | Liver | Plate3-437
438 | Male | Vehicle control | 0 | Yes | Kidney | Plate7-438
438 | Male | Vehicle control | 0 | Yes | Liver | Plate3-438
439 | Male | Vehicle control | 0 | Yes | Kidney | Plate7-439
439 | Male | Vehicle control | 0 | Yes | Liver | Plate3-439
440 | Male | Vehicle control | 0 | Yes | Kidney | Plate7-440
440 | Male | Vehicle control | 0 | Yes | Liver | Plate3-440
441 | Female | Vehicle control | 0 | Yes | Kidney | Plate7-441
441 | Female | Vehicle control | 0 | Yes | Liver | Plate3-441
442 | Female | Vehicle control | 0 | Yes | Kidney | Plate7-442
442 | Female | Vehicle control | 0 | Yes | Liver | Plate3-442
443 | Female | Vehicle control | 0 | Yes | Kidney | Plate7-443
443 | Female | Vehicle control | 0 | Yes | Liver | Plate4-443
444 | Female | Vehicle control | 0 | Yes | Kidney | Plate7-444
444 | Female | Vehicle control | 0 | Yes | Liver | Plate3-444
445 | Female | Vehicle control | 0 | Yes | Kidney | Plate7-445
445 | Female | Vehicle control | 0 | Yes | Liver | Plate4-445
446 | Female | Vehicle control | 0 | Yes | Kidney | Plate7-446
446 | Female | Vehicle control | 0 | Yes | Liver | Plate4-446
447 | Female | Vehicle control | 0 | Yes | Kidney | Plate7-447
447 | Female | Vehicle control | 0 | Yes | Liver | Plate4-447
448 | Female | Vehicle control | 0 | Yes | Kidney | Plate7-448
448 | Female | Vehicle control | 0 | Yes | Liver | Plate3-448
449 | Female | Vehicle control | 0 | Yes | Kidney | Plate8-449^a^
449 | Female | Vehicle control | 0 | Yes | Liver | Plate3-449
450 | Female | Vehicle control | 0 | Yes | Kidney | Plate8-450^a^
450 | Female | Vehicle control | 0 | Yes | Liver | Plate3-450
451 | Male | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-451
451 | Male | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate3-451
452 | Male | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate8-452^a^
452 | Male | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate3-452
453 | Male | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-453
453 | Male | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate4-453
454 | Male | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-454
454 | Male | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate3-454
455 | Male | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-455
455 | Male | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate4-455
456 | Female | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-456
456 | Female | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate3-456
457 | Female | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-457
457 | Female | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate3-457
458 | Female | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-458
458 | Female | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate3-458
459 | Female | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-459
459 | Female | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate3-459
460 | Female | 2,3-Benzofluorene | 0.15 | Yes | Kidney | Plate7-460
460 | Female | 2,3-Benzofluorene | 0.15 | Yes | Liver | Plate3-460
461 | Male | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-461
461 | Male | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-461
462 | Male | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-462
462 | Male | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-462
463 | Male | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-463
463 | Male | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-463
464 | Male | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-464
464 | Male | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-464
465 | Male | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-465
465 | Male | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-465
466 | Female | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-466
466 | Female | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-466
467 | Female | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate8-467^a^
467 | Female | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-467
468 | Female | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-468
468 | Female | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-468
469 | Female | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-469
469 | Female | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-469
470 | Female | 2,3-Benzofluorene | 0.5 | Yes | Kidney | Plate7-470
470 | Female | 2,3-Benzofluorene | 0.5 | Yes | Liver | Plate3-470
471 | Male | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-471
471 | Male | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate4-471
472 | Male | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-472
472 | Male | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate3-472
473 | Male | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-473
473 | Male | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate3-473
474 | Male | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate8-474^a^
474 | Male | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate3-474
475 | Male | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-475
475 | Male | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate3-475
476 | Female | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-476
476 | Female | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate3-476
477 | Female | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-477
477 | Female | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate3-477
478 | Female | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-478
478 | Female | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate3-478
479 | Female | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-479
479 | Female | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate4-479
480 | Female | 2,3-Benzofluorene | 1.4 | Yes | Kidney | Plate7-480
480 | Female | 2,3-Benzofluorene | 1.4 | Yes | Liver | Plate3-480
481 | Male | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-481
481 | Male | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-481
482 | Male | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-482
482 | Male | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-482
483 | Male | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-483
483 | Male | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-483
484 | Male | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-484
484 | Male | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-484
485 | Male | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-485
485 | Male | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-485
486 | Female | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-486
486 | Female | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-486
487 | Female | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-487
487 | Female | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-487
488 | Female | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-488
488 | Female | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-488
489 | Female | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate7-489
489 | Female | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate4-489
490 | Female | 2,3-Benzofluorene | 4.0 | Yes | Kidney | Plate8-490^a^
490 | Female | 2,3-Benzofluorene | 4.0 | Yes | Liver | Plate3-490
491 | Male | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate7-491
491 | Male | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate4-491
492 | Male | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate7-492
492 | Male | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate3-492
493 | Male | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate8-493^a^
493 | Male | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate3-493
494 | Male | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate8-494^a^
494 | Male | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate4-494
495 | Male | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate7-495
495 | Male | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate3-495
496 | Female | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate7-496
496 | Female | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate3-496
497 | Female | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate7-497
497 | Female | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate3-497
498 | Female | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate7-498
498 | Female | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate3-498
499 | Female | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate8-499^a^
499 | Female | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate4-499
500 | Female | 2,3-Benzofluorene | 12.0 | Yes | Kidney | Plate8-500^a^
500 | Female | 2,3-Benzofluorene | 12.0 | Yes | Liver | Plate3-500
501 | Male | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-501
501 | Male | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate3-501
502 | Male | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-502
502 | Male | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate4-502
503 | Male | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-503
503 | Male | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate3-503
504 | Male | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-504
504 | Male | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate4-504
505 | Male | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-505
505 | Male | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate3-505
506 | Female | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate8-506
506 | Female | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate3-506
507 | Female | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-507
507 | Female | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate3-507
508 | Female | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-508
508 | Female | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate3-508
509 | Female | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-509
509 | Female | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate3-509
510 | Female | 2,3-Benzofluorene | 37.0 | Yes | Kidney | Plate7-510
510 | Female | 2,3-Benzofluorene | 37.0 | Yes | Liver | Plate3-510
511 | Male | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate7-511
511 | Male | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-511
512 | Male | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate8-512^a^
512 | Male | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-512
513 | Male | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate8-513^a^
513 | Male | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-513
514 | Male | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate7-514
514 | Male | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-514
515 | Male | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate7-515
515 | Male | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-515
516 | Female | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate8-516^a^
516 | Female | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-516
517 | Female | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate8-517^a^
517 | Female | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-517
518 | Female | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate7-518
518 | Female | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-518
519 | Female | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate7-519
519 | Female | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-519
520 | Female | 2,3-Benzofluorene | 111.0 | Yes | Kidney | Plate7-520
520 | Female | 2,3-Benzofluorene | 111.0 | Yes | Liver | Plate3-520
521 | Male | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-521
521 | Male | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-521
522 | Male | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-522
522 | Male | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-522
523 | Male | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-523
523 | Male | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-523
524 | Male | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-524
524 | Male | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-524
525 | Male | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-525
525 | Male | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate4-525
526 | Female | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-526
526 | Female | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-526
527 | Female | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-527
527 | Female | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-527
528 | Female | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-528
528 | Female | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-528
529 | Female | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-529
529 | Female | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-529
530 | Female | 2,3-Benzofluorene | 333.0 | Yes | Kidney | Plate7-530
530 | Female | 2,3-Benzofluorene | 333.0 | Yes | Liver | Plate3-530
531 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-531
531 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate4-531
532 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-532
532 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate4-532
533 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-533
533 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate3-533
534 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-534
534 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate3-534
535 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-535
535 | Male | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate3-535
536 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-536
536 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate3-536
537 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate8-537^a^
537 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate3-537
538 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-538
538 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate4-538
539 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-539
539 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate3-539
540 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Kidney | Plate7-540
540 | Female | 2,3-Benzofluorene | 1,000.0 | Yes | Liver | Plate4-540

^a^ Removed due to plate/batch effect.