# Appendix A Internal Dose Assessment

## A.1 Quantitation of 2,3-Benzofluorene in Plasma

Quantification of 2,3-benzofluorene (2,3-BF) in plasma samples was completed by MRIGlobal (Kansas City, MO). A gas chromatography mass spectroscopy (GC/MS) method was developed to determine 2,3-BF concentrations in rat plasma. A six-point matrix calibration curve, in the range of 10–100 ng/mL, was prepared by adding 10 µL of an appropriate spiking solution of 2,3-BF in methanol to 100 µL of control matrix (adult male Sprague Dawley rat plasma). Quality control (QC) samples were prepared similarly at a target concentration of 52.5 ng/mL in plasma. Blanks and study samples were prepared like standards, except 10 µL of methanol was used in place of spiking solution. Each sample was extracted with 1,000 µL of hexane, vortex-mixed for 60 seconds, and then centrifuged at approximately 842 × g for 2 minutes. A 900 µL aliquot of the supernatant was removed, evaporatively dried at 25°C, and then reconstituted and mixed with 100 µL of extraction solvent.

All samples were analyzed using an Agilent 6890N GC with an Agilent 5975 MS (Santa Clara, CA). A Restek Rxi 5Sil MS column (30 m × 0.25 mm, 0.25 µm) was used with a helium carrier gas. A flow rate of 1 mL/min was run with a temperature program starting at 50°C for 3 minutes, a linear ramp at 25°C/min to 150°C, then a linear ramp at 10°C/min to 330°C, and then held at 330°C for 10 minutes. Electron impact ionization was used with an ionization voltage of 70 eV and a source temperature of 200°C. Single ion monitoring was used at m/z 216 and 215 (2,3-BF), and m/z 166 and 169 (internal standard).

A linear regression with 1/X weighting was used to relate peak area ratio of matrix calibration standards to their analyte concentration. Calibration curves were linear (r > 0.99). The limit of detection (LOD; 1.8 ng/mL) was estimated as three times the standard deviation of the lower limit of quantitation (LOQ; 10.0 ng/mL), expressed as concentration. For QC samples, the accuracy measured as percent relative error was within ±28.4% of the nominal concentration with relative standard deviations ≤24.4%. The concentrations (ng/mL) of 2,3-BF in study samples were calculated using peak areas and the regression equation. All values above LOD were reported.