# Summary

1,1,2,2-Tetrahydroperfluoro-1-dodecanol (10:2 fluorotelomer alcohol) is a member of the per- and polyfluoroalkyl class of compounds to which humans are widely exposed. A review of the literature did not identify toxicological data for estimating the potential adverse health effects of 1,1,2,2-tetrahydroperfluoro-1-dodecanol. This study used a transcriptomic approach and standard toxicological endpoints to estimate the in vivo biological potency of 1,1,2,2-tetrahydroperfluoro-1-dodecanol.

A subset of standard toxicological endpoints (cholesterol concentration in male rats; neutrophil count in female rats) exhibited benchmark dose (BMD) values much lower than would be expected given the endpoint-specific no-observed-effect level and lowest-observed-effect level values. Expert review of the data suggests that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and were likely an anomalous product of the BMD modeling approach.

Taking this into account, the most sensitive apical endpoint in male rats was an increase in relative liver weight with an estimated BMD and benchmark dose lower confidence limit (BMD_L_) of 8.087 (4.336) mg/kg. An increase in absolute liver weight and a decrease in reticulocyte count were the next most sensitive apical endpoint changes observed in male rats with BMDs (BMD_L_s) of 21.893 (10.337) and 54.227 (30.205) mg/kg, respectively. In female rats, the most sensitive apical endpoint was an increase in relative liver weight with a BMD (BMD_L_) of 5.372 (2.294) mg/kg. The next most sensitive apical endpoints observed were an increase in alkaline phosphatase activity and an increase in absolute liver weight with BMDs (BMD_L_s) of 6.461 (6.003) and 8.801 (3.465) mg/kg, respectively.

Gene set-level transcriptional changes in the liver following 1,1,2,2-tetrahydroperfluoro-1-dodecanol exposure were estimated to occur at a BMD (BMD_L_) as low as 5.235 (2.666) mg/kg in male rats, corresponding to nucleotide biosynthetic process (GO:0009165), and as low as 5.355 (3.108) mg/kg in female rats, corresponding to internal protein amino acid acetylation (GO:0006475). The most sensitive liver gene for which a reliable BMD could be determined was Pck1, with a BMD (BMD_L_) of 1.149 (0.548) mg/kg, in male rats, and Abcc3, with a BMD (BMD_L_) of 5.019 (2.945) mg/kg, in female rats.

Gene set-level transcriptional changes in the kidney were estimated to occur at a BMD (BMD_L_) as low as 144.319 (57.694) mg/kg in male rats, corresponding to regulation of myeloid leukocyte mediated immunity (GO:0002886), and as low as 57.313 (37.882) mg/kg in female rats, corresponding to innate immune response (GO:0045087). The most sensitive kidney gene in male rats for which a reliable BMD could be determined was Ugt2b7 with a BMD (BMD_L_) of 4.139 (1.398) mg/kg. In female rats, one kidney gene exhibited changes in expression at dose levels below which a reliable estimate of potency could be achieved (<0.023 mg/kg). The most sensitive gene in female rats for which a reliable BMD could be determined was Ckap2 with a BMD (BMD_L_) of 2.608 (0.997) mg/kg.

Under the conditions of this short-duration transcriptomic study in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats, the most sensitive point of departure with a reliable estimate in male rats was a transcriptional change in a gene, Pck1, with a BMD (BMD_L_) of 1.149 (0.548) mg/kg. Gene set transcriptional changes and apical endpoints provided potency estimates slightly higher than Pck1. In female rats, the most sensitive point of departure with a reliable estimate was a transcriptional change in a gene, Ckap2, with a BMD (BMD_L_) of 2.608 (0.997) mg/kg. Gene set transcriptional changes and apical endpoints provided potency estimates slightly higher than Ckap2.