# Results

## Animal Condition, Body Weights, and Organ Weights

All male and female rats administered 1,1,2,2-tetrahydroperfluoro-1-dodecanol (10:2 fluorotelomer alcohol) survived to the end of the study with no adverse clinical observations noted (Appendix F). There were no significant changes in terminal body weight for male or female rats administered 1,1,2,2-tetrahydroperfluoro-1-dodecanol (Table 2).

Table 2 Summary of Body Weights of Male and Female Rats Administered 1,1,2,2-Tetrahydroperfluoro-1-dodecanol for Five Days

Study Day^a,b^ | 0 mg/kg | 0.07 mg/kg | 0.2 mg/kg | 0.7 mg/kg | 2 mg/kg | 6 mg/kg | 18 mg/kg | 55 mg/kg | 160 mg/kg | 475 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
0 | 316.7 ± 6.2 | 311.2 ± 4.6 | 317.9 ± 5.8 | 318.5 ± 5.8 | 312.4 ± 8.8 | 317.0 ± 6.3 | 313.0 ± 9.4 | 319.1 ± 8.3 | 317.2 ± 3.8 | 317.5 ± 5.2 | ND | ND
5 | 333.9 ± 7.5 | 326.2 ± 9.9 | 333.0 ± 7.0 | 336.4 ± 7.3 | 328.0 ± 9.0 | 334.3 ± 8.8 | 325.3 ± 8.8 | 338.2 ± 9.5 | 334.6 ± 4.7 | 333.8 ± 7.4 | ND | ND
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
0 | 214.3 ± 2.8 | 216.0 ± 1.7 | 216.0 ± 1.8 | 216.6 ± 2.9 | 210.3 ± 4.2 | 218.4 ± 2.2 | 216.1 ± 4.9 | 217.6 ± 3.5 | 216.4 ± 3.9 | 217.6 ± 3.9 | ND | ND
5 | 222.6 ± 3.1 | 223.6 ± 1.6 | 222.3 ± 1.9 | 223.4 ± 3.2 | 221.0 ± 5.1 | 227.8 ± 3.1 | 224.4 ± 6.2 | 226.9 ± 2.5 | 225.6 ± 2.5 | 226.2 ± 4.3 | ND | ND

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; ND = not determined.

^a^ Data are displayed as mean ± standard error of the mean; body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

In male rats at study termination, a significant increase in absolute and relative liver weights occurred in dose groups ≥55 and ≥18 mg/kg body weight (mg/kg), respectively; both endpoints had positive trends (Table 3). The benchmark doses (benchmark dose lower confidence limits)—BMDs (BMD_L_s)—for increased absolute and relative liver weights were 21.893 (10.337) and 8.087 (4.336) mg/kg, respectively. The BMDs for all organ weights were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the estimated BMD values). Significant trend and pairwise comparisons were not observed in absolute or relative heart, right kidney, or left kidney weights (Appendix F).

Table 3 Summary of Select Organ Weights of Male and Female Rats Administered 1,1,2,2-Tetrahydroperfluoro-1-dodecanol for Five Days

Endpoint^a,b,c^ | 0 mg/kg | 0.07 mg/kg | 0.2 mg/kg | 0.7 mg/kg | 2 mg/kg | 6 mg/kg | 18 mg/kg | 55 mg/kg | 160 mg/kg | 475 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Terminal Body Wt. (g) | 333.9 ± 7.5 | 326.2 ± 9.9 | 333.0 ± 7.0 | 336.4 ± 7.3 | 328.0 ± 9.0 | 334.3 ± 8.8 | 325.3 ± 8.8 | 338.2 ± 9.5 | 334.6 ± 4.7 | 333.8 ± 7.4 | ND | ND
Liver
Absolute (g) | 12.52 ± 0.44** | 11.81 ± 0.75 | 12.57 ± 0.54 | 12.61 ± 0.55 | 12.05 ± 0.29 | 13.14 ± 0.52 | 13.48 ± 0.63 | 14.30 ± 0.40* | 15.69 ± 0.54** | 15.34 ± 0.53** | 21.893 | 10.337
Relative (mg/g)^d^ | 37.41 ± 0.66** | 36.07 ± 1.30 | 37.70 ± 0.96 | 37.42 ± 0.94 | 36.77 ± 0.42 | 39.29 ± 0.88 | 41.44 ± 1.47** | 42.31 ± 0.83** | 46.85 ± 1.16** | 45.93 ± 0.91** | 8.087 | 4.336
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Terminal Body Wt. (g) | 222.6 ± 3.1 | 223.6 ± 1.6 | 222.3 ± 1.9 | 223.4 ± 3.2 | 221.0 ± 5.1 | 227.8 ± 3.1 | 224.4 ± 6.2 | 226.9 ± 2.5 | 225.6 ± 2.5 | 226.2 ± 4.3 | ND | ND
Right Kidney
Absolute (g) | 0.66 ± 0.01** | 0.70 ± 0.01 | 0.68 ± 0.03 | 0.67 ± 0.02 | 0.68 ± 0.02 | 0.67 ± 0.01 | 0.70 ± 0.03 | 0.71 ± 0.01* | 0.72 ± 0.03* | 0.76 ± 0.02** | 72.145 | 18.001
Relative (mg/g) | 2.97 ± 0.06** | 3.15 ± 0.03 | 3.04 ± 0.10 | 3.00 ± 0.04 | 3.08 ± 0.09 | 2.94 ± 0.04 | 3.11 ± 0.07 | 3.15 ± 0.06 | 3.21 ± 0.10* | 3.34 ± 0.04** | NVM | NVM
Left Kidney
Absolute (g) | 0.64 ± 0.02** | 0.69 ± 0.02 | 0.66 ± 0.03 | 0.67 ± 0.01 | 0.68 ± 0.01 | 0.67 ± 0.01 | 0.69 ± 0.02 | 0.70 ± 0.01* | 0.72 ± 0.03** | 0.72 ± 0.02** | 56.634 | 10.508
Relative (mg/g) | 2.89 ± 0.06** | 3.10 ± 0.10 | 2.97 ± 0.10 | 3.01 ± 0.04 | 3.06 ± 0.07 | 2.92 ± 0.05 | 3.07 ± 0.07 | 3.08 ± 0.04 | 3.21 ± 0.09** | 3.17 ± 0.05** | 85.629 | 17.286
Liver
Absolute (g) | 8.16 ± 0.24** | 8.31 ± 0.30 | 7.69 ± 0.31 | 8.16 ± 0.21 | 8.12 ± 0.20 | 9.10 ± 0.49* | 9.07 ± 0.39* | 9.86 ± 0.41** | 9.92 ± 0.48** | 10.02 ± 0.34** | 8.801 | 3.465
Relative (mg/g) | 36.65 ± 0.85** | 37.16 ± 1.11 | 34.56 ± 1.12 | 36.52 ± 0.61 | 36.73 ± 0.38 | 39.90 ± 1.78 | 40.46 ± 1.61* | 43.48 ± 1.96** | 43.90 ± 1.75** | 44.27 ± 0.82** | 5.372 | 2.294

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; ND = not determined; NVM = nonviable model.

^a^ Descriptions of organ weight endpoints and changes are provided in Appendix E.

^b^ Data are displayed as mean ± standard error of the mean.

^c^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ Relative organ weights (organ weight-to-body weight ratios) are given as mg organ weight/g body weight.

In female rats at study termination, a significant increase in absolute and relative liver weights occurred in dose groups ≥6 and ≥18 mg/kg, respectively, with BMDs (BMD_L_s) of 8.801 (3.465) and 5.372 (2.294) mg/kg, respectively (Table 3). Absolute right and left kidney weights were significantly increased in the ≥55 mg/kg groups with BMDs (BMD_L_s) of 72.145 (18.001) and 56.634 (10.508) mg/kg, respectively. Relative right and left kidney weights were significantly increased in the ≥160 mg/kg female rats. The BMD (BMD_L_) for increased relative left kidney weight was 85.629 (17.286) mg/kg; a BMD (BMD_L_) was not determined for increased relative right kidney weight because no viable model was available. The organ weights mentioned above all exhibited positive trends. Significant trend and pairwise comparisons were not observed in absolute or relative heart weights (Appendix F).

## Clinical Pathology

In male rats, alkaline phosphatase (ALP) activity had a positive trend with significant pairwise comparisons in the 160 and 475 mg/kg groups; a BMD (BMD_L_) was not determined because no viable model was available (Table 4). In female rats, aspartate aminotransferase (AST) activity had a positive trend with a significant pairwise comparison in the 55 mg/kg group; a BMD (BMD_L_) was not determined because no viable model was available. ALP activity in female rats had a positive trend and a significant pairwise comparison in the 475 mg/kg group with a BMD (BMD_L_) of 6.461 (6.003) mg/kg. In male rats, cholesterol concentration had significant trend and pairwise comparisons. Although a BMD was estimated for cholesterol concentration, its value was much lower (approximately 10- to 25-fold) than would be expected given the endpoint-specific no-observed-effect level (NOEL) and lowest-observed-effect level (LOEL) values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach. The BMDs for all clinical pathology endpoints were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the estimated BMD values).

Table 4 Summary of Select Clinical Chemistry Data for Male and Female Rats Administered 1,1,2,2-Tetrahydroperfluoro-1-dodecanol for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.07 mg/kg | 0.2 mg/kg | 0.7 mg/kg | 2 mg/kg | 6 mg/kg | 18 mg/kg | 55 mg/kg | 160 mg/kg | 475 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 9^c^ | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 4^c^ | NA | NA
Cholesterol (mg/dL) | 118.1 ± 3.7* | 117.0 ± 5.1 | 110.0 ± 2.8 | 114.8 ± 2.5 | 113.8 ± 2.8 | 118.6 ± 3.7 | 104.6 ± 6.5 | 115.6 ± 5.5 | 107.6 ± 5.7 | 100.8 ± 1.4* | 17.539^d^ | 14.31^d^
Alkaline Phosphatase (IU/L) | 267.8 ± 8.0** | 253.4 ± 24.6 | 252.8 ± 8.7 | 277.0 ± 18.2 | 269.5 ± 8.2^e^ | 263.8 ± 10.7 | 285.0 ± 4.5 | 284.8 ± 20.5 | 326.0 ± 23.7* | 351.0 ± 12.8** | NVM | NVM
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Alkaline Phosphatase (IU/L) | 200.1 ± 9.7** | 195.6 ± 10.5 | 176.8 ± 8.3 | 191.4 ± 13.6 | 207.0 ± 17.8 | 210.2 ± 9.6 | 235.4 ± 3.8 | 234.2 ± 6.4 | 235.6 ± 14.2 | 247.8 ± 8.0** | 6.461 | 6.003
Aspartate Aminotransferase (U/L) | 78.50 ± 2.13* | 81.40 ± 4.21 | 79.40 ± 2.25 | 84.00 ± 5.55 | 80.80 ± 1.66 | 75.80 ± 1.53 | 77.40 ± 1.66 | 92.80 ± 3.29* | 89.20 ± 3.15 | 82.60 ± 0.60 | NVM | NVM

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; NVM = nonviable model.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample in the indicated dose groups was not received.

^d^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

^e^ One value for alkaline phosphatase in the 2 mg/kg group was excluded due to analysis concerns.

In male rats, the reticulocyte count exhibited a negative trend with a significant pairwise comparison at the 475 mg/kg group; the BMD (BMD_L_) was 54.227 (30.205) mg/kg (Table 5). In female rats, platelet count had a negative trend and significant pairwise comparisons in the ≥160 mg/kg groups with a BMD (BMD_L_) of 16.335 (9.571) mg/kg. In addition, the monocyte and large unstained cell counts in the female rats had a positive trend and significant pairwise comparisons in dose groups ≥160 mg/kg with BMDs (BMD_L_s) of 20.731 (4.642) and 58.894 (25.959) mg/kg, respectively. The neutrophil count in female rats had significant trend and pairwise comparisons. Although a BMD was estimated, its value was much lower (approximately 250- to 770-fold) than would be expected given the endpoint-specific NOEL and LOEL values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach.

Table 5 Summary of Select Hematology Data for Male and Female Rats Administered 1,1,2,2-Tetrahydroperfluoro-1-dodecanol for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.07 mg/kg | 0.2 mg/kg | 0.7 mg/kg | 2 mg/kg | 6 mg/kg | 18 mg/kg | 55 mg/kg | 160 mg/kg | 475 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 4^c^ | NA | NA
Reticulocytes (10^3^/μL) | 227.4 ± 9.7** | 226.4 ± 9.3 | 264.3 ± 16.1 | 258.4 ± 19.0 | 234.7 ± 15.1 | 241.2 ± 11.9 | 216.7 ± 17.7 | 210.6 ± 3.9 | 226.6 ± 24.3 | 174.5 ± 7.3* | 54.227 | 30.205
Female
n | 10 | 5 | 5 | 4^d^ | 4^d^ | 5 | 5 | 5 | 5 | 5 | NA | NA
Platelets (10^3^/μL) | 1,041 ± 37** | 1,067 ± 52 | 997 ± 34 | 971 ± 26 | 997 ± 19 | 966 ± 28 | 926 ± 31 | 1,011 ± 21 | 916 ± 34* | 823 ± 55** | 16.335 | 9.571
Neutrophils (10^3^/μL) | 0.42 ± 0.03** | 0.53 ± 0.03 | 0.62 ± 0.06 | 0.49 ± 0.03 | 0.53 ± 0.08 | 0.57 ± 0.09 | 0.53 ± 0.08 | 0.61 ± 0.05** | 0.60 ± 0.12* | 0.72 ± 0.11** | 0.071^e^ | 0.013^e^
Monocytes (10^3^/μL) | 0.18 ± 0.02** | 0.20 ± 0.03 | 0.22 ± 0.05 | 0.17 ± 0.02 | 0.19 ± 0.04 | 0.29 ± 0.04 | 0.24 ± 0.03 | 0.28 ± 0.04 | 0.38 ± 0.07** | 0.30 ± 0.09* | 20.731 | 4.642
Large Unstained Cells (10^3^/μL) | 0.04 ± 0.00** | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01* | 0.07 ± 0.02* | 58.894 | 25.959

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample in the indicated dose group was not received.

^d^ One sample from each of the indicated dose groups had a clot present and was not analyzed.

^e^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

In male rats, free thyroxine (fT4) concentration had a negative trend and a significant pairwise comparison in the 160 mg/kg group with a BMD (BMD_L_) of 142.469 (57.746) mg/kg (Table 6). Additionally, thyroid stimulating hormone (TSH) concentration had a positive trend and a significant pairwise comparison in the 475 mg/kg male rats with a BMD (BMD_L_) of 138.723 (20.376) mg/kg. In female rats, there were no thyroid hormone parameters that exhibited significant trend and pairwise comparisons (Appendix F).

Table 6 Summary of Select Hormone Data for Male Rats Administered 1,1,2,2-Tetrahydroperfluoro-1-dodecanol for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.07 mg/kg | 0.2 mg/kg | 0.7 mg/kg | 2 mg/kg | 6 mg/kg | 18 mg/kg | 55 mg/kg | 160 mg/kg | 475 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
n | 9^c^ | 4^c^ | 4^c^ | 4^c^ | 4^c^ | 4^c^ | 4^c^ | 5 | 5 | 5 | NA | NA
TSH (ng/mL) | 4.500 ± 0.667** | 3.275 ± 0.867 | 2.725 ± 0.602 | 4.050 ± 1.005 | 3.425 ± 0.807 | 5.400 ± 1.158 | 6.800 ± 1.529 | 12.480 ± 2.168 | 5.760 ± 0.865 | 11.560 ± 2.285* | 138.723 | 20.376
fT4 (ng/dL) | 7.260 ± 0.292* | 7.205 ± 0.237 | 6.785 ± 0.199 | 5.980 ± 0.367 | 6.840 ± 0.685 | 6.485 ± 0.583 | 6.980 ± 0.472 | 7.042 ± 0.249 | 5.604 ± 0.354* | 6.232 ± 0.531 | 142.469 | 57.746

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; TSH = thyroid stimulating hormone; fT4 = free thyroxine.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample in the indicated dose groups did not have sufficient specimen volume available for analysis.

## Internal Dose Assessment

For the 2 and 18 mg/kg groups, 1,1,2,2-tetrahydroperfluoro-1-dodecanol plasma concentrations were determined at 2 and 24 hours following the last dose administered on study day 4 to male and female rats. Average 1,1,2,2-tetrahydroperfluoro-1-dodecanol concentrations are given in Table 7. At 2 hours following administration, the average concentrations of 1,1,2,2-tetrahydroperfluoro-1-dodecanol in male and female rats in each dosed group were similar; as the administered dose increased from 2 to 18 mg/kg (a ninefold increase), there was a less-than-proportional increase (approximately four- to fivefold) in the average 1,1,2,2-tetrahydroperfluoro-1-dodecanol plasma concentration, suggesting changes in the absorption, distribution, metabolism, and excretion processes (e.g., lower absorption and/or induction of metabolism and clearance pathways) as the dose increased. At 24 hours postdose, the concentration decreased across each dosed group; in the 2 mg/kg group, the concentration was below the limit of quantitation (LOQ = 10 ng/mL) of the analytical method in female rats and close to the LOQ in male rats (average of 8 ng/mL), while in the 18 mg/kg group the concentration was approximately 5- and 12-fold lower in male and female rats, respectively. Half-lives estimated using the data from these two time points were similar between dosed groups and sexes (6.65 and 8.96 hours for the 2 and 18 mg/kg male rats, respectively, and 6.12 hours for the 18 mg/kg female rats); a value could not be estimated for the 2 mg/kg female rats due to concentrations falling below the LOQ at 24 hours.

Table 7 Summary of Plasma Concentration Data for Male and Female Rats Administered 1,1,2,2-Tetrahydroperfluoro-1-dodecanol for Five Days^a^

| 2 mg/kg | 18 mg/kg
n | 3 | 3
Male
2 Hours Postdose (ng/mL) | 80.2 ± 9.75 | 395 ± 60.1
24 Hours Postdose (ng/mL) | 8.1 ± 3.1 | 72.1 ± 5.52
Female
2 Hours Postdose (ng/mL) | 91.0 ± 16.9 | 386 ± 79.5
24 Hours Postdose (ng/mL) | BD | 31.9 ± 3.09

If over 20% of the animals in a group are above the limit of detection, then half the limit of detection value is substituted for values that are below it.

BD = below detection; group did not have over 20% of its values above the limit of detection so mean and standard error were not calculated.

^a^ Data are displayed as mean ± standard error of the mean.

## Apical Endpoint Benchmark Dose Summary

A summary of the calculated BMDs for each toxicological endpoint is provided in Table 8. The endpoint-specific LOEL and NOEL are included and could be informative for endpoints that lack a calculated BMD either because no viable model was available or because the estimated BMD was below the lower limit of extrapolation (<0.023 mg/kg).

Table 8 BMD, BMD_L_, LOEL, and NOEL Summary for Apical Endpoints, Sorted by BMD or LOEL from Low to High

Endpoint | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg) | LOEL (mg/kg)^a^ | NOEL (mg/kg) | Direction of Change
Male
Relative Liver Weight | 8.087 | 4.336 | 18 | 6 | UP
Absolute Liver Weight | 21.893 | 10.337 | 55 | 18 | UP
Reticulocytes | 54.227 | 30.205 | 475 | 160 | DOWN
Thyroid Stimulating Hormone | 138.723 | 20.376 | 475 | 160 | UP
Free Thyroxine | 142.469 | 57.746 | 160 | 55 | DOWN
Alkaline Phosphatase | NVM | NVM | 160 | 55 | UP
Cholesterol | UREP^b^ | UREP^b^ | 475 | 160 | –^b^
Female
Relative Liver Weight | 5.372 | 2.294 | 18 | 6 | UP
Alkaline Phosphatase | 6.461 | 6.003 | 475 | 160 | UP
Absolute Liver Weight | 8.801 | 3.465 | 6 | 2 | UP
Platelets | 16.335 | 9.571 | 160 | 55 | DOWN
Monocytes | 20.731 | 4.642 | 160 | 55 | UP
Absolute Left Kidney Weight | 56.634 | 10.508 | 55 | 18 | UP
Large Unstained Cells | 58.894 | 25.959 | 160 | 55 | UP
Absolute Right Kidney Weight | 72.145 | 18.001 | 55 | 18 | UP
Relative Left Kidney Weight | 85.629 | 17.286 | 160 | 55 | UP
Aspartate Aminotransferase | NVM | NVM | 55 | 18 | UP
Neutrophils | UREP | UREP | 55 | 18 | –
Relative Right Kidney Weight | NVM | NVM | 160 | 55 | UP

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; LOEL = lowest-observed-effect level; NOEL = no-observed-effect level; NVM = nonviable model, defined as a modeling result that does not meet prespecified fit criteria and hence is deemed unreliable; UREP = unreliable estimate of potency is a label based on review by a subject matter expert and rejection of BMD modeling results.

^a^ Values in bold text indicate the LOEL of endpoints for which a BMD could not be calculated.

^b^ BMD values are much lower than would be expected given the endpoint-specific LOEL and NOEL values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

## Gene Set Benchmark Dose Analysis

Chemical-induced alterations in liver and kidney gene transcript expression were examined to determine those gene sets most sensitive to 1,1,2,2-tetrahydroperfluoro-1-dodecanol exposure. To that end, BMD analysis of transcripts and gene sets (Gene Ontology [GO] biological process) was conducted to determine the potency of the chemical to elicit gene expression changes in the liver and kidney. This analysis used transcript-level BMD data to assess an aggregate score of gene set potency (median transcript BMD) and enrichment.

The “active” gene sets in the liver and kidney with the lowest BMD median values are shown in Table 9 and Table 10, respectively. The gene sets in Table 9 and Table 10 should be interpreted with caution from the standpoint of the underlying biological mechanism and any relationship to toxicity or toxic agents referenced in the GO term definitions. The data primarily should be considered a metric of potency for chemical-induced transcriptional changes (i.e., a concerted biological change) that could serve as a surrogate of estimated biological potency and, by extension, toxicological potency when more definitive toxicological data are unavailable.

Table 9 Top 10 Liver Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Category Name | No. of Active Genes/Platform Genes in Gene Set | % Gene Set Coverage | Active Genes | BMD_1std_ Median of Gene Set Transcripts (mg/kg) | Median BMD_L1Std_–BMD_U1Std_ (mg/kg) | Genes with Changed Direction Up | Genes with Changed Direction Down
Male
GO:0009165 nucleotide biosynthetic process | 3/55 | 5% | Rrm2b; Gcdh; Aldoa | 5.235 | 2.666–10.897 | 3 | 0
GO:0015850 organic hydroxy compound transport | 3/50 | 6% | Aqp9; Apoa1; Abcc3 | 5.978 | 3.303–16.491 | 1 | 2
GO:0051496 positive regulation of stress fiber assembly | 3/21 | 14% | Rhoc; Pak1; Apoa1 | 6.710 | 2.595–19.237 | 2 | 1
GO:0042908 xenobiotic transport | 4/11 | 36% | Slc17a3; Abcg2; Abcc4; Abcc3 | 6.716 | 3.394–26.223 | 4 | 0
GO:0032273 positive regulation of protein polymerization | 3/30 | 10% | Pak1; Icam1; Hspa1a | 7.304 | 2.595–23.878 | 3 | 0
GO:0032535 regulation of cellular component size | 3/60 | 5% | Sptan1; Icam1; Anxa7 | 7.304 | 2.970–23.878 | 3 | 0
GO:1903426 regulation of reactive oxygen species biosynthetic process | 5/48 | 10% | Rgn; Ptgs2; Icam1; Hspd1; Foxo3 | 7.304 | 3.587–23.878 | 3 | 2
GO:2000351 regulation of endothelial cell apoptotic process | 3/28 | 11% | Icam1; Foxo3; Ccl2 | 7.304 | 2.250–23.878 | 2 | 1
GO:0070741 response to interleukin-6 | 3/14 | 21% | Pck1; Icam1; Ccl2 | 7.304 | 2.250–23.878 | 2 | 1
GO:1903428 positive regulation of reactive oxygen species biosynthetic process | 3/33 | 9% | Ptgs2; Icam1; Foxo3 | 7.304 | 2.250–23.878 | 2 | 1
Female
GO:0006475 internal protein amino acid acetylation | 3/15 | 20% | Pck1; Ncoa1; Ehhadh | 5.355 | 3.108–9.861 | 3 | 0
GO:0009064 glutamine family amino acid metabolic process | 3/24 | 13% | Gclm; Gclc; Dao | 8.071 | 3.552–26.141 | 3 | 0
GO:0046700 heterocycle catabolic process | 4/63 | 6% | Hmox1; Dao; Aldh1l1; Akr7a3 | 8.437 | 2.875–33.533 | 4 | 0
GO:1901361 organic cyclic compound catabolic process | 5/89 | 6% | Hmox1; Dao; Cyp1a2; Aldh1l1; Akr7a3 | 8.803 | 3.082–26.141 | 4 | 1
GO:0009069 serine family amino acid metabolic process | 4/13 | 31% | Txnrd1; Gclm; Gclc; Dao | 9.286 | 4.360–24.515 | 4 | 0
GO:0055093 response to hyperoxia | 3/24 | 13% | Txnrd1; Cdkn1a; Cav1 | 10.500 | 5.321–22.888 | 2 | 1
GO:1901605 alpha-amino acid metabolic process | 5/72 | 7% | Txnrd1; Plod2; Gclm; Gclc; Dao | 10.500 | 5.167–26.141 | 5 | 0
GO:0007093 mitotic cell cycle checkpoint | 3/38 | 8% | Zwint; Kntc1; Cdkn1a | 11.920 | 4.772–41.705 | 2 | 1
GO:0010823 negative regulation of mitochondrion organization | 3/22 | 14% | Hgf; Gclc; Acaa2 | 11.956 | 5.167–23.735 | 2 | 1
GO:0035729 cellular response to hepatocyte growth factor stimulus | 3/14 | 21% | Hgf; Gclm; Gclc | 11.956 | 5.167–23.735 | 2 | 1

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^30^ Official gene symbols from the Rat Genome Database^31^ are shown in the “Active Genes” column.

GO process description version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

GO:0009165 nucleotide biosynthetic process: The chemical reactions and pathways resulting in the formation of nucleotides, any nucleoside that is esterified with (ortho)phosphate or an oligophosphate at any hydroxyl group on the glycose moiety; may be mono-, di- or triphosphate; this definition includes cyclic-nucleotides (nucleoside cyclic phosphates).

GO:0015850 organic hydroxy compound transport: The directed movement of an organic hydroxy compound (organic alcohol) into, out of, or within a cell, or between cells, by means of some agent such as a transporter or pore. An organic hydroxy compound is an organic compound having at least one hydroxy group attached to a carbon atom.

GO:0051496 positive regulation of stress fiber assembly: Any process that activates or increases the frequency, rate, or extent of the assembly of a stress fiber, a bundle of microfilaments and other proteins found in fibroblasts.

GO:0042908 xenobiotic transport: The directed movement of a xenobiotic into, out of or within a cell, or between cells, by means of some agent such as a transporter or pore. A xenobiotic is a compound foreign to the organism exposed to it. It may be synthesized by another organism (like ampicillin) or it can be a synthetic chemical.

GO:0032273 positive regulation of protein polymerization: Any process that activates or increases the frequency, rate or extent of the process of creating protein polymers.

GO:0032535 regulation of cellular component size: A process that modulates the size of a cellular component.

GO:1903426 regulation of reactive oxygen species biosynthetic process: Any process that modulates the frequency, rate, or extent of reactive oxygen species biosynthetic process.

GO:2000351 regulation of endothelial cell apoptotic process: Any process that modulates the frequency, rate, or extent of endothelial cell apoptotic process.

GO:0070741 response to interleukin-6: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an interleukin-6 stimulus.

GO:1903428 positive regulation of reactive oxygen species biosynthetic process: Any process that activates or increases the frequency, rate, or extent of reactive oxygen species biosynthetic process.

GO:0006475 internal protein amino acid acetylation: The addition of an acetyl group to a nonterminal amino acid in a protein.

GO:0009064 glutamine family amino acid metabolic process: The chemical reactions and pathways involving amino acids of the glutamine family, comprising arginine, glutamate, glutamine, and proline.

GO:0046700 heterocycle catabolic process: The chemical reactions and pathways resulting in the breakdown of heterocyclic compounds, those with a cyclic molecular structure, and at least two different atoms in the ring (or rings).

GO:1901361 organic cyclic compound catabolic process: The chemical reactions and pathways resulting in the breakdown of organic cyclic compound.

GO:0009069 serine family amino acid metabolic process: The chemical reactions and pathways involving amino acids of the serine family, comprising cysteine, glycine, homoserine, selenocysteine, and serine.

GO:0055093 response to hyperoxia: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a stimulus indicating increased oxygen tension.

GO:1901605 alpha-amino acid metabolic process: The chemical reactions and pathways involving an alpha-amino acid.

GO:0007093 mitotic cell cycle checkpoint: A signaling process that ensures accurate chromosome replication and segregation by preventing progression through a mitotic cell cycle until conditions are suitable for the cell to proceed to the next stage.

GO:0010823 negative regulation of mitochondrion organization: Any process that decreases the frequency, rate, or extent of a process involved in the formation, arrangement of constituent parts, or disassembly of a mitochondrion.

GO:0035729 cellular response to hepatocyte growth factor stimulus: Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a hepatocyte growth factor stimulus.

Table 10 Top 10 Kidney Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Category Name | No. of Active Genes/Platform Genes in Gene Set | % Gene Set Coverage | Active Genes | BMD_1std_ Median of Gene Set Transcripts (mg/kg) | Median BMD_L1Std_–BMD_U1Std_ (mg/kg) | Genes with Changed Direction Up | Genes with Changed Direction Down
Male
GO:0002886 regulation of myeloid leukocyte mediated immunity | 3/28 | 11% | Rt1-S3; Hmox1; C3 | 144.319 | 57.694–153.260 | 2 | 1
GO:0032570 response to progesterone | 3/40 | 8% | Srebf1; Map2; C3 | 145.437 | 104.718–237.081 | 2 | 1
GO:0002703 regulation of leukocyte mediated immunity | 4/79 | 5% | Rt1-S3; Il1b; Hmox1; C3 | 149.155 | 83.579–205.964 | 3 | 1
GO:0002675 positive regulation of acute inflammatory response | 3/17 | 18% | Rt1-S3; Il1b; C3 | 153.991 | 109.464–258.668 | 2 | 1
GO:0072347 response to anesthetic | 3/44 | 7% | Slc6a1; Il1b; Grin1 | 153.991 | 109.464–258.668 | 3 | 0
GO:1903531 negative regulation of secretion by cell | 3/60 | 5% | Srebf1; Il1b; Hmox1 | 153.991 | 109.464–258.668 | 2 | 1
GO:0009408 response to heat | 3/59 | 5% | Il1b; Hmox1; Cxcl10 | 153.991 | 109.464–258.668 | 2 | 1
GO:0050766 positive regulation of phagocytosis | 3/35 | 9% | Il1b; Clec7a; C3 | 153.991 | 109.464–258.668 | 3 | 0
GO:0002718 regulation of cytokine production involved in immune response | 3/36 | 8% | Rt1-S3; Il1b; Hmox1 | 153.991 | 109.464–258.668 | 2 | 1
GO:0045665 negative regulation of neuron differentiation | 3/54 | 6% | Map2; Il1b; Fgf13 | 153.991 | 109.464–258.668 | 2 | 1
Female
GO:0045087 innate immune response | 5/87 | 6% | Vnn1; Fcer1g; Col12a1; Clec4a; C3 | 57.313 | 37.882–112.773 | 4 | 1
GO:0002253 activation of immune response | 4/69 | 6% | Fyb1; Fcer1g; Col12a1; C3 | 78.645 | 45.596–480.937 | 3 | 1
GO:0002250 adaptive immune response | 3/57 | 5% | Fcer1g; Adgre1; Clec4a | 82.466 | 47.872–265.955 | 3 | 0
GO:0050729 positive regulation of inflammatory response | 3/52 | 6% | Tslp; Fcer1g; C3 | 99.976 | 53.311–818.733 | 2 | 1
GO:0006690 icosanoid metabolic process | 3/48 | 6% | Gstp1; Ephx1; Cyp4a2 | 147.888 | 112.384–215.342 | 3 | 0
GO:0071385 cellular response to glucocorticoid stimulus | 3/51 | 6% | Hmgcs2; Gstp1; Ephx1 | 147.888 | 112.384–215.342 | 3 | 0
GO:1901568 fatty acid derivative metabolic process | 4/57 | 7% | Hmgcs2; Gstp1; Ephx1; Cyp4a2 | 220.130 | 150.351–433.756 | 4 | 0
GO:0046165 alcohol biosynthetic process | 3/41 | 7% | Hmgcs2; Ephx1; Cyp26b1 | 238.250 | 181.323–370.243 | 3 | 0
GO:0045580 regulation of T cell differentiation | 3/47 | 6% | Vnn1; Lilrb4; Cyp26b1 | 238.250 | 181.323–370.243 | 3 | 0
GO:0021700 developmental maturation | 3/51 | 6% | Sez6; Fgg; C3 | 251.984 | 163.812–471.307 | 2 | 1

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^30^ Official gene symbols from the Rat Genome Database^31^ are shown in the “Active Genes” column.

GO process description version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

GO:0002886 regulation of myeloid leukocyte mediated immunity: Any process that modulates the frequency, rate, or extent of myeloid leukocyte mediated immunity.

GO:0032570 response to progesterone: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a progesterone stimulus.

GO:0002703 regulation of leukocyte mediated immunity: Any process that modulates the frequency, rate, or extent of leukocyte mediated immunity.

GO:0002675 positive regulation of acute inflammatory response: Any process that activates or increases the frequency, rate, or extent of an acute inflammatory response.

GO:0072347 response to anesthetic: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an anesthetic stimulus. An anesthetic is a substance that causes loss of feeling, awareness, or sensation.

GO:1903531 negative regulation of secretion by cell: Any process that stops, prevents, or reduces the frequency, rate, or extent of secretion by cell.

GO:0009408 response to heat: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a heat stimulus, a temperature stimulus above the optimal temperature for that organism.

GO:0050766 positive regulation of phagocytosis: Any process that activates or increases the frequency, rate, or extent of phagocytosis.

GO:0002718 regulation of cytokine production involved in immune response: Any process that modulates the frequency, rate, or extent of cytokine production that contributes to an immune response.

GO:0045665 negative regulation of neuron differentiation: Any process that stops, prevents, or reduces the frequency, rate, or extent of neuron differentiation.

GO:0045087 innate immune response: Innate immune responses are defense responses mediated by germline encoded components that directly recognize components of potential pathogens.

GO:0002253 activation of immune response: Any process that initiates an immune response.

GO:0002250 adaptive immune response: An immune response mediated by cells expressing specific receptors for antigen produced through a somatic diversification process and allowing for an enhanced secondary response to subsequent exposures to the same antigen (immunological memory).

GO:0050729 positive regulation of inflammatory response: Any process that activates or increases the frequency, rate, or extent of the inflammatory response.

GO:0006690 icosanoid metabolic process: The chemical reactions and pathways involving icosanoids, any of a group of C20 polyunsaturated fatty acids.

GO:0071385 cellular response to glucocorticoid stimulus: Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a glucocorticoid stimulus. Glucocorticoids are hormonal C21 corticosteroids synthesized from cholesterol with the ability to bind with the cortisol receptor and trigger similar effects. Glucocorticoids act primarily on carbohydrate and protein metabolism and have anti-inflammatory effects.

GO:1901568 fatty acid derivative metabolic process: The chemical reactions and pathways involving fatty acid derivative.

GO:0046165 alcohol biosynthetic process: The chemical reactions and pathways resulting in the formation of alcohols, any of a class of compounds containing one or more hydroxyl groups attached to a saturated carbon atom.

GO:0045580 regulation of T cell differentiation: Any process that modulates the frequency, rate, or extent of T cell differentiation.

GO:0021700 developmental maturation: A developmental process, independent of morphogenetic (shape) change that is required for an anatomical structure, cell, or cellular component to attain its fully functional state.

No gene sets in the liver of male or female rats had estimated BMD median values <0.023 mg/kg. In male rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were nucleotide biosynthetic process (GO:0009165) and organic hydroxy compound transport (GO:0015850) with median BMDs (BMD_L_s) of 5.235 (2.666) and 5.978 (3.303) mg/kg, respectively. In female rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were internal protein amino acid acetylation (GO:0006475) and glutamine family amino acid metabolic process (GO:0009064) with median BMDs (BMD_L_s) of 5.355 (3.108) and 8.071 (3.552) mg/kg, respectively.

No gene sets in the kidney of male or female rats had estimated BMD median values <0.023 mg/kg. In male rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were regulation of myeloid leukocyte mediated immunity (GO:0002886) and response to progesterone (GO:0032570) with median BMDs (BMD_L_s) of 144.319 (57.694) and 145.437 (104.718) mg/kg, respectively. In female rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were innate immune response (GO:0045087) and activation of immune response (GO:0002253) with median BMDs (BMD_L_s) of 57.313 (37.882) and 78.645 (45.596) mg/kg, respectively. The full list of affected gene sets in the liver and kidney of male and female rats can be found in Appendix F.

## Gene Benchmark Dose Analysis

The top 10 genes based on BMD potency in the liver and kidney (fold change >|2|, significant Williams trend test, global goodness-of-fit p value >0.1, and BMD_U_/BMD_L_ ≤40) are shown in Table 11 and Table 12. As with the GO analysis, the biological or toxicological significance of the changes in gene expression shown in Table 11 and Table 12 should be interpreted with caution. The data primarily should be considered a metric of potency for chemical-induced transcriptional changes that could serve as a conservative surrogate of estimated biological potency, and by extension toxicological potency, when more definitive toxicological data are unavailable.

Table 11 Top 10 Liver Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | BMD_1Std_ (BMD_L1std_–BMD_U1std_) in mg/kg | Maximum Fold Change | Direction of Expression Change
Male
Pck1 | 362282 | PCK1_9439 | 1.149 (0.548–2.562) | 2.7 | DOWN
A2m | 24153 | A2M_7932 | 1.733 (0.972–3.497) | 3.0 | DOWN
Loc100911545/A2m | 100911545 | A2M_7932 | 1.733 (0.972–3.497) | 3.0 | DOWN
Zfp354a | 24522 | ZFP354A_10203 | 1.785 (0.579–5.737) | 3.6 | DOWN
Akr7a3 | 26760 | AKR7A3_8015 | 2.192 (1.593–3.715) | 9.5 | UP
Ephx1 | 25315 | EPHX1_8567 | 2.467 (1.828–4.041) | 5.6 | UP
Me1 | 24552 | ME1_9215 | 3.531 (2.076–6.794) | 3.4 | UP
Cyp4a1 | 50549 | CYP4A1_33111 | 4.588 (2.345–9.587) | 2.6 | UP
Anxa7 | 155423 | ANXA7_8051 | 4.660 (2.970–7.797) | 3.8 | UP
Slc17a3 | 266730 | SLC17A3_9840 | 5.147 (3.485–8.103) | 3.1 | UP
Female
Abcc3 | 140668 | ABCC3_7941 | 5.019 (2.945–9.451) | 3.5 | UP
Gsta2 | 24422 | GSTA2_8756 | 5.153 (2.796–10.815) | 2.8 | UP
Gsta5 | 494499 | GSTA2_8756 | 5.153 (2.796–10.815) | 2.8 | UP
Ephx1 | 25315 | EPHX1_8567 | 5.233 (3.072–9.586) | 3.8 | UP
Akr7a3 | 26760 | AKR7A3_8015 | 5.348 (3.082–10.631) | 5.7 | UP
Ehhadh | 171142 | EHHADH_8534 | 5.355 (3.108–9.861) | 2.2 | UP
Pir | 363465 | PIR_9487 | 6.124 (2.642–15.294) | 2.8 | UP
Gclm | 29739 | GCLM_8700 | 8.034 (3.552–19.773) | 2.1 | UP
Dao | 114027 | DAO_8437 | 8.071 (2.669–26.141) | 2.1 | UP
Me1 | 24552 | ME1_9215 | 8.192 (2.618–30.949) | 2.3 | UP

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean.

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^32^ and Entrez Gene.^33^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Pck1: Human Uniprot function (Human PCK1): Cytosolic phosphoenolpyruvate carboxykinase that catalyzes the reversible decarboxylation and phosphorylation of oxaloacetate (OAA) and acts as the rate-limiting enzyme in gluconeogenesis (PubMed30193097, PubMed24863970, PubMed26971250, PubMed28216384). Regulates cataplerosis and anaplerosis, the processes that control the levels of metabolic intermediates in the citric acid cycle (PubMed30193097, PubMed24863970, PubMed26971250, PubMed28216384). At low glucose levels, it catalyzes the cataplerotic conversion of oxaloacetate to phosphoenolpyruvate (PEP), the rate-limiting step in the metabolic pathway that produces glucose from lactate and other precursors derived from the citric acid cycle (PubMed30193097). At high glucose levels, it catalyzes the anaplerotic conversion of phosphoenolpyruvate to oxaloacetate (PubMed30193097). Acts as a regulator of formation and maintenance of memory CD8(+) T-cells upregulated in these cells, where it generates phosphoenolpyruvate, via gluconeogenesis (by similarity). The resultant phosphoenolpyruvate flows to glycogen and pentose phosphate pathway, which is essential for memory CD8(+) T-cells homeostasis (by similarity). In addition to the phosphoenolpyruvate carboxykinase activity, also acts as a protein kinase when phosphorylated at Ser-90 phosphorylation at Ser-90 by AKT1 reduces the binding affinity to oxaloacetate and promotes an atypical serine protein kinase activity using GTP as donor (PubMed32322062). The protein kinase activity regulates lipogenesis upon phosphorylation at Ser-90, translocates to the endoplasmic reticulum and catalyzes phosphorylation of INSIG proteins (INSIG1 and INSIG2), thereby disrupting the interaction between INSIG proteins and SCAP and promoting nuclear translocation of SREBP proteins (SREBF1/SREBP1 or SREBF2/SREBP2) and subsequent transcription of downstream lipogenesis-related genes (PubMed32322062). {ECO0000250|UniProtKBQ9Z2V4, ECO0000269|PubMed24863970, ECO0000269|PubMed26971250, ECO0000269|PubMed28216384, ECO0000269|PubMed30193097, ECO0000269|PubMed32322062}.

A2m: Human Uniprot function (Human A2M): Is able to inhibit all four classes of proteinases by a unique ‘trapping’ mechanism. This protein has a peptide stretch, called the ‘bait region’ which contains specific cleavage sites for different proteinases. When a proteinase cleaves the bait region, a conformational change is induced in the protein which traps the proteinase. The entrapped enzyme remains active against low molecular weight substrates (activity against high molecular weight substrates is greatly reduced). Following cleavage in the bait region, a thioester bond is hydrolyzed and mediates the covalent binding of the protein to the proteinase.

LOC100911545/A2m: Human Uniprot function (Human A2M): Is able to inhibit all four classes of proteinases by a unique ‘trapping’ mechanism. This protein has a peptide stretch, called the ‘bait region’ which contains specific cleavage sites for different proteinases. When a proteinase cleaves the bait region, a conformational change is induced in the protein which traps the proteinase. The entrapped enzyme remains active against low molecular weight substrates (activity against high molecular weight substrates is greatly reduced). Following cleavage in the bait region, a thioester bond is hydrolyzed and mediates the covalent binding of the protein to the proteinase.

Zfp354a: Rat Uniprot function (Human ZNF354A): It may play a role in renal development and may also be involved in the repair of the kidney after ischemia-reperfusion or folic acid administration.

Akr7a3: Human Uniprot function (Human AKR7A3): Can reduce the dialdehyde protein-binding form of aflatoxin B1 (AFB1) to the nonbinding AFB1 dialcohol. May be involved in protection of liver against the toxic and carcinogenic effects of AFB1, a potent hepatocarcinogen. {ECO0000269|PubMed18416522}.

Ephx1: Human Uniprot function (Human EPHX1): Biotransformation enzyme that catalyzes the hydrolysis of arene and aliphatic epoxides to less reactive and more water soluble dihydrodiols by the trans addition of water (by similarity). Plays a role in the metabolism of endogenous lipids such as epoxide-containing fatty acids (PubMed22798687). Metabolizes the abundant endocannabinoid 2-arachidonoylglycerol (2-AG) to free arachidonic acid (AA) and glycerol (PubMed24958911). {ECO0000250|UniProtKBP07687, ECO0000269|PubMed22798687, ECO0000269|PubMed24958911}.

Me1: Human Entrez Gene Summary (Human ME1): This gene encodes a cytosolic, NADP-dependent enzyme that generates NADPH for fatty acid biosynthesis. The activity of this enzyme, the reversible oxidative decarboxylation of malate, links the glycolytic and citric acid cycles. The regulation of expression for this gene is complex. Increased expression can result from elevated levels of thyroid hormones or by higher proportions of carbohydrates in the diet. [provided by RefSeq, Jul 2008]

Cyp4a1: Human Uniprot function (Human CYP4A22): Catalyzes the omega- and (omega-1)-hydroxylation of various fatty acids such as laurate and palmitate. Shows no activity toward arachidonic acid and prostaglandin A1. Lacks functional activity in the kidney and does not contribute to renal 20-hydroxyeicosatetraenoic acid (20-HETE) biosynthesis. {ECO0000269|PubMed10860550, ECO0000269|PubMed15611369}.

Anxa7: Human Uniprot function (Human ANXA7): Calcium/phospholipid-binding protein that promotes membrane fusion and is involved in exocytosis.

Slc17a3: Human Uniprot function (Human SLC17A3): [Isoform 2] voltage-driven, multispecific, organic anion transporter able to transport para-aminohippurate (PAH), estrone sulfate, estradiol-17-beta-glucuronide, bumetanide, and ochratoxin A. Isoform 2 functions as urate efflux transporter on the apical side of renal proximal tubule and is likely to act as an exit path for organic anionic drugs as well as urate in vivo. May be involved in actively transporting phosphate into cells via Na(+) cotransport.

Abcc3: Human Uniprot function (Human ABCC3): ATP-dependent transporter of the ATP-binding cassette (ABC) family that binds and hydrolyzes ATP to enable active transport of various substrates, including many drugs, toxicants, and endogenous compounds across cell membranes (PubMed11581266, PubMed15083066, PubMed10359813). Transports glucuronide conjugates such as bilirubin diglucuronide, estradiol-17-beta-o-glucuronide, and GSH conjugates such as leukotriene C4 (LTC4) (PubMed15083066, PubMed11581266). Transports also various bile salts (taurocholate, glycocholate, taurochenodeoxycholate-3-sulfate, taurolithocholate- 3-sulfate) (by similarity). Does not contribute substantially to bile salt physiology but provides an alternative route for the export of bile acids and glucuronides from cholestatic hepatocytes (by similarity). Can confer resistance to various anticancer drugs, methotrexate, tenoposide, and etoposide by decreasing accumulation of these drugs in cells (PubMed11581266, PubMed10359813).

Gsta2: Human Uniprot function (Human GSTA2): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles.

Gsta5: Rat Uniprot function (Human GSTA5): Conjugation of reduced glutathione to a wide number of exogenous and endogenous hydrophobic electrophiles. Has substantial activity toward aflatoxin B1-8,9-epoxide.

Ehhadh: Human Uniprot function (Human EHHADH): Peroxisomal trifunctional enzyme possessing 2-enoyl-CoA hydratase, 3-hydroxyacyl-CoA dehydrogenase, and delta 3, delta 2-enoyl-CoA isomerase activities. Catalyzes two of the four reactions of the long straight chain fatty acids peroxisomal beta-oxidation pathway. Optimal isomerase for 2,5 double bonds into 3,5 form isomerization in a range of enoyl-CoA species (Probable). Also able to isomerize both 3-cis and 3-trans double bonds into the 2-trans form in a range of enoyl-CoA species (by similarity). With HSD17B4, catalyzes the hydration of trans-2-enoyl-CoA and the dehydrogenation of 3-hydroxyacyl-CoA, but with opposite chiral specificity (PubMed15060085). Regulates the amount of medium-chain dicarboxylic fatty acids which are essential regulators of all fatty acid oxidation pathways (by similarity). Also involved in the degradation of long-chain dicarboxylic acids through peroxisomal beta-oxidation (PubMed15060085). {ECO0000250|UniProtKBP07896, ECO0000250|UniProtKBQ9DBM2, ECO0000269|PubMed15060085, ECO0000305|PubMed15060085}.

Pir: Human Uniprot function (Human PIR): Transcriptional coregulator of NF-kappa-B which facilitates binding of NF-kappa-B proteins to target kappa-B genes in a redox-state-dependent manner. May be required for efficient terminal myeloid maturation of hematopoietic cells. Has quercetin 2,3-dioxygenase activity (in vitro). {ECO0000269|PubMed17288615, ECO0000269|PubMed20010624, ECO0000269|PubMed20711196, ECO0000269|PubMed23716661}.

Gclm: Human Entrez Gene Summary (Human GCLM): Glutamate-cysteine ligase, also known as gamma-glutamylcysteine synthetase, is the first rate-limiting enzyme of glutathione synthesis. The enzyme consists of two subunits, a heavy catalytic subunit and a light regulatory subunit. Gamma-glutamylcysteine synthetase deficiency has been implicated in some forms of hemolytic anemia. Alternative splicing results in multiple transcript variants encoding different isoforms. [provided by RefSeq, Apr 2015]

Dao: Human Uniprot function (Human DAO): Regulates the level of the neuromodulator D-serine in the brain. Has high activity toward D-DOPA and contributes to dopamine synthesis. Could act as a detoxifying agent which removes D-amino acids accumulated during aging. Acts on a variety of D-amino acids with a preference for those having small hydrophobic side chains followed by those bearing polar, aromatic, and basic groups. Does not act on acidic amino acids. {ECO0000269|PubMed17303072}.

Table 12 Top 10 Kidney Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Gene Symbol | Entrez Gene IDs | Probe IDs | BMD_1Std_ (BMD_L1std_–BMD_U1std_) in mg/kg | Maximum Fold Change | Direction of Expression Change
Male
Ugt2b7 | 286989 | UGT2B7_33032 | 4.139 (1.398–16.569) | 3.6 | UP
Ephx1 | 25315 | EPHX1_8567 | 12.509 (3.282–61.397) | 2.1 | UP
Adgre1 | 316137 | EMR1_8558 | 119.065 (89.170–178.281) | 3.1 | UP
Map2 | 25595 | MAP2_32650 | 145.437 (104.718–237.081) | 2.1 | UP
Slc6a1 | 79212 | SLC6A1_32594 | 145.445 (104.722–237.101) | 2.0 | UP
Naaa | 497009 | NAAA_32484 | 151.002 (107.821–250.969) | 2.2 | UP
Il1b | 24494 | IL1B_8892 | 153.991 (109.464–258.668) | 2.9 | UP
Cyp24a1 | 25279 | CYP24A1_32574 | 189.111 (127.579–364.247) | 2.2 | UP
Top2a | 360243 | TOP2A_10059 | 203.468 (108.442–572.253) | 2.1 | DOWN
Nsg1 | 25247 | NSG1_32675 | 216.472 (166.237–342.576) | 3.4 | UP
Female
Mrc1 | 291327 | MRC1_33067 | <0.023^b^ (NR) | 2.1 | DOWN
Ckap2 | 306575 | CKAP2_8324 | 2.608 (0.997–6.811) | 2.3 | UP
Ugt2b37 | 29623 | UGT2B15_33121 | 32.501 (7.520–103.327) | 3.3 | UP
Slc51a | 303879 | SLC51A_33157 | 37.134 (11.007–108.745) | 2.2 | UP
Ugt2b7 | 286989 | UGT2B7_33032 | 54.314 (15.595–186.641) | 4.8 | UP
Bbox1 | 64564 | BBOX1_8133 | 61.319 (39.473–135.622) | 2.0 | UP
Adgre1 | 316137 | EMR1_8558 | 61.524 (39.671–132.174) | 2.4 | UP
Clec4a | 474143 | CLEC4A_32636 | 82.466 (47.872–265.955) | 2.2 | UP
Cyp26b1 | 312495 | CYP26B1_8418 | 238.250 (181.323–370.243) | 2.8 | UP
Lilrb4 | 292594 | LILRB4_9000 | 350.991 (212.248–1011.690) | 2.3 | UP

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NR = the BMD_L1Std_–BMD_U1Std_ range is not reportable because the BMD_1Std_ median is below the lower limit of extrapolation (<1/3 of the lowest nonzero dose tested).

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^32^ and Entrez Gene.^33^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ <0.023 = a best-fit model was identified and a BMD_1Std_ was estimated that was <1/3 of the lowest nonzero dose tested.

Gene definition version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Ugt2b7: Human Uniprot function (Human UGT2B7): UDP-glucuronosyltransferase (UGT) that catalyzes phase II biotransformation reactions in which lipophilic substrates are conjugated with glucuronic acid to increase the metabolite’s water solubility, thereby facilitating excretion into either the urine or bile (PubMed10702251, PubMed15472229, PubMed15470161, PubMed18674515, PubMed18719240, PubMed19022937, PubMed23288867, PubMed23756265, PubMed26220143, PubMed17442341). Essential for the elimination and detoxification of drugs, xenobiotics, and endogenous compounds (PubMed15470161, PubMed18674515, PubMed23756265). Catalyzes the glucuronidation of endogenous steroid hormones such as androgens (epitestosterone, androsterone) and estrogens (estradiol, epiestradiol, estriol, catechol estrogens) (PubMed2159463, PubMed15472229, PubMed18719240, PubMed19022937, PubMed23288867, PubMed26220143, PubMed17442341). Also regulates the levels of retinoic acid, a major metabolite of vitamin A involved in apoptosis, cellular growth and differentiation, and embryonic development (PubMed10702251). Contributes to bile acid (BA) detoxification by catalyzing the glucuronidation of BA substrates, which are natural detergents for dietary lipids absorption (PubMed23756265). Involved in the glucuronidation of the AGTR1 angiotensin receptor antagonist losartan, caderastan, and zolarsatan, drugs that can inhibit the effect of angiotensin II (PubMed18674515). Also metabolizes mycophenolate, an immunosuppressive agent (PubMed15470161). {ECO0000269|PubMed10702251, ECO0000269|PubMed15470161, ECO0000269|PubMed15472229, ECO0000269|PubMed17442341, ECO0000269|PubMed18674515, ECO0000269|PubMed18719240, ECO0000269|PubMed19022937, ECO0000269|PubMed2159463, ECO0000269|PubMed23288867, ECO0000269|PubMed23756265, ECO0000269|PubMed26220143}.

Ephx1: Human Uniprot function (Human EPHX1): Biotransformation enzyme that catalyzes the hydrolysis of arene and aliphatic epoxides to less reactive and more water soluble dihydrodiols by the trans addition of water (by similarity). Plays a role in the metabolism of endogenous lipids such as epoxide-containing fatty acids (PubMed22798687). Metabolizes the abundant endocannabinoid 2-arachidonoylglycerol (2-AG) to free arachidonic acid (AA) and glycerol (PubMed24958911). {ECO0000250|UniProtKBP07687, ECO0000269|PubMed22798687, ECO0000269|PubMed24958911}.

Adgre1: Human Uniprot function (Human ADGRE1): Orphan receptor involved in cell adhesion and probably in cell-cell interactions specifically involving cells of the immune system. May play a role in regulatory T-cells (Treg) development. {ECO0000250|UniProtKBQ61549}.

Map2: Human Uniprot function (Human MAP2): The exact function of MAP2 is unknown but MAPs may stabilize the microtubules against depolymerization. They also seem to have a stiffening effect on microtubules.

Slc6a1: Human Uniprot function (Human SLC6A1): Terminates the action of GABA by its high affinity sodium-dependent reuptake into presynaptic terminals.

Naaa: Human Uniprot function (Human NAAA): Degrades bioactive fatty acid amides to their corresponding acids with the following preference: N-palmitoylethanolamine > N-myristoylethanolamine > N-lauroylethanolamine = N-stearoylethanolamine > N-arachidonoylethanolamine > N-oleoylethanolamine (PubMed15655246, PubMed17980170, PubMed18793752, PubMed30301806, PubMed22825852). Also exhibits weak hydrolytic activity against the ceramides N-lauroylsphingosine and N-palmitoylsphingosine (PubMed15655246). {ECO0000269|PubMed15655246, ECO0000269|PubMed17980170, ECO0000269|PubMed18793752, ECO0000269|PubMed22825852, ECO0000269|PubMed30301806}.

Il1b: Human Uniprot function (Human IL1B): Potent proinflammatory cytokine. Initially discovered as the major endogenous pyrogen, induces prostaglandin synthesis, neutrophil influx and activation, T cell activation and cytokine production, B-cell activation and antibody production, and fibroblast proliferation and collagen production. Promotes Th17 differentiation of T-cells. Synergizes with IL12/interleukin-12 to induce IFNG synthesis from T-helper 1 (Th1) cells (PubMed10653850). Plays a role in angiogenesis by inducing VEGF production synergistically with TNF and IL6 (PubMed12794819). {ECO0000269|PubMed10653850, ECO0000269|PubMed12794819, ECO0000269|PubMed3920526}.

Cyp24a1: Human Uniprot function (Human CYP24A1): A cytochrome P450 monooxygenase with a key role in vitamin D catabolism and calcium homeostasis. Via C24- and C23-oxidation pathways, catalyzes the inactivation of both the vitamin D precursor calcidiol (25-hydroxyvitamin D(3)) and the active hormone calcitriol (1-alpha,25-dihydroxyvitamin D(3)) (PubMed24893882, PubMed15574355, PubMed8679605, PubMed11012668, PubMed16617161). With initial hydroxylation at C-24 (via C24-oxidation pathway), performs a sequential 6-step oxidation of calcitriol leading to the formation of the biliary metabolite calcitroic acid (PubMed24893882, PubMed15574355). With initial hydroxylation at C-23 (via C23-oxidation pathway), catalyzes sequential oxidation of calcidiol leading to the formation of 25(OH)D3-26,23-lactone as end product (PubMed11012668, PubMed8679605). Preferentially hydroxylates at C-25 other vitamin D active metabolites, such as CYP11A1-derived secosteroids 20S-hydroxycholecalciferol and 20S,23-dihydroxycholecalciferol (PubMed25727742). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate and reducing the second into a water molecule with two electrons provided by NADPH via FDXR/adrenodoxin reductase and FDX1/adrenodoxin (PubMed8679605). {ECO0000269|PubMed11012668, ECO0000269|PubMed15574355, ECO0000269|PubMed16617161, ECO0000269|PubMed24893882, ECO0000269|PubMed25727742, ECO0000269|PubMed8679605}.

Top2a: Human Uniprot function (Human TOP2A): Key decatenating enzyme that alters DNA topology by binding to two double-stranded DNA molecules, generating a double-stranded break in one of the strands, passing the intact strand through the broken strand, and religating the broken strand (PubMed17567603, PubMed18790802, PubMed22013166, PubMed22323612). May play a role in regulating the period length of ARNTL/BMAL1 transcriptional oscillation (by similarity). {ECO0000250|UniProtKBQ01320, ECO0000269|PubMed17567603, ECO0000269|PubMed18790802, ECO0000269|PubMed22013166, ECO0000269|PubMed22323612}.

Nsg1: Human Uniprot function (Human NSG1): Plays a role in the recycling mechanism in neurons of multiple receptors, including AMPAR, APP, and L1CAM, and acts at the level of early endosomes to promote sorting of receptors toward a recycling pathway. Regulates sorting and recycling of GRIA2 through interaction with GRIP1 and then contributes to the regulation of synaptic transmission and plasticity by affecting the recycling and targeting of AMPA receptors to the synapse (by similarity). Is required for faithful sorting of L1CAM to axons by facilitating trafficking from somatodendritic early endosome or the recycling endosome (by similarity). On the other hand, induces apoptosis via the activation of CASP3 in response to DNA damage (PubMed20599942, PubMed20878061). {ECO0000250|UniProtKBP02683, ECO0000250|UniProtKBQ62092, ECO0000269|PubMed20599942, ECO0000269|PubMed20878061}.

Mrc1: Human Uniprot function (Human MRC1): Mediates the endocytosis of glycoproteins by macrophages. Binds both sulfated and nonsulfated polysaccharide chains. FUNCTION (Microbial infection) Acts as phagocytic receptor for bacteria, fungi, and other pathogens. FUNCTION (Microbial infection) Acts as a receptor for Dengue virus envelope protein E. {ECO0000269|PubMed18266465}. FUNCTION (Microbial infection) Interacts with Hepatitis B virus envelope protein. {ECO0000269|PubMed19683778}.

Ckap2: Human Uniprot function (Human CKAP2): Possesses microtubule stabilizing properties. Involved in regulating aneuploidy, cell cycling, and cell death in a p53/TP53-dependent manner (by similarity). {ECO0000250}.

Ugt2b37: Human Uniprot function (Human UGT2B10): UDPGT is of major importance in the conjugation and subsequent elimination of potentially toxic xenobiotics and endogenous compounds.

Slc51a: Human Uniprot function (Human SLC51A): Essential component of the Ost-alpha/Ost-beta complex, a heterodimer that acts as the intestinal basolateral transporter responsible for bile acid export from enterocytes into portal blood. Efficiently transports the major species of bile acids. {ECO0000269|PubMed16317684}.

Bbox1: Human Uniprot function (Human BBOX1): Catalyzes the formation of L-carnitine from gamma-butyrobetaine.

Clec4a: Human Uniprot function (Human CLEC4A): C-type lectin receptor that binds carbohydrates mannose and fucose but also weakly interacts with N-acetylglucosamine (GlcNAc) in a Ca2+-dependent manner (PubMed27015765). Involved in regulating immune reactivity (PubMed18258799, PubMed10438934). Once triggered by an antigen, it is internalized by clathrin-dependent endocytosis and delivers its antigenic cargo into the antigen presentation pathway resulting in cross-priming of CD8+ T-cells. This cross-presentation and cross-priming are enhanced by TLR7 and TLR8 agonists with increased expansion of the CD8+ T-cells, high production of IFNG and TNF with reduced levels of IL4, IL5, and IL13 (PubMed18258799, PubMed20530286). In plasmacytoid dendritic cells, inhibits TLR9-mediated IFNA and TNF production (PubMed18258799). May be involved via its ITIM motif (immunoreceptor tyrosine-based inhibitory motifs) in the inhibition of B-cell-receptor-mediated calcium mobilization and protein tyrosine phosphorylation (PubMed10438934). {ECO0000269|PubMed10438934, ECO0000269|PubMed18258799, ECO0000269|PubMed20530286, ECO0000269|PubMed27015765} FUNCTION (Microbial infection) Involved in the interaction between HIV-1 virus and dendritic cells. Enhances HIV-1 binding/entry and virus infection. Requires ITIM motif-associated signal transduction pathway involving phosphatases PTPN6 and PTPN11, SYK, Src kinases and MAP kinases.{ECO0000269|PubMed21536857}.

Cyp26b1: Human Uniprot function (Human CYP26B1): Involved in the metabolism of retinoic acid (RA), rendering this classical morphogen inactive through oxidation (PubMed10823918, PubMed22020119). Involved in the specific inactivation of all-trans-retinoic acid (all-trans-RA) with a preference for the following substrates all-trans-RA > 9-cis-RA > 13-cis-RA (PubMed10823918, PubMed22020119). Generates several hydroxylated forms of RA, including 4-OH-RA, 4-oxo-RA, and 18-OH-RA (PubMed10823918). Catalyzes the hydroxylation of carbon hydrogen bonds of at RA primarily at C-4 (PubMed10823918, PubMed22020119). Essential for postnatal survival (by similarity). Plays a central role in germ cell development acts by degrading RA in the developing testis, preventing STRA8 expression, thereby leading to delay of meiosis (by similarity). Required for the maintenance of the undifferentiated state of male germ cells during embryonic development in Sertoli cells, inducing arrest in G0 phase of the cell cycle and preventing meiotic entry (by similarity). Plays a role in skeletal development, both at the level of patterning and in the ossification of bone and the establishment of some synovial joints (PubMed22019272). {ECO0000250|UniProtKBQ811W2, ECO0000269|PubMed10823918, ECO0000269|PubMed22019272, ECO0000269|PubMed22020119}. FUNCTION Has also a significant activity in oxidation of tazarotenic acid and may therefore metabolize that xenobiotic in vivo. {ECO0000269|PubMed26937021}.

Lilrb4: Human Uniprot function (Human LILRB4): Receptor for class I MHC antigens. Recognizes a broad spectrum of HLA-A, HLA-B, HLA-C, and HLA-G alleles. Involved in the downregulation of the immune response and the development of tolerance, e.g., toward transplants. Interferes with TNFRSF5-signaling and NF-kappa-B upregulation. Inhibits receptor-mediated phosphorylation of cellular proteins and mobilization of intracellular calcium ions. {ECO0000269|PubMed11875462, ECO0000269|PubMed9151699}.

No liver genes in male or female rats had estimated BMD median values <0.023 mg/kg. In male rats, the most sensitive upregulated genes with a calculated BMD were Akr7a3 (aldo-keto reductase family 7 member A3), Ephx1 (epoxide hydrolase 1), Me1 (malic enzyme 1), Cyp4a1 (cytochrome P450, family 4, subfamily a, polypeptide 1), Anxa7 (annexin A7), and Slc17a3 (solute carrier family 17 member 3) with BMDs (BMD_L_s) of 2.192 (1.593), 2.467 (1.828), 3.531 (2.076), 4.588 (2.345), 4.660 (2.970), and 5.147 (3.485) mg/kg, respectively. The most sensitive genes exhibiting a decrease in expression were Pck1 (phosphoenolpyruvate carboxykinase 1), A2m (alpha-2-macroglobulin), Loc100911545/A2m (alpha-2-macroglobulin), and Zfp354a (zinc finger protein 354A) with BMDs (BMD_L_s) of 1.149 (0.548), 1.733 (0.972), 1.733 (0.972), and 1.785 (0.579) mg/kg, respectively.

In female rats, all 10 of the most sensitive liver genes were upregulated. These genes were Abcc3 (ATP-binding cassette subfamily C member 3), Gsta2 (glutathione S-transferase alpha 2), Gsta5 (glutathione S-transferase alpha 5), Ephx1 (epoxide hydrolase 1), Akr7a3 (aldo-keto reductase family 7 member A3), Ehhadh (enoyl-CoA hydratase and 3-hydroxyacyl CoA dehydrogenase), Pir (pirin), Gclm (glutamate-cysteine ligase, modifier subunit), Dao (D-amino-acid oxidase), and Me1 (malic enzyme 1) with BMDs (BMD_L_s) of 5.019 (2.945), 5.153 (2.796), 5.153 (2.796), 5.233 (3.072), 5.348 (3.082), 5.355 (3.108), 6.124 (2.642), 8.034 (3.552), 8.071 (2.669), and 8.192 (2.618) mg/kg, respectively.

None of the top 10 most sensitive kidney genes in male rats had estimated BMD median values <0.023 mg/kg. The most sensitive upregulated genes with a calculated BMD were Ugt2b7 (UDP-glucuronosyltransferase family 2 member B7), Ephx1 (epoxide hydrolase 1), Adgre1 (adhesion G protein-coupled receptor E1), Map2 (microtubule-associated protein 2), Slc6a1 (solute carrier family 6 member 1), Naaa (N-acylethanolamine acid amidase), Il1b (interleukin 1 beta), Cyp24a1 (cytochrome P450, family 24, subfamily a, polypeptide 1), and Nsg1 (neuronal vesicle trafficking associated 1) with BMDs (BMD_L_s) of 4.139 (1.398), 12.509 (3.282), 119.065 (89.170), 145.437 (104.718), 145.445 (104.722), 151.002 (107.821), 153.991 (109.464), 189.111 (127.579), and 216.472 (166.237) mg/kg, respectively. One gene, Top2a (DNA topoisomerase II alpha), was downregulated with a BMD (BMD_L_) of 203.468 (108.442) mg/kg.

The most sensitive kidney gene in female rats, exhibiting a decrease in expression, was Mrc1 (mannose receptor, C-type 1) with an estimated BMD median value <0.023 mg/kg. There were no other downregulated genes. The most sensitive upregulated genes with a calculated BMD were Ckap2 (cytoskeleton associated protein 2), Ugt2b37 (UDP-glucuronosyltransferase 2 family, member 37), Slc51a (solute carrier family 51 subunit alpha), Ugt2b7 (UDP-glucuronosyltransferase family 2 member B7), Bbox1 (gamma-butyrobetaine hydroxylase 1), Adgre1 (adhesion G protein-coupled receptor E1), Clec4a (C-type lectin domain family 4, member A), Cyp26b1 (cytochrome P450, family 26, subfamily b, polypeptide 1), and Lilrb4 (leukocyte immunoglobulin like receptor B4) with BMDs (BMD_L_s) of 2.608 (0.997), 32.501 (7.520), 37.134 (11.007), 54.314 (15.595), 61.319 (39.473), 61.524 (39.671), 82.466 (47.872), 238.250 (181.323), and 350.991 (212.248) mg/kg, respectively.