# Background

1,1,2,2-Tetrahydroperfluoro-1-dodecanol (10:2 fluorotelomer alcohol) (CASRN: 865-86-1, U.S. Environmental Protection Agency [EPA] Chemical Dashboard: DTXSID2029905,^1^ PubChem CID: 70083,^2^ European Committee Number: 212-748-7^3^) is a member of the per- and polyfluoroalkyl class of compounds that are associated with numerous toxicological effects.^4^ There is widespread human exposure to this class of compounds.^5,6^ The predicted upper 95th percentile human exposure to 1,1,2,2-tetrahydroperfluoro-1-dodecanol is 0.00112 mg/kg body weight/day.^7^ This dose level is within 100-fold of the lowest dose tested in this study. A review of the existing literature failed to identify any in vivo toxicological information on 1,1,2,2-tetrahydroperfluoro-1-dodecanol, and according to the EPA Chemical Dashboard, no quantitative risk assessment values or quantitative hazard values exist for this test article.^8^ Publicly available information on 1,1,2,2-tetrahydroperfluoro-1-dodecanol can be found in PubChem^2^ and the EPA Chemical Dashboard.^1^

Recent studies have demonstrated that short-term in vivo gavage studies coupled with transcriptomics on select target organs can be used to estimate a biological potency that provides a reasonable approximation of toxicological potency in long-term guideline toxicological assessments.^9^ To estimate biological potency and gain insight into the nature of biological changes elicited by 1,1,2,2-tetrahydroperfluoro-1-dodecanol, the National Institute of Environmental Health Sciences performed a short-term in vivo biological potency study of male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. The results of this study are presented in this report.