# Appendix B Animal Identifiers

Table B-1 Animal Numbers and FASTQ Data File Names

Animal Number | Sex | Group | Dose (mg/kg) | Survived to Study Termination | Tissue | FASTQ File ID
211 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-211
211 | Male | Vehicle control | 0 | Yes | Liver | Plate11-211
212 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-212
212 | Male | Vehicle control | 0 | Yes | Liver | Plate11-212
213 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-213
213 | Male | Vehicle control | 0 | Yes | Liver | Plate9-213
214 | Male | Vehicle control | 0 | Yes | Kidney | Plate12-214^a^
214 | Male | Vehicle control | 0 | Yes | Liver | Plate11-214
215 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-215
215 | Male | Vehicle control | 0 | Yes | Liver | Plate9-215
216 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-216
216 | Male | Vehicle control | 0 | Yes | Liver | Plate9-216
217 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-217
217 | Male | Vehicle control | 0 | Yes | Liver | Plate11-217
218 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-218
218 | Male | Vehicle control | 0 | Yes | Liver | Plate9-218
219 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-219
219 | Male | Vehicle control | 0 | Yes | Liver | Plate9-219
220 | Male | Vehicle control | 0 | Yes | Kidney | Plate10-220
220 | Male | Vehicle control | 0 | Yes | Liver | Plate9-220
221 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-221
221 | Female | Vehicle control | 0 | Yes | Liver | Plate9-221
222 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-222
222 | Female | Vehicle control | 0 | Yes | Liver | Plate9-222
223 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-223
223 | Female | Vehicle control | 0 | Yes | Liver | Plate9-223
224 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-224
224 | Female | Vehicle control | 0 | Yes | Liver | Plate9-224
225 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-225
225 | Female | Vehicle control | 0 | Yes | Liver | Plate9-225
226 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-226
226 | Female | Vehicle control | 0 | Yes | Liver | Plate9-226
227 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-227
227 | Female | Vehicle control | 0 | Yes | Liver | Plate9-227
228 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-228
228 | Female | Vehicle control | 0 | Yes | Liver | Plate9-228
229 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-229
229 | Female | Vehicle control | 0 | Yes | Liver | Plate9-229
230 | Female | Vehicle control | 0 | Yes | Kidney | Plate10-230
230 | Female | Vehicle control | 0 | Yes | Liver | Plate9-230
231 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate10-231
231 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate9-231
232 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate10-232
232 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate9-232
233 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate10-233
233 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate9-233
234 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate10-234
234 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate9-234
235 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate10-235
235 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate11-235
236 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate10-236
236 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate9-236
237 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate12-237^a^
237 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate9-237
238 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate12-238^a^
238 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate11-238
239 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate10-239
239 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate9-239
240 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Kidney | Plate10-240
240 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.07 | Yes | Liver | Plate9-240
241 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-241
241 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-241
242 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-242
242 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate11-242
243 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-243
243 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-243
244 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-244
244 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-244
245 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-245
245 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-245
246 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-246
246 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-246^b^
247 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-247
247 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-247
248 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-248
248 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-248
249 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-249
249 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-249
250 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Kidney | Plate10-250
250 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.2 | Yes | Liver | Plate9-250
251 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate10-251
251 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-251
252 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate10-252
252 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-252
253 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate10-253
253 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate11-253
254 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate10-254
254 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-254
255 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate12-255^a^
255 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-255
256 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate10-256
256 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-256
257 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate12-257^a^
257 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-257
258 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate10-258
258 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-258
259 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate10-259
259 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-259
260 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Kidney | Plate10-260
260 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 0.7 | Yes | Liver | Plate9-260
261 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-261
261 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate11-261
262 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-262
262 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate9-262
263 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-263
263 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate9-263
264 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate12-264^a^
264 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate9-264
265 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-265
265 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate9-265
266 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-266
266 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate9-266
267 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-267
267 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate9-267
268 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-268
268 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate11-268
269 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-269
269 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate9-269
270 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Kidney | Plate10-270
270 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 2.0 | Yes | Liver | Plate9-270
271 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-271
271 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-271
272 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-272
272 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-272
273 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate12-273^a^
273 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-273
274 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-274
274 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate11-274
275 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-275
275 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-275
276 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-276
276 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-276
277 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-277
277 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-277
278 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-278
278 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-278
279 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-279
279 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-279
280 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Kidney | Plate10-280
280 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 6.0 | Yes | Liver | Plate9-280
281 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate12-281^a^
281 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-281
282 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate10-282
282 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-282
283 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate12-283^a^
283 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-283
284 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate10-284
284 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-284
285 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate10-285
285 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate11-285
286 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate10-286
286 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-286
287 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate10-287
287 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-287
288 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate10-288
288 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-288
289 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate12-289^a^
289 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-289
290 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Kidney | Plate10-290
290 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 18.0 | Yes | Liver | Plate9-290
291 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate12-291^a^
291 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate9-291
292 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate12-292^a^
292 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate9-292
293 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate12-293^a^
293 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate11-293
294 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate10-294
294 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate9-294
295 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate10-295
295 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate9-295
296 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate10-296
296 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate11-296
297 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate10-297
297 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate9-297
298 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate10-298
298 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate9-298
299 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate10-299
299 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate9-299
300 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Kidney | Plate10-300
300 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 55.0 | Yes | Liver | Plate9-300
301 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate10-301
301 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate11-301
302 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate10-302
302 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate9-302
303 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate10-303
303 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate11-303
304 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate10-304
304 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate9-304
305 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate12-305^a^
305 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate9-305
306 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate12-306^a^
306 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate9-306
307 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate12-307^a^
307 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate9-307
308 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate10-308
308 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate9-308
309 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate10-309
309 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate9-309
310 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Kidney | Plate10-310
310 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 160.0 | Yes | Liver | Plate9-310
311 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate10-311
311 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate9-311
312 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate12-312^a^
312 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate9-312
313 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate10-313
313 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate11-313
314 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate12-314^a^
314 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate11-314
315 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate12-315^a^
315 | Male | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate9-315
316 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate10-316
316 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate9-316
317 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate12-317^a^
317 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate11-317
318 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate10-318
318 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate9-318
319 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate10-319
319 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate9-319
320 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Kidney | Plate10-320
320 | Female | 1,1,2,2-Tetrahydroperfluoro-1-dodecanol | 475.0 | Yes | Liver | Plate11-320

^a^ Removed due to plate/batch effect.

^b^ Removed due to principal component analysis/hierarchical cluster analysis outlier.