# Appendix A Internal Dose Assessment

## A.1 Quantitation of 1,1,2,2-Tetrahydroperfluoro-1-dodecanol in Plasma

Quantification of 1,1,2,2-tetrahydroperfluoro-1-dodecanol (10:2 fluorotelomer alcohol) in plasma samples was completed by RTI International (Research Triangle Park, NC). A gas chromatography with mass spectrometry detection (GC/MS) method was developed to determine 1,1,2,2-tetrahydroperfluoro-1-dodecanol concentrations in rat plasma. A six-point matrix calibration curve, in the range of 10–1,000 ng/mL, was prepared by adding 10 µL of an appropriate spiking solution (1,1,2,2-tetrahydroperfluoro-1-dodecanol in ethyl acetate) and 20 µL of an internal standard solution (2-perfluorodecyl-[1,1-2H2]-[1,2-13e2]-ethanol in methanol) to 100 µL of control matrix (adult male Sprague Dawley rat plasma). Quality control (QC) samples were prepared similarly at a target concentration of 100 ng/mL in plasma. Blanks and study samples were prepared like calibration standards, except 10 µL of ethyl acetate was used in place of spiking solution. All samples were then extracted by adding 300 µL of ethyl acetate, vortex mixing, and centrifuging for 5 minutes. The organic layer of each sample was collected for analysis.

All samples were analyzed using an Agilent 7890A GC with an Agilent 5975C mass selective detector (Santa Clara, CA). A J&W DB-WAX column (30 m × 0.32 mm inner diameter) with a 0.50 µm film was used with a Helium carrier gas. A flow rate of 2.0 mL/min was run with a temperature program starting at 50°C for 2 minutes, a linear ramp at 15°C/min to 230°C, and held at 230°C for 2 minutes. Electron impact ionization was used with an ionization voltage of 70 eV and a source temperature of 230°C. Single ion monitoring was used at m/z 95 (1,1,2,2-tetrahydroperfluoro-1-dodecanol quantitation ion) and m/z 509 (internal standard).

A linear regression with 1/X^2^ weighting was used to relate peak area ratios of analyte to internal standard and analyte concentrations. Calibration curves were linear (r > 0.99). The lower limit of quantitation (LOQ) for 1,1,2,2-tetrahydroperfluoro-1-dodecanol in rat plasma was 10.0 ng/mL. For QC samples, the accuracy measured as percent relative error was within ±16.7% of the nominal concentration. The concentrations (ng/mL) of 1,1,2,2-tetrahydroperfluoro-1-dodecanol in study samples were calculated using peak area ratios and the regression equation. All values above LOQ were reported.