# Publication Details

Publisher: National Institute of Environmental Health Sciences

Publishing Location: Research Triangle Park, NC

ISSN: 2768-5632

DOI: https://doi.org/10.22427/NIEHS-07

Report Series: NIEHS Report Series

Report Series Number: 07

Official citation: Auerbach SS, Aillon KL, Ballin JD, Collins BJ, Cora MC, Duncan NS, Fostel JM, Liu YF, Luh J, Machesky NJ, Pickett SJ, Roberts GK, Shipkowski KA, Skowronek AJ, Smith LL, Sparrow BR, Toy H, Waidyanatha S, Watson ATD. 2023. NIEHS report on the in vivo repeat dose biological potency study of 6:1 fluorotelomer alcohol (CASRN 375-82-6) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (gavage studies). Research Triangle Park, NC: National Institute of Environmental Health Sciences. NIEHS Report 07.