# References

1 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: 6:1 Fluorotelomer alcohol 375-82-6 | DTXSID00190950. 2021. https://comptox.epa.gov/dashboard/chemical/details/DTXSID00190950
2 National Center for Biotechnology Information (NCBI). PubChem Compound Summary for CID 550386, 1H,1H-Perfluoro-1-heptanol. 2021. https://pubchem.ncbi.nlm.nih.gov/compound/1H_1H-Perfluoro-1-heptanol
3 European Chemicals Agency (ECHA). Substance Infocard: 2,2,3,3,4,4,5,5,6,6,7,7,7-Tridecafluoroheptan-1-ol. 2021. https://echa.europa.eu/substance-information/-/substanceinfo/100.006.179
4 Fenton SE, Ducatman A, Boobis A, DeWitt JC, Lau C, Ng C, Smith JS, Roberts SM. Per- and polyfluoroalkyl substance toxicity and human health review: Current state of knowledge and strategies for informing future research. Environ Toxicol Chem. 2021; 40(3):606–630. 10.1002/etc.4890 33017053
5 Domingo JL, Nadal M. Human exposure to per- and polyfluoroalkyl substances (PFAS) through drinking water: A review of the recent scientific literature. Environ Res. 2019; 177:108648. 10.1016/j.envres.2019.108648 31421451
6 Domingo JL, Nadal M. Per- and polyfluoroalkyl substances (PFASs) in food and human dietary intake: A review of the recent scientific literature. J Agric Food Chem. 2017; 65(3):533–543. 10.1021/acs.jafc.6b04683 28052194
7 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: 6:1 Fluorotelomer alcohol 375-82-6 | DTXSID00190950: Exposure predictions. 2021. https://comptox.epa.gov/dashboard/chemical/exposure-predictions/DTXSID00190950
8 U.S. Environmental Protection Agency (USEPA). CompTox Chemicals Dashboard: 6:1 Fluorotelomer alcohol 375-82-6 | DTXSID00190950: Executive summary. 2021. https://comptox.epa.gov/dashboard/chemical/executive-summary/DTXSID00190950
9 Gwinn WM, Auerbach SS, Parham F, Stout MD, Waidyanatha S, Mutlu E, Collins B, Paules RS, Merrick BA, Ferguson S, et al. Evaluation of 5-day in vivo rat liver and kidney with high-throughput transcriptomics for estimating benchmark doses of apical outcomes. Toxicol Sci. 2020; 176(2):343–354. 10.1093/toxsci/kfaa081 32492150
10 Mansouri K, Karmaus AL, Fitzpatrick J, Patlewicz G, Pradeep P, Alberga D, Alepee N, Allen TEH, Allen D, Alves VM, et al. CATMoS: Collaborative Acute Toxicity Modeling Suite. Environ Health Perspect. 2021; 129(4):47013. 10.1289/EHP8495 33929906
11 Mansouri K, Grulke CM, Judson RS, Williams AJ. OPERA models for predicting physicochemical properties and environmental fate endpoints. J Cheminform. 2018; 10(1):10. 10.1186/s13321-018-0263-1 29520515
12 Patlewitz G. Personal Communication: EPA Point of Departure Estimate. 2021.
13 Waidyanatha S, Fletcher BL, Fernando RA, Cora MC, Silinski MAR. Development and validation of an ultraperformance liquid chromatography-tandem mass spectrometry method for quantitation of total 3,3′,5-triiodo-L-thyronine and 3,3′,5,5′-tetraiodo-L-thyronine in rodent serum. Anal Lett. 2022; 55(5):796–811. 10.1080/00032719.2021.1967969 35812014
14 Langmead B, Trapnell C, Pop M, Salzberg SL. Ultrafast and memory-efficient alignment of short DNA sequences to the human genome. Genome Biol. 2009; 10(3):R25. 10.1186/gb-2009-10-3-r25 19261174
15 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
16 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
17 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
18 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
19 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
20 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
21 Dixon WJ, Massey FJ. Introduction to Statistical Analysis. New York: McGraw-Hill; 1951.
22 U.S. Environmental Protection Agency (USEPA). Benchmark dose technical guidance. Washington, DC: U.S. Environmental Protection Agency, Risk Assessment Forum; 2012. https://www.epa.gov/sites/production/files/2015-01/documents/benchmark_dose_guidance.pdf
23 Wignall JA, Shapiro AJ, Wright FA, Woodruff TJ, Chiu WA, Guyton KZ, Rusyn I. Standardizing benchmark dose calculations to improve science-based decisions in human health assessments. Environ Health Perspect. 2014; 122(5):499–505. 10.1289/ehp.1307539 24569956
24 National Toxicology Program (NTP). NTP research report on National Toxicology Program approach to genomic dose-response modeling. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2018. NTP Research Report No. 5.
25 Shi L, Jones WD, Jensen RV, Harris SC, Perkins RG, Goodsaid FM, Guo L, Croner LJ, Boysen C, Fang H, et al. The balance of reproducibility, sensitivity, and specificity of lists of differentially expressed genes in microarray studies. BMC Bioinformatics. 2008; 9:S10. 10.1186/1471-2105-9-S9-S10 18793455
26 Auerbach SS, Ballin JD, Blake JC, Browning DB, Collins BJ, Cora MC, Fernando RA, Fostel JM, Liu YF, Luh J, et al. NIEHS report on the in vivo repeat dose biological potency study of perfluorohexanesulfonamide (CASRN 41997-13-1) in Sprague Dawley (Hsd:Sprague Dawley® SD®) rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institute of Environmental Health Sciences; 2023. NIEHS Report 10. 10.22427/NIEHS-10
27 Auerbach SS, Ballin JD, Blake JC, Browning DB, Collins BJ, Cora MC, Fernando RA, Fostel JM, Liu YF, Luh J, et al. NIEHS report on the in vivo repeat dose biological potency study of 1,1,2,2-tetrahydroperfluoro-1-dodecanol (CASRN 865-86-1) in Sprague Dawley (Hsd:Sprague Dawley® SD®) rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institute of Environmental Health Sciences; 2023. NIEHS Report 08. 10.22427/NIEHS-08
28 Auerbach SS, Aillon KL, Ballin JD, Collins BJ, Cora MC, Duncan NS, Fostel JM, Kerns SP, Liu YF, Luh J, et al. NIEHS report on the in vivo repeat dose biological potency study of 2,3-benzofluorene (CASRN 243-17-4) in Sprague Dawley (Hsd:Sprague Dawley® SD®) rats (gavage studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institute of Environmental Health Sciences; 2023. NIEHS Report 09. 10.22427/NIEHS-09
29 National Toxicology Program (NTP). NIEHS 07: Chemical Effects in Biological Systems (CEBS) data repository. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2023.
30 Geneontology. The gene ontology resource. 2021. http://geneontology.org/
31 Medical College of Wisconsin. Rat Genome Database. 2021. https://rgd.mcw.edu/
32 UniProt. UniProtKB results. 2021. https://www.uniprot.org/uniprot/
33 Entrez Gene. Gene. 2021. https://www.ncbi.nlm.nih.gov/gene/
34 Thomas RS, Allen BC, Nong A, Yang L, Bermudez E, Clewell HJ 3rd, Andersen ME. A method to integrate benchmark dose estimates with genomic data to assess the functional effects of chemical exposure. Toxicol Sci. 2007; 98(1):240–248. 10.1093/toxsci/kfm092 17449896