# Summary

6:1 Fluorotelomer alcohol (6:1 FTOH) is a member of the per- and polyfluoroalkyl class of compounds to which humans are widely exposed. A review of the literature did not identify toxicological data for estimating the potential adverse health effects of 6:1 FTOH. This study used a transcriptomic approach and standard toxicological endpoints to estimate the in vivo biological potency of 6:1 FTOH.

A subset of standard toxicological endpoints (albumin/globulin ratio, globulin concentration, total triiodothyronine concentration, relative right kidney weight, and reticulocyte count in male rats; cholesterol concentration in female rats) exhibited benchmark dose (BMD) values much lower than would be expected given the endpoint-specific no-observed-effect level and lowest-observed-effect level values. Expert review of the data suggests that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and were likely an anomalous product of the BMD modeling approach.

Taking this into account, the most sensitive apical endpoint in male rats was a decrease in total thyroxine concentration with an estimated BMD and benchmark dose lower confidence limit (BMD_L_) of 3.19 (1.774) mg/kg. Increases in relative liver weight and albumin concentration were the next most sensitive apical endpoint changes observed in male rats with BMDs (BMD_L_s) of 12.122 (9.527) and 13.365 (4.084) mg/kg, respectively. In female rats, the most sensitive apical endpoint was a decrease in reticulocyte count with a BMD (BMD_L_) of 15.578 (3.622) mg/kg. The next most sensitive apical endpoints observed were an increase in large unstained cell count and a decrease in total triiodothyronine concentration with BMDs (BMD_L_s) of 54.339 (15.759) and 161.48 (122.215) mg/kg, respectively.

Gene set-level transcriptional changes in the liver following 6:1 FTOH exposure were estimated to occur at a BMD (BMD_L_) as low as 0.368 (0.103) mg/kg in male rats, corresponding to cellular response to epidermal growth factor stimulus (GO:0071364), and as low as 44.730 (22.260) mg/kg in female rats, corresponding to positive regulation of phagocytosis (GO:0050766). The most sensitive liver gene for which a reliable BMD could be determined was Myc, with a BMD (BMD_L_) of 0.186 (0.103) mg/kg, in male rats and Gdf15, with a BMD (BMD_L_) of 17.724 (8.696) mg/kg, in female rats.

Gene set-level transcriptional changes in the kidney were estimated to occur at a BMD (BMD_L_) as low as 1.346 (0.541) mg/kg in male rats, corresponding to acetyl-CoA metabolic process (GO:0006084), and as low as 21.079 (13.312) mg/kg in female rats, corresponding to fatty acid beta-oxidation (GO:0006635). Two kidney gene sets in male rats had BMD estimates below the lower limit of extrapolation (<0.050 mg/kg). The most sensitive kidney gene in male rats for which a reliable BMD could be determined was Decr1 with a BMD (BMD_L_) of 0.680 (0.505) mg/kg. In female rats, one kidney gene exhibited changes in expression at dose levels below which a reliable estimate of potency could be achieved (<0.050 mg/kg). The most sensitive gene in female rats for which a reliable BMD could be determined was Eci1 with a BMD (BMD_L_) of 9.486 (7.353) mg/kg.

Under the conditions of this short-duration transcriptomic study in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats, the most sensitive point of departure with a reliable estimate in male rats was a transcriptional change in a gene, Myc, with a BMD (BMD_L_) of 0.186 (0.103) mg/kg. Gene set transcriptional changes provided potency estimates slightly higher than Myc, while apical endpoints provided potency estimates higher than Myc. In female rats, the most sensitive point of departure with a reliable estimate was a transcriptional change in a gene, Eci1, with a BMD (BMD_L_) of 9.486 (7.353) mg/kg. Gene set transcriptional changes and apical endpoints provided potency estimates slightly higher than Eci1. Follow-up studies that investigate transcriptional changes at lower doses will be a useful future direction to determine the biological potency of 6:1 FTOH more accurately.