# Results

## Animal Condition, Body Weights, and Organ Weights

Male and female rats administered 333 or 1,000 mg/kg body weight (mg/kg) of 6:1 fluorotelomer alcohol (6:1 FTOH) began exhibiting signs of overt toxicity on study days 1–2, which included red discharge from eyes, slow breathing, ruffled or unkempt coat, cold to touch, soft feces, hunched posture, prone positioning, wet urogenital area, and lethargy (Appendix F). The 1,000 mg/kg male rats exhibited high mortality, with three rats found dead on study day 4 and one male rat moribund on study day 1 and euthanized at that time due to severe toxicity. No significant changes in terminal body weight for male or female rats occurred with exposure to 6:1 FTOH (Table 2).

Table 2 Summary of Body Weights of Male and Female Rats Administered 6:1 Fluorotelomer Alcohol for Five Days

Study Day^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
0 | 299.9 ± 6.3 | 307.1 ± 5.6 | 300.7 ± 4.3 | 307.3 ± 8.3 | 295.0 ± 10.2 | 304.3 ± 2.6 | 300.7 ± 11.9 | 303.8 ± 9.1 | 306.4 ± 3.4 | 298.7 ± 7.3 | ND | ND
5 | 315.0 ± 6.8 | 320.7 ± 5.3 | 310.7 ± 5.1 | 324.0 ± 10.6 | 310.8 ± 9.7 | 317.0 ± 2.4 | 316.2 ± 12.6 | 319.4 ± 10.3 | 304.4 ± 4.9 | 295.8^c^ | ND | ND
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
0 | 213.2 ± 6.4 | 216.5 ± 4.8 | 213.1 ± 6.6 | 215.7 ± 4.6 | 209.1 ± 6.4 | 209.8 ± 2.8 | 218.0 ± 5.3 | 211.5 ± 4.1 | 210.5 ± 4.8 | 215.1 ± 2.8 | ND | ND
5 | 218.8 ± 7.0 | 224.9 ± 8.6 | 218.9 ± 6.0 | 219.1 ± 6.6 | 213.9 ± 6.1 | 219.3 ± 2.9 | 222.0 ± 5.5 | 216.2 ± 3.9 | 219.7 ± 5.7 | 222.8 ± 3.0 | ND | ND

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; ND = not determined.

^a^ Data are displayed as mean ± standard error of the mean; body weight data are presented in grams.

^b^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^c^ One male rat was moribund and euthanized on study day 1 and three male rats were found dead on study day 4. Body weight data from the remaining male rat were excluded from statistical analysis and BMD calculations.

In male rats at study termination, a significant increase in absolute and relative liver weights occurred in dose groups ≥37 mg/kg; both endpoints had positive trends (Table 3). The benchmark doses (benchmark dose lower confidence limits)—BMDs (BMD_L_s)—for increased absolute and relative liver weights were 28.507 (15.286) and 12.122 (9.527) mg/kg, respectively. Relative left kidney weight showed a significant pairwise increase at 333 mg/kg with a positive trend; the BMD (BMD_L_) was 20.907 (4.272) mg/kg. Relative right kidney weight had significant trend and pairwise comparisons. Although a BMD was estimated for relative right kidney weight, its value was much lower (approximately 25- to 80-fold) than would be expected given the endpoint-specific no-observed-effect level (NOEL) and lowest-observed-effect level (LOEL) values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach. The BMDs for all organ weights were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the estimated BMD values). Significant trend and pairwise comparisons were not observed in absolute left or right kidney weights or absolute or relative heart weights (Appendix F).

Table 3 Summary of Select Organ Weights of Male and Female Rats Administered 6:1 Fluorotelomer Alcohol for Five Days

Endpoint^a,b,c^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 1^d^ | NA | NA
Terminal Body Wt. (g) | 315.0 ± 6.8 | 320.7 ± 5.3 | 310.7 ± 5.1 | 324.0 ± 10.6 | 310.8 ± 9.7 | 317.0 ± 2.4 | 316.2 ± 12.6 | 319.4 ± 10.3 | 304.4 ± 4.9 | 295.8 | ND | ND
Right Kidney
Relative (mg/g)^e^ | 3.10 ± 0.04** | 3.16 ± 0.04 | 3.16 ± 0.13 | 3.19 ± 0.12 | 3.43 ± 0.08 | 3.20 ± 0.06 | 3.50 ± 0.04** | 3.41 ± 0.10** | 3.50 ± 0.15** | 3.45 | 0.464^f^ | 0.082^f^
Left Kidney
Relative (mg/g) | 3.10 ± 0.06** | 3.21 ± 0.03 | 3.15 ± 0.08 | 3.11 ± 0.07 | 3.24 ± 0.07 | 3.20 ± 0.05 | 3.37 ± 0.05 | 3.19 ± 0.09 | 3.44 ± 0.14** | 3.28 | 20.907 | 4.272
Liver
Absolute (g) | 11.78 ± 0.39** | 12.05 ± 0.23 | 11.83 ± 0.52 | 12.37 ± 0.65 | 12.29 ± 0.59 | 12.12 ± 0.34 | 13.47 ± 0.55** | 16.63 ± 0.55** | 18.04 ± 0.20** | 17.87 | 28.507 | 15.286
Relative (mg/g) | 37.37 ± 0.80** | 37.58 ± 0.63 | 38.03 ± 1.21 | 38.11 ± 1.05 | 39.50 ± 1.06 | 38.26 ± 1.06 | 42.60 ± 0.63** | 52.12 ± 1.06** | 59.30 ± 0.73** | 60.41 | 12.122 | 9.527
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Terminal Body Wt. (g) | 218.8 ± 7.0 | 224.9 ± 8.6 | 218.9 ± 6.0 | 219.1 ± 6.6 | 213.9 ± 6.1 | 219.3 ± 2.9 | 222.0 ± 5.5 | 216.2 ± 3.9 | 219.7 ± 5.7 | 222.8 ± 3.0 | ND | ND
Liver
Absolute (g) | 7.92 ± 0.41** | 8.47 ± 0.61 | 8.21 ± 0.22 | 7.80 ± 0.38 | 7.87 ± 0.46 | 8.15 ± 0.21 | 8.16 ± 0.24 | 7.87 ± 0.13 | 9.22 ± 0.18** | 12.02 ± 0.17** | NVM | NVM
Relative (mg/g) | 36.00 ± 0.72** | 37.50 ± 1.29 | 37.54 ± 0.39 | 35.52 ± 0.64 | 36.67 ± 1.13 | 37.15 ± 0.72 | 36.76 ± 0.46 | 36.40 ± 0.34 | 42.01 ± 0.50** | 53.98 ± 0.92** | NVM | NVM

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; ND = not determined; NVM = nonviable model.

^a^ Descriptions of organ weight endpoints and changes are provided in Appendix E.

^b^ Data are displayed as mean ± standard error of the mean.

^c^ Statistical analysis performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests.

^d^ One male rat was moribund and euthanized on study day 1 and three male rats were found dead on study day 4. Body weight and organ weight data from the remaining male rat were excluded from statistical analysis and BMD calculations.

^e^ Relative organ weights (organ weight-to-body weight ratios) are given as mg organ weight/g body weight.

^f^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

In female rats at study termination, a significant increase in absolute and relative liver weights occurred in the 333 and 1,000 mg/kg groups and both endpoints had positive trends (Table 3); BMDs (BMD_L_s) for increased absolute and relative liver weights were not determined because no viable models were available. Significant trend and pairwise comparisons were not observed in absolute or relative heart, right kidney, or left kidney weights (Appendix F).

## Clinical Pathology

In male rats, triglyceride and cholesterol concentrations were significantly decreased in dose groups ≥12 mg/kg and ≥37 mg/kg, respectively; BMDs (BMD_L_s) were not determined for these two endpoints because no viable models were available (Table 4). Creatinine concentration was significantly increased in the 333 mg/kg male rats with a BMD (BMD_L_) of 97.38 (32.365) mg/kg. Albumin concentration was significantly increased in the ≥37 mg/kg male rats with a BMD (BMD_L_) of 13.365 (4.084) mg/kg. Alanine aminotransferase activity was significantly increased in male rats in the ≥37 mg/kg groups and aspartate aminotransferase (AST) activity was significantly increased in the ≥111 mg/kg groups with BMDs (BMD_L_s) of 36.116 (21.468) and 28.117 (19.352) mg/kg, respectively. Alkaline phosphatase activity was significantly increased in the 333 mg/kg male rat group with a BMD (BMD_L_) of 89.383 (74.114) mg/kg. In female rats, AST activity was significantly increased in the 1,000 mg/kg group with a BMD (BMD_L_) of 497.046 (340.458) mg/kg. Globulin concentration in male rats, albumin/globulin (A/G) ratio in male rats, and cholesterol concentration in female rats had significant trend and pairwise comparisons. Although a BMD was estimated for each of these endpoints, these values were much lower (approximately 10- to 35-fold, 10- to 25-fold, and 70- to 210-fold for globulin concentration in male rats, A/G ratio in male rats, and cholesterol concentration in female rats, respectively) than would be expected given the endpoint-specific NOEL and LOEL values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach. The BMDs for all clinical pathology endpoints were reviewed by a subject matter expert for anomalous modeling results (i.e., when the traditional statistics are notably different from the estimated BMD values).

Table 4 Summary of Select Clinical Chemistry Data for Male and Female Rats Administered 6:1 Fluorotelomer Alcohol for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 10 | 5 | 5 | 5 | 4^c^ | 5 | 5 | 5 | 5 | 1^d^ | NA | NA
Creatinine (mg/dL) | 0.41 ± 0.01** | 0.42 ± 0.02 | 0.42 ± 0.02 | 0.42 ± 0.02 | 0.43 ± 0.03 | 0.38 ± 0.02 | 0.44 ± 0.02 | 0.46 ± 0.02 | 0.50 ± 0.03** | 0.50 | 97.38 | 32.365
Globulin (g/dL) | 1.95 ± 0.03** | 1.96 ± 0.05 | 2.10 ± 0.06 | 2.28 ± 0.16 | 2.03 ± 0.09 | 1.70 ± 0.03* | 1.76 ± 0.05* | 1.40 ± 0.10** | 1.34 ± 0.14** | 1.20 | 0.322^e^ | 0.188^e^
A/G Ratio | 2.29 ± 0.06** | 2.28 ± 0.06 | 2.13 ± 0.04 | 2.03 ± 0.13 | 2.27 ± 0.08 | 2.69 ± 0.07* | 2.71 ± 0.06* | 3.50 ± 0.31** | 3.75 ± 0.31** | 3.92 | 0.456^e^ | 0.237^e^
Albumin (g/dL) | 4.46 ± 0.06** | 4.46 ± 0.07 | 4.46 ± 0.08 | 4.54 ± 0.06 | 4.58 ± 0.05 | 4.56 ± 0.05 | 4.76 ± 0.07** | 4.78 ± 0.07** | 4.86 ± 0.11** | 4.70 | 13.365 | 4.084
Cholesterol (mg/dL) | 106.6 ± 3.8** | 107.6 ± 1.8 | 103.2 ± 2.2 | 114.0 ± 15.8 | 92.8 ± 5.4 | 89.6 ± 6.9 | 84.8 ± 4.2** | 75.6 ± 2.8** | 69.2 ± 4.9** | 50.0 | NVM | NVM
Triglycerides (mg/dL) | 99.9 ± 9.9** | 85.6 ± 9.9 | 107.4 ± 19.0 | 118.4 ± 35.2 | 82.0 ± 3.0 | 48.8 ± 8.3** | 66.8 ± 14.0* | 53.0 ± 2.9** | 58.6 ± 14.8* | 111.0 | NVM | NVM
Alanine Aminotransferase (IU/L) | 61.2 ± 3.6** | 64.0 ± 5.2 | 55.0 ± 2.6 | 58.8 ± 3.2 | 70.5 ± 4.3 | 57.4 ± 3.7 | 72.2 ± 3.1* | 110.2 ± 19.6* | 209.2 ± 67.2** | 134.0 | 36.116 | 21.468
Alkaline Phosphatase (IU/L) | 302.2 ± 19.9**^f^ | 315.8 ± 18.4^f^ | 277.2 ± 11.1 | 322.8 ± 18.7 | 346.0 ± 15.5 | 325.0 ± 16.9 | 335.8 ± 23.5 | 357.2 ± 18.3 | 527.8 ± 34.1** | 466.0 | 89.383 | 74.114
Aspartate Aminotransferase (U/L) | 80.10 ± 4.72** | 83.40 ± 4.86 | 72.20 ± 3.09 | 78.40 ± 3.36 | 82.50 ± 4.56 | 74.20 ± 3.73 | 91.00 ± 4.71 | 128.40 ± 17.32** | 195.00 ± 54.03** | 154.00 | 28.117 | 19.352
Female
n | 10 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Cholesterol (mg/dL) | 95.6 ± 4.9** | 100.6 ± 7.7 | 104.8 ± 8.0 | 93.6 ± 11.9 | 82.2 ± 3.8 | 84.8 ± 2.2 | 90.4 ± 2.7 | 92.8 ± 3.1 | 38.0 ± 4.5** | 54.0 ± 6.8** | 1.591^e^ | 0.58^e^
Aspartate Aminotransferase (U/L) | 72.80 ± 1.78** | 73.60 ± 2.44 | 71.80 ± 2.03 | 76.40 ± 3.53 | 77.00 ± 2.59 | 75.60 ± 2.48 | 79.20 ± 2.97 | 74.00 ± 3.70 | 76.00 ± 2.74 | 103.60 ± 19.79** | 497.046 | 340.458

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; A/G Ratio = ratio of albumin to globulin; NVM = nonviable model.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample in the indicated dose group was not received.

^d^ One male rat was moribund and euthanized on study day 1 and three male rats were found dead on study day 4. Clinical chemistry data from the remaining male rat were excluded from statistical analysis and BMD calculations.

^e^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

^f^ One value for alkaline phosphatase in the vehicle control group and the 0.15 mg/kg group were excluded due to sample and/or analysis concerns.

The reticulocyte count was significantly decreased in the ≥37 mg/kg female groups with a BMD (BMD_L_) of 15.578 (3.622) mg/kg (Table 5). In addition, in female rats, the monocyte and large unstained cell counts were significantly increased in dose groups ≥111 mg/kg and ≥37 mg/kg with BMDs (BMD_L_s) of 257.111 (160.613) mg/kg and 54.339 (15.759) mg/kg, respectively. The reticulocyte count in male rats had significant trend and pairwise comparisons. Although a BMD was estimated, its value was much lower (approximately 120- to 360-fold) than would be expected given the endpoint-specific NOEL and LOEL values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach.

Table 5 Summary of Select Hematology Data for Male and Female Rats Administered 6:1 Fluorotelomer Alcohol for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 9^c^ | 4^c^ | 5 | 4^c^ | 4^c^ | 5 | 5 | 4^c^ | 4^c^ | 1^d^ | NA | NA
Reticulocytes (10^3^/μL) | 240.2 ± 8.5** | 237.2 ± 4.3 | 207.4 ± 13.6 | 228.4 ± 14.9 | 222.2 ± 6.6 | 211.9 ± 8.6 | 235.4 ± 9.9 | 194.9 ± 12.1* | 89.9 ± 9.8** | 88.4 | 0.308^e^ | 0.112^e^
Female
n | 9^c^ | 5 | 5 | 4^c^ | 5 | 5 | 5 | 5 | 5 | 5 | NA | NA
Reticulocytes (10^3^/μL) | 224.6 ± 11.5** | 235.1 ± 17.6 | 205.3 ± 17.2 | 206.6 ± 7.6 | 210.7 ± 11.9 | 200.6 ± 14.0 | 161.9 ± 6.5** | 199.4 ± 20.2* | 126.4 ± 9.4** | 112.3 ± 12.7** | 15.578 | 3.622
Monocytes (10^3^/μL) | 0.19 ± 0.04** | 0.31 ± 0.08 | 0.28 ± 0.03 | 0.29 ± 0.04 | 0.28 ± 0.05 | 0.22 ± 0.04 | 0.28 ± 0.03 | 0.37 ± 0.05* | 0.40 ± 0.06** | 0.66 ± 0.18** | 257.111 | 160.613
Large Unstained Cells (10^3^/μL) | 0.04 ± 0.01** | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.04 ± 0.01 | 0.06 ± 0.00** | 0.07 ± 0.01** | 0.07 ± 0.01** | 0.07 ± 0.02* | 54.339 | 15.759

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample from each of the indicated dose groups had a clot present and was not analyzed.

^d^ One male rat was moribund and euthanized on study day 1 and three male rats were found dead on study day 4. Hematology data from the remaining male rat were excluded from statistical analysis and BMD calculations.

^e^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

In male rats, total thyroxine (total T4) concentration was significantly decreased in the ≥4 mg/kg groups with a BMD (BMD_L_) of 3.19 (1.774) mg/kg (Table 6). In addition, free thyroxine (fT4) concentration was significantly decreased in the 333 mg/kg male rats; a BMD (BMD_L_) was not determined because no viable model was available. In female rats, the total triiodothyronine (total T3) and total T4 concentrations were significantly decreased in the ≥333 mg/kg groups. The BMD (BMD_L_) for decreased total T3 was 161.48 (122.215) mg/kg. A BMD (BMD_L_) was not determined for decreased total T4 because no viable model was available. Additionally, thyroid stimulating hormone (TSH) concentration was significantly increased in female rats in the 1,000 mg/kg group with a BMD (BMD_L_) of 356.61 (268.917) mg/kg. Total T3 concentration in male rats had significant trend and pairwise comparisons. Although a BMD was estimated, its value was much lower (approximately 10- to 25-fold) than would be expected given the endpoint-specific NOEL and LOEL values, suggesting that the BMD estimate did not accurately reflect the true potency of the effect and was likely an anomalous product of the BMD modeling approach.

Table 6 Summary of Select Hormone Data for Male and Female Rats Administered 6:1 Fluorotelomer Alcohol for Five Days

Endpoint^a,b^ | 0 mg/kg | 0.15 mg/kg | 0.5 mg/kg | 1.4 mg/kg | 4 mg/kg | 12 mg/kg | 37 mg/kg | 111 mg/kg | 333 mg/kg | 1,000 mg/kg | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg)
Male
n | 9^c^ | 5 | 5 | 4^c^ | 4^c^ | 5 | 5 | 4^c^ | 4^c^ | 1^d^ | NA | NA
Total T3 (ng/dL) | 49.244 ± 2.130** | 51.720 ± 1.832 | 56.580 ± 4.871 | 47.650 ± 0.999 | 44.975 ± 1.527 | 34.920 ± 2.801** | 31.960 ± 2.646** | 33.025 ± 0.999** | 33.150 ± 4.547** | 27.600 | 0.462^e^ | 0.245^e^
fT4 (ng/dL) | 6.761 ± 0.817** | 5.864 ± 0.686 | 6.680 ± 0.316 | 5.755 ± 0.496 | 6.410 ± 0.393 | 4.982 ± 0.435 | 5.726 ± 0.661 | 5.115 ± 0.301 | 4.363 ± 0.424** | 3.780 | NVM | NVM
Total T4 (μg/dL) | 2.71 ± 0.16** | 2.47 ± 0.26 | 2.57 ± 0.30 | 2.52 ± 0.14 | 1.58 ± 0.16** | 1.01 ± 0.07** | 0.93 ± 0.10** | 0.66 ± 0.04** | 0.50 ± 0.02** | 0.66 | 3.19 | 1.774
Female
n | 9^c^ | 4^c^ | 3^f^ | 4^c^ | 5 | 4^c^ | 5 | 5 | 4^c^ | 5 | NA | NA
TSH (ng/mL) | 3.122 ± 0.371** | 3.400 ± 1.013 | 2.800 ± 0.551 | 2.425 ± 0.375 | 3.020 ± 0.475 | 3.400 ± 0.826 | 2.540 ± 0.367 | 4.480 ± 0.388 | 3.775 ± 1.150 | 6.900 ± 0.933** | 356.61 | 268.917
Total T3 (ng/dL) | 66.000 ± 3.455** | 58.825 ± 1.727 | 66.900 ± 4.891 | 59.825 ± 4.950 | 61.540 ± 4.315 | 62.700 ± 4.457 | 63.740 ± 2.761 | 59.040 ± 2.090 | 42.425 ± 2.062** | 31.060 ± 1.857** | 161.48 | 122.215
Total T4 (μg/dL) | 3.12 ± 0.29** | 2.83 ± 0.43 | 2.31 ± 0.08 | 2.64 ± 0.43 | 2.76 ± 0.11 | 2.79 ± 0.16 | 2.31 ± 0.22 | 2.64 ± 0.26 | 1.20 ± 0.18** | 0.86 ± 0.14** | NVM | NVM

Statistical significance for a dosed group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NA = not applicable; total T3 = total triiodothyronine; fT4 = free thyroxine; NVM = nonviable model; total T4 = total thyroxine; TSH = thyroid stimulating hormone.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ One sample in the indicated dose groups did not have sufficient specimen volume available for analysis.

^d^ One male rat was moribund and euthanized on study day 1 and three male rats were found dead on study day 4. Hormone data from the remaining male rat were excluded from statistical analysis and BMD calculations.

^e^ BMD values are much lower than would be expected given the lowest-observed-effect level and no-observed-effect level values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

^f^ Two samples in the indicated dose group did not have sufficient specimen volume available for analysis.

## Internal Dose Assessment

For the 4 and 37 mg/kg groups, 6:1 FTOH plasma concentrations were determined at 2 and 24 hours following the last dose administered on study day 4 to male and female rats. Average 6:1 FTOH concentrations are given in Table 7. In the 4 mg/kg male rats at 2 hours following administration, the average concentration was slightly above the limit of detection (LOD = 2.9 ng/mL) of the analytical method. As the administered dose increased from 4 to 37 mg/kg (a ninefold increase), there was a more-than-proportional increase (38-fold) in the average 6:1 FTOH plasma concentration, suggesting changes in the absorption, distribution, metabolism, and excretion processes (e.g., saturation of clearance pathways) as the dose increased. In female rats at 2 hours postdose, the 6:1 FTOH plasma concentration was below the LOD of the analytical method in the 4 mg/kg group, and at 37 mg/kg, the average group concentration was lower than that observed in male rats (female, 115 ng/mL; male, 148 ng/mL), demonstrating some sex differences. At 24 hours postdose, the concentration fell below the LOD for both male and female rats suggesting short plasma half-lives of 6:1 FTOH in rats.

Table 7 Summary of Plasma Concentration Data for Male and Female Rats Administered 6:1 Fluorotelomer Alcohol for Five Days^a^

| 4 mg/kg | 37 mg/kg
n | 3 | 3
Male
2 Hours Postdose (ng/mL) | 3.86 ± 0.164 | 148 ± 29.0
24 Hours Postdose (ng/mL) | BD | BD
Female
2 Hours Postdose (ng/mL) | BD^b^ | 115 ± 44.9
24 Hours Postdose (ng/mL) | BD | BD

If over 20% of the animals in a group are above the limit of detection, then half the limit of detection value is substituted for values that are below it.

BD = below detection; group did not have over 20% of its values above the limit of detection so mean and standard error were not calculated.

^a^ Data are displayed as mean ± standard error of the mean.

^b^ Only two samples were received for the 4 mg/kg female rats at 2 hours postdose.

## Apical Endpoint Benchmark Dose Summary

A summary of the calculated BMDs for each toxicological endpoint is provided in Table 8. The endpoint-specific LOEL and NOEL are included and could be informative for endpoints that lack a calculated BMD either because no viable model was available or because the estimated BMD was below the lower limit of extrapolation (<0.050 mg/kg).

Table 8 BMD, BMD_L_, LOEL, and NOEL Summary for Apical Endpoints, Sorted by BMD or LOEL from Low to High

Endpoint | BMD_1Std_ (mg/kg) | BMD_L1Std_ (mg/kg) | LOEL (mg/kg)^a^ | NOEL (mg/kg) | Direction of Change
Male
Total Thyroxine | 3.19 | 1.774 | 4 | 1.4 | DOWN
Relative Liver Weight | 12.122 | 9.527 | 37 | 12 | UP
Albumin | 13.365 | 4.084 | 37 | 12 | UP
Relative Left Kidney Weight | 20.907 | 4.272 | 333 | 111 | UP
Aspartate Aminotransferase | 28.117 | 19.352 | 111 | 37 | UP
Absolute Liver Weight | 28.507 | 15.286 | 37 | 12 | UP
Alanine Aminotransferase | 36.116 | 21.468 | 37 | 12 | UP
Alkaline Phosphatase | 89.383 | 74.114 | 333 | 111 | UP
Creatinine | 97.38 | 32.365 | 333 | 111 | UP
A/G Ratio | UREP^b^ | UREP^b^ | 12 | 4 | –^b^
Globulin | UREP | UREP | 12 | 4 | –
Total Triiodothyronine | UREP | UREP | 12 | 4 | –
Triglycerides | NVM | NVM | 12 | 4 | DOWN
Cholesterol | NVM | NVM | 37 | 12 | DOWN
Relative Right Kidney Weight | UREP | UREP | 37 | 12 | –
Reticulocytes | UREP | UREP | 111 | 37 | –
Free Thyroxine | NVM | NVM | 333 | 111 | DOWN
Female
Reticulocytes | 15.578 | 3.622 | 37 | 12 | DOWN
Large Unstained Cells | 54.339 | 15.759 | 37 | 12 | UP
Total Triiodothyronine | 161.48 | 122.215 | 333 | 111 | DOWN
Monocytes | 257.111 | 160.613 | 111 | 37 | UP
Thyroid Stimulating Hormone | 356.61 | 268.917 | 1,000 | 333 | UP
Aspartate Aminotransferase | 497.046 | 340.458 | 1,000 | 333 | UP
Absolute Liver Weight | NVM | NVM | 333 | 111 | UP
Cholesterol | UREP | UREP | 333 | 111 | –
Relative Liver Weight | NVM | NVM | 333 | 111 | UP
Total Thyroxine | NVM | NVM | 333 | 111 | DOWN

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; LOEL = lowest-observed-effect level; NOEL = no-observed-effect level; A/G Ratio = ratio of albumin to globulin; UREP = unreliable estimate of potency is a label based on review by a subject matter expert and rejection of BMD modeling results; NVM = nonviable model, defined as a modeling result that does not meet prespecified fit criteria and hence is deemed unreliable.

^a^ Values in bold text indicate the LOEL of endpoints for which a BMD could not be calculated.

^b^ BMD values are much lower than would be expected given the end-point specific LOEL and NOEL values, suggesting that the BMD estimates do not accurately reflect the true potency of the effect of these endpoints and are likely an anomalous product of the BMD modeling approach.

## Gene Set Benchmark Dose Analysis

Chemical-induced alterations in liver and kidney gene transcript expression were examined to determine those gene sets most sensitive to 6:1 FTOH exposure. To that end, BMD analysis of transcripts and gene sets (Gene Ontology [GO] biological process) was conducted to determine the potency of the chemical to elicit gene expression changes in the liver and kidney. This analysis used transcript-level BMD data to assess an aggregate score of gene set potency (median transcript BMD) and enrichment.

The “active” gene sets in the liver and kidney with the lowest BMD median values are shown in Table 9 and Table 10, respectively. The gene sets in Table 9 and Table 10 should be interpreted with caution from the standpoint of the underlying biological mechanism and any relationship to toxicity or toxic agents referenced in the GO term definitions. The data primarily should be considered a metric of potency for chemical-induced transcriptional changes (i.e., a concerted biological change) that could serve as a surrogate of estimated biological potency and, by extension, toxicological potency when more definitive toxicological data are unavailable.

Table 9 Top 10 Liver Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Category Name | No. of Active Genes/ Platform Genes in Gene Set | % Gene Set Coverage | Active Genes | BMD_1std_ Median of Gene Set Transcripts (mg/kg) | Median BMD_L1Std_–BMD_U1Std_ (mg/kg) | Genes with Changed Direction Up | Genes with Changed Direction Down
Male
GO:0071364 cellular response to epidermal growth factor stimulus | 3/20 | 15% | Zfp36; Ncl; Myc | 0.368 | 0.103–1.817 | 1 | 2
GO:0070849 response to epidermal growth factor | 4/26 | 15% | Zfp36; Ncl; Myc; Acot2 | 0.690 | 0.456–1.597 | 2 | 2
GO:0006635 fatty acid beta-oxidation | 10/33 | 30% | Slc27a2; Gcdh; Etfdh; Ehhadh; Eci1; Ech1; Crot; Cpt1b; Acox1; Acadsb | 2.017 | 1.401–3.184 | 9 | 1
GO:0009062 fatty acid catabolic process | 12/42 | 29% | Slc27a2; Hacl1; Gcdh; Etfdh; Ehhadh; Eci1; Ech1; Crot; Cpt1b; Acox1; Acot2; Acadsb | 2.017 | 1.288–3.184 | 11 | 1
GO:0072329 monocarboxylic acid catabolic process | 15/48 | 31% | Slc27a2; Hacl1; Gcdh; Etfdh; Ehhadh; Eci1; Ech1; Cyp26b1; Crot; Cpt1b; Agxt2; Acox1; Acot2; Acadsb; Abat | 2.238 | 1.439–3.909 | 12 | 3
GO:0070371 ERK1 and ERK2 cascade | 3/14 | 21% | Tf; Myc; Apoa1 | 2.377 | 1.208–5.187 | 0 | 3
GO:0000038 very long-chain fatty acid metabolic process | 5/12 | 42% | Slc27a2; Acox1; Acot4; Acot2; Acot1 | 2.721 | 1.888–4.505 | 5 | 0
GO:0046395 carboxylic acid catabolic process | 21/87 | 24% | Cemip2; Slc27a2; Kynu; Kmo; Hacl1; Gcdh; Etfdh; Ehhadh; Eci1; Ech1; Cyp26b1; Crot; Cpt1b; Cdo1; Blmh; Agxt2; Acox1; Acot4; Acot2; Acadsb; Abat | 3.806 | 1.610–6.038 | 15 | 6
GO:0006637 acyl-CoA metabolic process | 9/31 | 29% | Mpc2; Kynu; Gcdh; Acss2; Acot4; Acot2; Acot12; Acot1; Acadsb | 4.030 | 2.953–10.491 | 7 | 2
GO:0044282 small molecule catabolic process | 23/120 | 19% | Cemip2; Sult1e1; Slc27a2; Kynu; Kmo; Inpp1; Hacl1; Gcdh; Etfdh; Ehhadh; Eci1; Ech1; Cyp26b1; Crot; Cpt1b; Cdo1; Blmh; Agxt2; Acox1; Acot4; Acot2; Acadsb; Abat | 4.136 | 1.888–10.491 | 17 | 6
Female
GO:0050766 positive regulation of phagocytosis | 4/35 | 11% | Cd36; C3; Apoa2; Ahsg | 44.730 | 22.260–122.653 | 2 | 2
GO:0050764 regulation of phagocytosis | 5/51 | 10% | Cd36; C3; Apoa2; Alox15; Ahsg | 48.555 | 27.154–159.716 | 2 | 3
GO:0002718 regulation of cytokine production involved in immune response | 3/36 | 8% | Ticam1; Cd36; Apoa2 | 48.555 | 17.366–159.716 | 3 | 0
GO:0034381 plasma lipoprotein particle clearance | 3/11 | 27% | Cd36; Apoc3; Apoa2 | 48.555 | 17.366–159.716 | 2 | 1
GO:0016051 carbohydrate biosynthetic process | 3/32 | 9% | Gpd1; G6pd; Acadm | 48.822 | 39.627–63.173 | 3 | 0
GO:0006399 tRNA metabolic process | 3/20 | 15% | Tsen2; Iars2; Hsd17b10 | 57.734 | 46.011–76.940 | 3 | 0
GO:0051181 cofactor transport | 3/10 | 30% | Slc27a1; Slc22a8; Abcg2 | 60.649 | 31.055–121.705 | 1 | 2
GO:0044262 cellular carbohydrate metabolic process | 3/40 | 8% | Inpp1; Acadm; Abcg2 | 60.649 | 39.560–121.705 | 2 | 1
GO:0045926 negative regulation of growth | 4/72 | 6% | Gdf15; G6pd; Cdkn1a; Ahsg | 61.369 | 35.006–115.629 | 2 | 2
GO:0006635 fatty acid beta-oxidation | 18/33 | 55% | Slc27a2; Hadhb; Hadh; Gcdh; Etfdh; Ehhadh; Eci1; Ech1; Decr1; Crot; Crat; Cpt2; Cpt1b; Acox1; Acadsb; Acadm; Acadl; Acaa2 | 64.027 | 46.553–95.058 | 17 | 1

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; GO = Gene Ontology.

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^30^ Official gene symbols from the Rat Genome Database^31^ are shown in the “Active Genes” column.

GO process description version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

GO:0071364 cellular response to epidermal growth factor stimulus: Any process that results in a change in state or activity of a cell (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an epidermal growth factor stimulus.

GO:0070849 response to epidermal growth factor: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of an epidermal growth factor stimulus.

GO:0006635 fatty acid beta-oxidation: A fatty acid oxidation process that results in the complete oxidation of a long-chain fatty acid. Fatty acid beta-oxidation begins with the addition of coenzyme A to a fatty acid and occurs by successive cycles of reactions during each of which the fatty acid is shortened by a two-carbon fragment removed as acetyl-coenzyme A; the cycle continues until only two or three carbons remain (as acetyl-CoA or propionyl-CoA, respectively).

GO:0009062 fatty acid catabolic process: The chemical reactions and pathways resulting in the breakdown of a fatty acid, any of the aliphatic monocarboxylic acids that can be liberated by hydrolysis from naturally occurring fats and oils. Fatty acids are predominantly straight-chain acids of 4 to 24 carbon atoms, which may be saturated or unsaturated; branched fatty acids and hydroxy fatty acids also occur, and very long-chain acids of over 30 carbons are found in waxes.

GO:0072329 monocarboxylic acid catabolic process: The chemical reactions and pathways resulting in the breakdown of monocarboxylic acids, any organic acid containing one carboxyl (-COOH) group.

GO:0070371 ERK1 and ERK2 cascade: An intracellular protein kinase cascade containing at least ERK1 or ERK2 (MAPKs), a MEK (a MAPKK) and a MAP3K. The cascade may involve four different kinases, as it can also contain an additional tier: the upstream MAP4K. The kinases in each tier phosphorylate and activate the kinase in the downstream tier to transmit a signal within a cell.

GO:0000038 very long-chain fatty acid metabolic process: The chemical reactions and pathways involving a fatty acid with a chain length greater than C22.

GO:0046395 carboxylic acid catabolic process: The chemical reactions and pathways resulting in the breakdown of carboxylic acids, which are any organic acid containing one or more carboxyl (-COOH) groups.

GO:0006637 acyl-CoA metabolic process: The chemical reactions and pathways involving acyl-CoA, which is any derivative of coenzyme A in which the sulfhydryl group is in thiolester linkage with an acyl group.

GO:0044282 small molecule catabolic process: The chemical reactions and pathways resulting in the breakdown of small molecules, which are any low molecular weight, monomeric, nonencoded molecule.

GO:0050766 positive regulation of phagocytosis: Any process that activates or increases the frequency, rate, or extent of phagocytosis.

GO:0050764 regulation of phagocytosis: Any process that modulates the frequency, rate, or extent of phagocytosis, the process in which phagocytes engulf external particulate material.

GO:0002718 regulation of cytokine production involved in immune response: Any process that modulates the frequency, rate, or extent of cytokine production that contributes to an immune response.

GO:0034381 plasma lipoprotein particle clearance: The process in which a lipoprotein particle is removed from the blood via receptor-mediated endocytosis and its constituent parts degraded.

GO:0016051 carbohydrate biosynthetic process: The chemical reactions and pathways resulting in the formation of carbohydrates, which are any of a group of organic compounds based on the general formula C_x_(H_2_O)_y_.

GO:0006399 tRNA metabolic process: The chemical reactions and pathways involving tRNA (transfer RNA), which is a class of relatively small RNA molecules responsible for mediating the insertion of amino acids into the sequence of nascent polypeptide chains during protein synthesis. Transfer RNA is characterized by the presence of many unusual minor bases, the function of which has not been completely established.

GO:0051181 cofactor transport: The directed movement of a cofactor into, out of, or within a cell, or between cells, by means of some agent such as a transporter or pore. A cofactor is a substance that is required for the activity of an enzyme or other protein.

GO:0044262 cellular carbohydrate metabolic process: The chemical reactions and pathways involving carbohydrates, which are any of a group of organic compounds based on the general formula C_x_(H_2_O)_y_, as carried out by individual cells.

GO:0045926 negative regulation of growth: Any process that stops, prevents, or reduces the rate or extent of growth (the increase in size or mass of all or part of an organism).

Table 10 Top 10 Kidney Gene Ontology Biological Process Gene Sets Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Category Name | No. of Active Genes/ Platform Genes in Gene Set | % Gene Set Coverage | Active Genes | BMD_1std_ Median of Gene Set Transcripts (mg/kg) | Median BMD_L1Std_–BMD_U1Std_ (mg/kg) | Genes with Changed Direction Up | Genes with Changed Direction Down
Male
GO:0048143 astrocyte activation | 3/11 | 27% | Il1b; Grn; C1qa | <0.050^b^ | NR | 1 | 2
GO:0002832 negative regulation of response to biotic stimulus | 3/27 | 11% | Parp14; Grn; Tkfc | <0.050 | NR | 0 | 3
GO:0006084 acetyl-CoA metabolic process | 3/16 | 19% | Hmgcs2; Acot12; Acaa2 | 1.346 | 0.541–4.058 | 2 | 1
GO:0006637 acyl-CoA metabolic process | 6/31 | 19% | Hmgcs2; Acot4; Acot2; Acot12; Acot1; Acaa2 | 1.928 | 1.305–4.031 | 5 | 1
GO:0010883 regulation of lipid storage | 3/22 | 14% | Srebf1; Nfkbia; C3 | 2.189 | 0.888–5.495 | 2 | 1
GO:0030522 intracellular receptor signaling pathway | 3/42 | 7% | Srebf1; Nr1d2; Nfkbia | 2.189 | 0.888–5.495 | 2 | 1
GO:0006721 terpenoid metabolic process | 3/34 | 9% | Pecr; Hmgcs2; Cyp2e1 | 2.994 | 0.682–13.980 | 2 | 1
GO:0002698 negative regulation of immune effector process | 4/43 | 9% | Lgals3; Grn; Enpp3; Tkfc | 3.710 | 1.436–9.709 | 1 | 3
GO:0009062 fatty acid catabolic process | 12/42 | 29% | Hadh; Etfdh; Ehhadh; Eci2; Ech1; Decr1; Cpt2; Adipoq; Acox1; Acot2; Acadm; Acaa2 | 3.895 | 1.678–6.474 | 12 | 0
GO:0000038 very long-chain fatty acid metabolic process | 4/12 | 33% | Acox1; Acot4; Acot2; Acot1 | 4.235 | 2.759–6.872 | 4 | 0
Female
GO:0006635 fatty acid beta-oxidation | 8/33 | 24% | Ppard; Ehhadh; Eci2; Eci1; Ech1; Acadm; Acadl; Acaa2 | 21.079 | 13.312–34.031 | 7 | 1
GO:0019395 fatty acid oxidation | 10/43 | 23% | Ppard; Hao2; Ehhadh; Eci2; Eci1; Ech1; Cd36; Acadm; Acadl; Acaa2 | 27.058 | 13.877–61.247 | 8 | 2
GO:0009062 fatty acid catabolic process | 12/42 | 29% | Ppard; Pck2; Pck1; Ehhadh; Eci2; Eci1; Ech1; Ces1d; Acot2; Acadm; Acadl; Acaa2 | 27.540 | 15.179–63.270 | 10 | 2
GO:0006637 acyl-CoA metabolic process | 7/31 | 23% | Hmgcs2; Acss2; Acot4; Acot2; Acot12; Acot1; Acaa2 | 38.393 | 23.116–70.139 | 5 | 2
GO:0000038 very long-chain fatty acid metabolic process | 3/12 | 25% | Acot4; Acot2; Acot1 | 38.393 | 23.116–70.139 | 3 | 0
GO:0033875 ribonucleoside bisphosphate metabolic process | 8/41 | 20% | Pank1; Hmgcs2; Acss2; Acot4; Acot2; Acot12; Acot1; Acaa2 | 44.906 | 31.624–70.563 | 6 | 2
GO:0030258 lipid modification | 13/70 | 19% | Ppard; Hao2; Ephx2; Ehhadh; Eci2; Eci1; Ech1; Cyp2e1; Cyp1a1; Cd36; Acadm; Acadl; Acaa2 | 49.703 | 38.943–83.829 | 10 | 3
GO:0009409 response to cold | 3/27 | 11% | Cxcl10; Acadm; Acadl | 61.062 | 46.535–88.000 | 2 | 1
GO:0009150 purine ribonucleotide metabolic process | 10/80 | 13% | Pank1; Pde4c; Hmgcs2; Aldoc; Acss2; Acot4; Acot2; Acot12; Acot1; Acaa2 | 67.924 | 50.324–104.308 | 7 | 3
GO:0006732 coenzyme metabolic process | 12/67 | 18% | Vnn1; Rgn; Pank1; Mthfd2; Hmgcs2; Gclc; Acss2; Acot4; Acot2; Acot12; Acot1; Acaa2 | 67.924 | 50.324–104.308 | 8 | 4

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; GO = Gene Ontology; NR = the BMD_L1Std_–BMD_U1Std_ range is not reportable because the BMD_1Std_ median is below the lower limit of extrapolation (<1/3 of the lowest nonzero dose tested).

^a^ Definitions of GO terms were adapted from the Gene Ontology Resource.^30^ Official gene symbols from the Rat Genome Database^31^ are shown in the “Active Genes” column.

^b^ <0.050 = a best-fit model was identified and a BMD_1Std_ was estimated that was <1/3 of the lowest nonzero dose tested.

GO process description version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

GO:0048143 astrocyte activation: A change in morphology and behavior of an astrocyte resulting from exposure to a cytokine, chemokine, cellular ligand, or soluble factor.

GO:0002832 negative regulation of response to biotic stimulus: Any process that stops, prevents, or reduces the frequency, rate, or extent of a response to biotic stimulus.

GO:0006084 acetyl-CoA metabolic process: The chemical reactions and pathways involving acetyl-CoA, a derivative of coenzyme A in which the sulfhydryl group is acetylated. Acetyl-CoA is a metabolite derived from several pathways (e.g., glycolysis, fatty acid oxidation, amino-acid catabolism) and is further metabolized by the tricarboxylic acid cycle. It is a key intermediate in lipid and terpenoid biosynthesis.

GO:0006637 acyl-CoA metabolic process: The chemical reactions and pathways involving acyl-CoA, any derivative of coenzyme A in which the sulfhydryl group is in thiolester linkage with an acyl group.

GO:0010883 regulation of lipid storage: Any process that modulates the rate, frequency, or extent of lipid storage. Lipid storage is the accumulation and maintenance in cells or tissues of lipids, which are compounds soluble in organic solvents but insoluble or sparingly soluble in aqueous solvents. Lipid reserves can be accumulated during early developmental stages for mobilization and utilization at later stages of development.

GO:0030522 intracellular receptor signaling pathway: Any series of molecular signals initiated by a ligand binding to a receptor located within a cell.

GO:0006721 terpenoid metabolic process: The chemical reactions and pathways involving terpenoids, which are any member of a class of compounds characterized by an isoprenoid chemical structure and including derivatives with various functional groups.

GO:0002698 negative regulation of immune effector process: Any process that stops, prevents, or reduces the frequency, rate, or extent of an immune effector process.

GO:0009062 fatty acid catabolic process: The chemical reactions and pathways resulting in the breakdown of fatty acids, which are any of the aliphatic monocarboxylic acids that can be liberated by hydrolysis from naturally occurring fats and oils. Fatty acids are predominantly straight-chain acids of 4 to 24 carbon atoms, which may be saturated or unsaturated; branched fatty acids and hydroxy fatty acids also occur, and very long-chain acids of over 30 carbons are found in waxes.

GO:0000038 very long-chain fatty acid metabolic process: The chemical reactions and pathways involving a fatty acid with a chain length greater than C22.

GO:0006635 fatty acid beta-oxidation: A fatty acid oxidation process that results in the complete oxidation of a long-chain fatty acid. Fatty acid beta-oxidation begins with the addition of coenzyme A to a fatty acid and occurs by successive cycles of reactions during each of which the fatty acid is shortened by a two-carbon fragment removed as acetyl-coenzyme A; the cycle continues until only two or three carbons remain (as acetyl-CoA or propionyl-CoA, respectively).

GO:0019395 fatty acid oxidation: The removal of one or more electrons from a fatty acid, with or without the concomitant removal of a proton or protons, by reaction with an electron-accepting substance, by addition of oxygen, or by removal of hydrogen.

GO:0033875 ribonucleoside bisphosphate metabolic process: The chemical reactions and pathways involving a ribonucleoside bisphosphate, which is a compound consisting of a nucleobase linked to a ribose sugar esterified with one phosphate group attached to each of two different hydroxyl groups on the sugar.

GO:0030258 lipid modification: The covalent alteration of one or more fatty acids in a lipid, resulting in a change in the properties of the lipid.

GO:0009409 response to cold: Any process that results in a change in state or activity of a cell or an organism (in terms of movement, secretion, enzyme production, gene expression, etc.) as a result of a cold stimulus (a temperature stimulus below the optimal temperature for that organism).

GO:0009150 purine ribonucleotide metabolic process: The chemical reactions and pathways involving a purine ribonucleotide, which is a compound consisting of ribonucleoside (a purine base linked to a ribose sugar) esterified with a phosphate group at either the 3’ or 5’-hydroxyl group of the sugar.

GO:0006732 coenzyme metabolic process: The chemical reactions and pathways involving coenzymes, which are any of various nonprotein organic cofactors that are required, in addition to an enzyme and a substrate, for an enzymatic reaction to proceed.

No gene sets in the liver of male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were cellular response to epidermal growth factor stimulus (GO:0071364) and response to epidermal growth factor (GO:0070849) with median BMDs (BMD_L_s) of 0.368 (0.103) and 0.690 (0.456) mg/kg, respectively. In female rats, the most sensitive GO biological processes for which a BMD value could be reliably calculated were positive regulation of phagocytosis (GO:0050766) and regulation of phagocytosis (GO:0050764) with median BMDs (BMD_L_s) of 44.730 (22.260) and 48.555 (27.154) mg/kg, respectively.

Two gene sets in the kidney of male rats had estimated BMD median values <0.050 mg/kg, which were related to astrocyte activation (GO:0048143) and negative regulation of response to biotic stimulus (GO:0002832). The most sensitive GO biological processes for which a BMD value could be reliably calculated were acetyl-CoA metabolic process (GO:0006084) and acyl-CoA metabolic process (GO:0006637) with median BMDs (BMD_L_s) of 1.346 (0.541) and 1.928 (1.305) mg/kg, respectively. No gene sets in the kidney of female rats had estimated BMD median values <0.050 mg/kg. The most sensitive GO biological processes for which a BMD value could be reliably calculated were fatty acid beta-oxidation (GO:0006635) and fatty acid oxidation (GO:0019395) with median BMDs (BMD_L_s) of 21.079 (13.312) and 27.058 (13.877) mg/kg, respectively. The full list of affected gene sets in the liver and kidney of male and female rats can be found in Appendix F.

## Gene Benchmark Dose Analysis

The top 10 genes based on BMD potency in the liver and kidney (fold change >|2|, significant Williams trend test, global goodness-of-fit p value >0.1, and BMD_U_/BMD_L_ ≤40) are shown in Table 11 and Table 12. As with the GO analysis, the biological or toxicological significance of the changes in gene expression shown in Table 11 and Table 12 should be interpreted with caution. The data primarily should be considered a metric of potency for chemical-induced transcriptional changes that could serve as a conservative surrogate of estimated biological potency, and by extension toxicological potency, when more definitive toxicological data are unavailable.

Table 11 Top 10 Liver Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | | BMD_1Std_ (BMD_L1std_–BMD_U1std_) in mg/kg | Maximum Fold Change | Direction of Expression Change
Male
Myc | 24577 | MYC_9271 | | 0.186 (0.103–0.478) | 3.3 | DOWN
Zfp36 | 79426 | ZFP36_10204 | | 0.368 (0.097–1.817) | 2.1 | DOWN
Acot2 | 192272 | ACOT2_7969 | | 1.012 (0.809–1.377) | 19.9 | UP
Eci1 | 29740 | ECI1_8520 | | 1.013 (0.769–1.465) | 23.5 | UP
Loc100911558/Spink1l | 100911558 | SPINK1_32461 | | 1.270 (0.542–3.173) | 2.0 | UP
Spink1 | 266602 | SPINK1_32461 | | 1.270 (0.542–3.173) | 2.0 | UP
Ehhadh | 171142 | EHHADH_8534 | | 1.280 (1.047–1.879) | 95.2 | UP
Crot | 83842 | CROT_8384 | | 1.411 (1.092–1.919) | 7.5 | UP
Acaa1a | 24157 | ACAA1A_7954 | | 1.874 (1.524–2.760) | 39.0 | UP
Acaa1b | 501072 | ACAA1A_7954 | | 1.874 (1.524–2.760) | 39.0 | UP
Female
Gdf15 | 29455 | GDF15_33113 | 17.724 (8.696–37.098) | | 5.8 | UP
Igfbp1 | 25685 | IGFBP1_32306 | 18.792 (7.230–51.558) | | 4.3 | UP
Eci1 | 29740 | ECI1_8520 | 32.546 (27.162–40.287) | | 9.6 | UP
Etfdh | 295143 | ETFDH_8575 | 34.846 (26.297–48.311) | | 2.0 | UP
Cyp2b1 | 24300 | CYP2B1_32451 | 35.483 (29.479–44.233) | | 196.8 | UP
Loc108348266/Cyp2b1 | 108348266 | CYP2B1_32451 | 35.483 (29.479–44.233) | | 196.8 | UP
Dhrs7 | 299135 | DHRS7_8469 | 35.986 (10.630–156.958) | | 4.4 | UP
Dhrs7l1 | 299131 | DHRS7_8469 | 35.986 (10.630–156.958) | | 4.4 | UP
Slc27a2 | 65192 | SLC27A2_9860 | 36.103 (26.571–51.373) | | 2.3 | UP
Vnn1 | 29142 | VNN1_10157 | 37.026 (30.688–46.324) | | 15.8 | UP

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean.

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^32^ and Entrez Gene.^33^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

Gene definition version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Myc: Human Uniprot function (Human MYC): Transcription factor that binds DNA in a nonspecific manner, yet also specifically recognizes the core sequence 5’-CAC[GA]TG-3’. Activates the transcription of growth-related genes. Binds to the VEGFA promoter, promoting VEGFA production and subsequent sprouting angiogenesis (PubMed24940000). Regulator of somatic reprogramming; controls self-renewal of embryonic stem cells. Functions with TAF6L to activate target gene expression through RNA polymerase II pause release (by similarity).{ECO0000250|UniProtKBP01108, ECO0000269|PubMed24940000, ECO0000269|PubMed25956029}.

Zfp36: Human Uniprot function (Human ZFP36): Zinc-finger RNA-binding protein that destabilizes several cytoplasmic AU-rich element (ARE)-containing mRNA transcripts by promoting their poly(A) tail removal or deadenylation, and hence provide a mechanism for attenuating protein synthesis (PubMed9703499, PubMed10330172, PubMed10751406, PubMed11279239, PubMed12115244, PubMed12748283, PubMed15187101, PubMed15634918, PubMed17030620, PubMed16702957, PubMed20702587, PubMed20221403, PubMed21775632, PubMed27193233, PubMed23644599, PubMed25815583). Acts as an 3’-untranslated region (UTR) ARE mRNA-binding adapter protein to communicate signaling events to the mRNA decay machinery (PubMed15687258, PubMed23644599). Recruits deadenylase CNOT7 (and probably the CCR4-NOT complex) via association with CNOT1, and hence promotes ARE-mediated mRNA deadenylation (PubMed23644599). Functions also by recruiting components of the cytoplasmic RNA decay machinery to the bound ARE-containing mRNAs (PubMed11719186, PubMed12748283, PubMed15687258, PubMed16364915). Self regulates by destabilizing its own mRNA (PubMed15187101). Binds to 3’-UTR ARE of numerous mRNAs and of its own mRNA (PubMed10330172, PubMed10751406, PubMed12115244, PubMed15187101, PubMed15634918, PubMed17030620, PubMed16702957, PubMed19188452, PubMed20702587, PubMed20221403, PubMed21775632, PubMed25815583). Plays a role in anti-inflammatory responses; suppresses tumor necrosis factor (TNF)-alpha production by stimulating ARE-mediated TNF-alpha mRNA decay and several other inflammatory ARE-containing mRNAs in interferon (IFN)- and/or lipopolysaccharide (LPS)-induced macrophages (by similarity). Also plays a role in the regulation of dendritic cell maturation at the post-transcriptional level, and hence operates as part of a negative feedback loop to limit the inflammatory response (PubMed18367721). Promotes ARE-mediated mRNA decay of hypoxia-inducible factor HIF1A mRNA during the response of endothelial cells to hypoxia (PubMed21775632). Positively regulates early adipogenesis of preadipocytes by promoting ARE-mediated mRNA decay of immediate early genes (IEGs) (by similarity). Negatively regulates hematopoietic/erythroid cell differentiation by promoting ARE-mediated mRNA decay of the transcription factor STAT5B mRNA (PubMed20702587). Plays a role in maintaining skeletal muscle satellite cell quiescence by promoting ARE-mediated mRNA decay of the myogenic determination factor MYOD1 mRNA (by similarity). Associates also with and regulates the expression of non-ARE-containing target mRNAs at the post-transcriptional level, such as MHC class I mRNAs (PubMed18367721). Participates in association with argonaute RISC catalytic components in the ARE-mediated mRNA decay mechanism; assists microRNA (miRNA) targeting ARE-containing mRNAs (PubMed15766526). May also play a role in the regulation of cytoplasmic mRNA decapping; enhances decapping of ARE-containing RNAs, in vitro (PubMed16364915). Involved in the delivery of target ARE-mRNAs to processing bodies (PBs) (PubMed17369404). In addition to its cytosolic mRNA decay function, affects nuclear pre-mRNA processing (by similarity). Negatively regulates nuclear poly(A)-binding protein PABPN1-stimulated polyadenylation activity on ARE-containing pre-mRNA during LPS-stimulated macrophages (by similarity). Also involved in the regulation of stress granule (SG) and P-body formation and fusion (by similarity). Plays a role in the regulation of keratinocyte proliferation, differentiation, and apoptosis (PubMed27182009). Plays a role as a tumor suppressor by inhibiting cell proliferation in breast cancer cells (PubMed26926077).{ECO0000250|UniProtKBP22893, ECO0000269|PubMed10330172, ECO0000269|PubMed10751406, ECO0000269|PubMed11279239, ECO0000269|PubMed11719186, ECO0000269|PubMed12115244, ECO0000269|PubMed12748283, ECO0000269|PubMed15187101, ECO0000269|PubMed15634918, ECO0000269|PubMed15687258, ECO0000269|PubMed15766526, ECO0000269|PubMed16364915, ECO0000269|PubMed16702957, ECO0000269|PubMed17030620, ECO0000269|PubMed17369404, ECO0000269|PubMed18367721, ECO0000269|PubMed19188452, ECO0000269|PubMed20221403, ECO0000269|PubMed20702587, ECO0000269|PubMed21775632, ECO0000269|PubMed23644599, ECO0000269|PubMed25815583, ECO0000269|PubMed26926077, ECO0000269|PubMed27182009, ECO0000269|PubMed27193233, ECO0000269|PubMed9703499}. FUNCTION (Microbial infection) Negatively regulates HTLV-1 TAX-dependent transactivation of viral long terminal repeat (LTR) promoter.{ECO0000269|PubMed14679154}.

Acot2: Human Uniprot function (Human ACOT2): Acyl-CoA thioesterases are a group of enzymes that catalyze the hydrolysis of acyl-CoAs to the free fatty acid and coenzyme A (CoASH), providing the potential to regulate intracellular levels of acyl-CoAs, free fatty acids and CoASH (PubMed16940157). Acyl-coenzyme A thioesterase 2/ACOT2 displays higher activity toward long-chain acyl-CoAs (C14-C20) (PubMed16940157, PubMed10944470). The enzyme is involved in enhancing the hepatic fatty acid oxidation in mitochondria (by similarity).{ECO0000250|UniProtKBQ9QYR9, ECO0000269|PubMed10944470, ECO0000269|PubMed16940157, ECO0000303|PubMed16940157}.

Eci1: Human Uniprot function (Human ECI1): Able to isomerize both 3-cis and 3-trans double bonds into the 2-trans form in a range of enoyl-CoA species.{ECO0000269|PubMed7818490}.

LOC100911558/Spink1l: Human Uniprot function (Human SPINK1): Serine protease inhibitor that exhibits anti-trypsin activity (PubMed7142173). In the pancreas, protects against trypsin-catalyzed premature activation of zymogens (by similarity).{ECO0000250|UniProtKBP09036, ECO0000269|PubMed7142173}. FUNCTION: In the male reproductive tract, binds to sperm heads where it modulates sperm capacitance by inhibiting calcium uptake and nitrogen oxide (NO) production.{ECO0000250|UniProtKBP09036}.

Spink1: Human Uniprot function (Human SPINK1): Serine protease inhibitor which exhibits anti-trypsin activity (PubMed7142173). In the pancreas, protects against trypsin-catalyzed premature activation of zymogens (by similarity).{ECO:0000250|UniProtKB:P09036, ECO:0000269|PubMed7142173}. FUNCTION: In the male reproductive tract, binds to sperm heads where it modulates sperm capacitance by inhibiting calcium uptake and NO production.{ECO:0000250|UniProtKB:P09036}.

Ehhadh: Human Uniprot function (Human EHHADH): Peroxisomal trifunctional enzyme possessing 2-enoyl-CoA hydratase, 3-hydroxyacyl-CoA dehydrogenase, and delta 3, delta 2-enoyl-CoA isomerase activities. Catalyzes two of the four reactions of the long straight-chain fatty acids peroxisomal beta-oxidation pathway. Optimal isomerase for 2,5 double bonds into 3,5 form isomerization in a range of enoyl-CoA species (probable). Also able to isomerize both 3-cis and 3-trans double bonds into the 2-trans form in a range of enoyl-CoA species (by similarity). With HSD17B4, catalyzes the hydration of trans-2-enoyl-CoA and the dehydrogenation of 3-hydroxyacyl-CoA, but with opposite chiral specificity (PubMed15060085). Regulates the amount of medium-chain dicarboxylic fatty acids, which are essential regulators of all fatty acid oxidation pathways (by similarity). Also involved in the degradation of long-chain dicarboxylic acids through peroxisomal beta-oxidation (PubMed15060085). {ECO0000250|UniProtKBP07896, ECO0000250|UniProtKBQ9DBM2, ECO0000269|PubMed15060085, ECO0000305|PubMed15060085}.

Crot: Human Uniprot function (Human CROT): Beta-oxidation of fatty acids. The highest activity concerns the C6 to C10 chain length substrate. Converts the end product of pristanic acid beta-oxidation, 4,8-dimethylnonanoyl-CoA, to its corresponding carnitine ester.{ECO0000269|PubMed10486279}.

Acaa1a: Human Entrez Gene Summary (Human ACAA1): This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. (provided by RefSeq, Jul 2008)

Acaa1b: Human Entrez Gene Summary (Human ACAA1): This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. (provided by RefSeq, Jul 2008)

Gdf15: Human Uniprot function (Human GDF15): Regulates food intake, energy expenditure and body weight in response to metabolic and toxin-induced stresses (PubMed28953886, PubMed28846097, PubMed28846098, PubMed28846099, PubMed23468844, PubMed29046435). Binds to its receptor, GFRAL, and activates GFRAL-expressing neurons localized in the area postrema and nucleus tractus solitarius of the brainstem (PubMed28953886, PubMed28846097, PubMed28846098, PubMed28846099). It then triggers the activation of neurons localized within the parabrachial nucleus and central amygdala, which constitutes part of the “emergency circuit” that shapes feeding responses to stressful conditions (PubMed28953886). On hepatocytes, inhibits growth hormone signaling (by similarity).{ECO0000250|UniProtKBQ9Z0J7, ECO0000269|PubMed23468844, ECO0000269|PubMed28846097, ECO0000269|PubMed28846098, ECO0000269|PubMed28846099, ECO0000269|PubMed28953886, ECO0000269|PubMed29046435}.

Igfbp1: Human Uniprot function (Human IGFBP1): IGF-binding proteins prolong the half-life of the IGFs and have been shown to either inhibit or stimulate the growth-promoting effects of the IGFs on cell culture. They alter the interaction of IGFs with their cell surface receptors. Promotes cell migration.{ECO0000269|PubMed15972819}.

Etfdh: Human Uniprot function (Human ETFDH): Accepts electrons from ETF and reduces ubiquinone.

Cyp2b1: Human Uniprot function (Human CYP2B6): A cytochrome P450 monooxygenase involved in the metabolism of endocannabinoids and steroids (PubMed21289075, PubMed12865317). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH–hemoprotein reductase). Catalyzes the epoxidation of double bonds of arachidonoylethanolamide (anandamide) to 8,9-, 11,12-, and 14,15-epoxyeicosatrienoic acid ethanolamides (EpETrE-Eas), potentially modulating endocannabinoid system signaling (PubMed21289075). Hydroxylates steroid hormones, including testosterone at C-16 and estrogens at C-2 (PubMed21289075, PubMed12865317). Plays a role in the oxidative metabolism of xenobiotics, including plant lipids and drugs (PubMed11695850, PubMed22909231). Acts as a 1,4-cineole 2-exo-monooxygenase (PubMed11695850).{ECO0000269|PubMed11695850, ECO0000269|PubMed12865317, ECO0000269|PubMed21289075, ECO0000269|PubMed22909231}. FUNCTION Allele 2B6*9: Has low affinity for anandamide and can only produce 11,12 EpETrE-Eas.{ECO0000269|PubMed21289075}.

LOC108348266/Cyp2b1: Human Uniprot function (Human CYP2B6): A cytochrome P450 monooxygenase involved in the metabolism of endocannabinoids and steroids (PubMed21289075, PubMed12865317). Mechanistically, uses molecular oxygen inserting one oxygen atom into a substrate, and reducing the second into a water molecule, with two electrons provided by NADPH via cytochrome P450 reductase (NADPH–hemoprotein reductase). Catalyzes the epoxidation of double bonds of arachidonoylethanolamide (anandamide) to 8,9-, 11,12-, and 14,15-epoxyeicosatrienoic acid ethanolamides (EpETrE-Eas), potentially modulating endocannabinoid system signaling (PubMed21289075). Hydroxylates steroid hormones, including testosterone at C-16 and estrogens at C-2 (PubMed21289075, PubMed12865317). Plays a role in the oxidative metabolism of xenobiotics, including plant lipids and drugs (PubMed11695850, PubMed22909231). Acts as a 1,4-cineole 2-exo-monooxygenase (PubMed11695850) {ECO0000269|PubMed11695850, ECO0000269|PubMed12865317, ECO0000269|PubMed21289075, ECO0000269|PubMed22909231}. FUNCTION Allele 2B6*9: Has low affinity for anandamide and can only produce 11,12 EpETrE-Eas.{ECO0000269|PubMed21289075}.

Dhrs7: Human Entrez Gene Summary (Human DHRS7): This gene encodes a member of the short-chain dehydrogenases/reductases (SDR) family, which has over 46,000 members. Members in this family are enzymes that metabolize many different compounds, such as steroid hormones, prostaglandins, retinoids, lipids, and xenobiotics. (provided by RefSeq, Apr 2016)

Dhrs7l1: Human Entrez Gene Summary (Human DHRS7): This gene encodes a member of the SDR family, which has over 46,000 members. Members in this family are enzymes that metabolize many different compounds, such as steroid hormones, prostaglandins, retinoids, lipids, and xenobiotics. (provided by RefSeq, Apr 2016)

Slc27a2: Human Uniprot function (Human SLC27A2): Acyl-CoA synthetase that activates long-chain and very long-chain fatty acids (VLCFAs) by catalyzing the formation of fatty acyl-CoA (PubMed10198260, PubMed10749848, PubMed11980911). Can also activate branched-chain fatty acids such as phytanic acid and pristanic acid (PubMed10198260). Does not activate C24 bile acids, cholate, and chenodeoxycholate (PubMed11980911). In vitro, activates 3-alpha,7-alpha,12-alpha-trihydroxy-5-beta-cholestanate (THCA), the C27 precursor of cholic acid deriving from the de novo synthesis from cholesterol (PubMed11980911). Exhibits long-chain fatty acids (LCFAs) transport activity and plays an important role in hepatic fatty acid uptake (PubMed20530735).{ECO0000269|PubMed10198260, ECO0000269|PubMed10749848, ECO0000269|PubMed11980911, ECO0000269|PubMed20530735}. FUNCTION [Isoform 1]: Exhibits both LCFAs transport activity and acyl-CoA synthetase toward VLCFAs (PubMed21768100). Shows a preference for generating CoA derivatives of n-3 fatty acids, which are preferentially trafficked into phosphatidylinositol (PubMed21768100).{ECO0000269|PubMed21768100}. FUNCTION [Isoform 2]: Exhibits LCFAs transport activity but lacks acyl-CoA synthetase toward VLCFAs.{ECO0000269|PubMed21768100}.

Vnn1: Human Uniprot function (Human VNN1): Amidohydrolase that hydrolyzes one of the carboamide linkages specifically in D-pantetheine thus recycling pantothenic acid (vitamin B5) and releasing cysteamine.{ECO0000269|PubMed10567687, ECO0000269|PubMed11491533, ECO0000269|PubMed25478849}.

Table 12 Top 10 Kidney Genes Ranked by Potency of Perturbation, Sorted by Benchmark Dose Median^a^

Gene Symbol | Entrez Gene IDs | Probe IDs^b^ | BMD_1Std_ (BMD_L1std_–BMD_U1std_) in mg/kg | Maximum Fold Change | Direction of Expression Change
Male
Decr1 | 117543 | DECR1_8458 | 0.680 (0.505–1.264) | 3.1 | UP
Vnn1 | 29142 | VNN1_10157 | 0.705 (0.488–1.353) | 6.0 | UP
Acmsd | 171385 | ACMSD_32377 | 0.775 (0.183–4.177) | 2.3 | DOWN
Hmgcs2 | 24450 | HMGCS2_8812 | 0.804 (0.541–1.442) | 11.8 | UP
Ehhadh | 171142 | EHHADH_8534 | 0.953 (0.671–1.585) | 8.7 | UP
Eci2 | 291075 | ECI2_8521 | 0.989 (0.643–1.915) | 2.1 | UP
Acaa2 | 170465 | ACAA2_7955 | 1.346 (0.539–4.058) | 2.8 | UP
Acot1 | 50559 | ACOT1_7968 | 1.363 (0.938–2.405) | 2.2 | UP
Cyp4a1 | 50549 | CYP4A1_33111 | 1.593 (1.021–3.028) | 4.5 | UP
Ech1 | 64526 | ECH1_8516 | 2.055 (1.124–4.620) | 2.2 | UP
Female
Plod3 | 288583 | PLOD3_9507 | <0.050^c^ (NR) | 2.1 | UP
Eci1 | 29740 | ECI1_8520 | 9.486 (7.353–12.810) | 4.4 | UP
Vnn1 | 29142 | VNN1_10157 | 10.025 (7.993–13.110) | 7.8 | UP
Hmgcs2 | 24450 | HMGCS2_8812 | 11.644 (9.266–15.267) | 37.7 | UP
Ehhadh | 171142 | EHHADH_8534 | 12.212 (9.437–16.563) | 6.7 | UP
Eci2 | 291075 | ECI2_8521 | 12.789 (9.488–18.156) | 2.0 | UP
Acaa1a | 24157 | ACAA1A_7954 | 13.850 (11.009–18.172) | 5.2 | UP
Acaa1b | 501072 | ACAA1A_7954 | 13.850 (11.009–18.172) | 5.2 | UP
Ech1 | 64526 | ECH1_8516 | 19.820 (14.141–29.396) | 2.1 | UP
Acaa2 | 170465 | ACAA2_7955 | 22.339 (13.614–38.665) | 2.3 | UP

BMD_1Std_ = benchmark dose corresponding to a benchmark response set to one standard deviation from the mean; BMD_L1Std_ = benchmark dose lower confidence limit corresponding to a benchmark response set to one standard deviation from the mean; BMD_U1Std_ = benchmark dose upper confidence limit corresponding to a benchmark response set to one standard deviation from the mean; NR = the BMD_L1Std_–BMD_U1Std_ range is not reportable because the BMD_1Std_ median is below the lower limit of extrapolation (<1/3 of the lowest nonzero dose tested).

^a^ Descriptions of orthologous human genes are shown due to the increased detail available in public resources such as UniprotKB^32^ and Entrez Gene.^33^ Gene definitions adapted from Human UniprotKB were used as the primary resource due to the greater breadth of annotation and depth of functional detail provided. Gene definitions adapted from Rat UniprotKB were used as the secondary resource if the primary source did not provide a detailed description of function. Human Entrez Gene was used as the third resource. Rat Entrez Gene was used as the fourth resource.

^b^ In some cases, a probe may map to more than one gene, resulting in duplicate reporting of that probe mapped to different genes.

^c^ <0.050 = a best-fit model was identified and a BMD_1Std_ was estimated that was <1/3 of the lowest nonzero dose tested.

Gene definition version: https://doi.org/10.22427/NTP-DATA-002-00600-0002-000-0.

Decr1: Human Uniprot function (Human DECR1): Auxiliary enzyme of beta-oxidation. It participates in the metabolism of unsaturated fatty enoyl-CoA esters having double bonds in both even- and odd-numbered positions in mitochondria. Catalyzes the NADP-dependent reduction of 2,4-dienoyl-CoA to yield trans-3-enoyl-CoA.{ECO0000269|PubMed15531764}.

Vnn1: Human Uniprot function (Human VNN1): Amidohydrolase that hydrolyzes one of the carboamide linkages specifically in D-pantetheine thus recycling pantothenic acid (vitamin B5) and releasing cysteamine.{ECO0000269|PubMed10567687, ECO0000269|PubMed11491533, ECO0000269|PubMed25478849}.

Acmsd: Human Uniprot function (Human ACMSD): Converts alpha-amino-beta-carboxymuconate-epsilon-semialdehyde (ACMS) to alpha-aminomuconate semialdehyde (AMS). ACMS can be converted nonenzymatically to quinolate, a key precursor of NAD, and a potent endogenous excitotoxin of neuronal cells, which is implicated in the pathogenesis of various neurodegenerative disorders. In the presence of ACMSD, ACMS is converted to AMS, a benign catabolite. ACMSD ultimately controls the metabolic fate of tryptophan catabolism along the kynurenine pathway.{ECO0000269|PubMed19843166}.

Hmgcs2: Human Uniprot function (Human HMGCS2): Catalyzes the first irreversible step in ketogenesis, condensing acetyl-CoA to acetoacetyl-CoA to form HMG-CoA, which is converted by HMG-CoA reductase (HMGCR) into mevalonate.{ECO0000269|PubMed11228257, ECO0000269|PubMed23751782, ECO0000269|PubMed29597274}.

Ehhadh: Human Uniprot function (Human EHHADH): Peroxisomal trifunctional enzyme possessing 2-enoyl-CoA hydratase, 3-hydroxyacyl-CoA dehydrogenase, and delta 3, delta 2-enoyl-CoA isomerase activities. Catalyzes two of the four reactions of the long straight-chain fatty acids peroxisomal beta-oxidation pathway. Optimal isomerase for 2,5 double bonds into 3,5 form isomerization in a range of enoyl-CoA species (probable). Also able to isomerize both 3-cis and 3-trans double bonds into the 2-trans form in a range of enoyl-CoA species (by similarity). With HSD17B4, catalyzes the hydration of trans-2-enoyl-CoA and the dehydrogenation of 3-hydroxyacyl-CoA, but with opposite chiral specificity (PubMed15060085). Regulates the amount of medium-chain dicarboxylic fatty acids, which are essential regulators of all fatty acid oxidation pathways (by similarity). Also involved in the degradation of long-chain dicarboxylic acids through peroxisomal beta-oxidation (PubMed15060085). {ECO0000250|UniProtKBP07896, ECO0000250|UniProtKBQ9DBM2, ECO0000269|PubMed15060085, ECO0000305|PubMed15060085}.

Eci2: Human Uniprot function (Human ECI2): Able to isomerize both 3-cis and 3-trans double bonds into the 2-trans form in a range of enoyl-CoA species. Has a preference for 3-trans substrates.{ECO0000269|PubMed10419495}.

Acaa2: Human Uniprot function (Human ACAA2): In the production of energy from fats, this is one of the enzymes that catalyzes the last step of the mitochondrial beta-oxidation pathway, an aerobic process breaking down fatty acids into acetyl-CoA (probable). Using free coenzyme A/CoA, catalyzes the thiolytic cleavage of medium- to long-chain unbranched 3-oxoacyl-CoAs into acetyl-CoA and a fatty acyl-CoA shortened by two carbon atoms (probable). Also catalyzes the condensation of two acetyl-CoA molecules into acetoacetyl-CoA and could be involved in the production of ketone bodies (probable). Also displays hydrolase activity on various fatty acyl-CoAs (PubMed25478839); therefore, could be responsible for the production of acetate in a side reaction to beta-oxidation (probable). Abolishes BNIP3-mediated apoptosis and mitochondrial damage (PubMed18371312).{ECO0000269|PubMed18371312, ECO0000269|PubMed25478839, ECO0000305|PubMed25478839}.

Acot1: Human Uniprot function (Human ACOT1): Acyl-CoA thioesterases are a group of enzymes that catalyze the hydrolysis of acyl-CoAs into free fatty acids and coenzyme A (CoASH), regulating intracellular levels of acyl-CoAs, free fatty acids, and CoASH. More active toward saturated and unsaturated long-chain fatty acyl-CoAs (C12-C20) {ECO0000269|PubMed16940157}.

Cyp4a1: Human Uniprot function (Human CYP4A22): Catalyzes the omega- and (omega-1)-hydroxylation of various fatty acids such as laurate and palmitate. Shows no activity toward arachidonic acid and prostaglandin A1. Lacks functional activity in the kidney and does not contribute to renal 20-hydroxyeicosatetraenoic acid (20-HETE) biosynthesis {ECO0000269|PubMed10860550, ECO0000269|PubMed15611369}.

Ech1: Human Uniprot function (Human ECH1): Isomerization of 3-trans,5-cis-dienoyl-CoA to 2-trans,4-trans-dienoyl-CoA.{ECO0000250|UniProtKBQ62651}.

Plod3: Human Uniprot function (Human PLOD3): Multifunctional enzyme that catalyzes a series of essential post-translational modifications on Lys residues in procollagen (PubMed11956192, PubMed12475640, PubMed18298658, PubMed30089812, PubMed18834968). Plays a redundant role in catalyzing the formation of hydroxylysine residues in -Xaa-Lys-Gly- sequences in collagens (PubMed9582318, PubMed9724729, PubMed11956192, PubMed12475640, PubMed18298658, PubMed30089812, PubMed18834968). Plays a redundant role in catalyzing the transfer of galactose onto hydroxylysine groups, giving rise to galactosyl 5-hydroxylysine (PubMed12475640, PubMed18298658, PubMed30089812, PubMed18834968). Has an essential role by catalyzing the subsequent transfer of glucose moieties, giving rise to 1,2-glucosylgalactosyl-5-hydroxylysine residues (PubMed10934207, PubMed11896059, PubMed11956192, PubMed12475640, PubMed18298658, PubMed30089812, PubMed18834968). Catalyzes hydroxylation and glycosylation of Lys residues in the MBL1 collagen-like domain, giving rise to hydroxylysine and 1,2-glucosylgalactosyl-5-hydroxylysine residues (PubMed25419660). Essential for normal biosynthesis and secretion of type IV collagens (PubMed18834968) (probable). Essential for normal formation of basement membranes (by similarity).{ECO0000250|UniProtKBQ9R0E1, ECO0000269|PubMed10934207, ECO0000269|PubMed11896059, ECO0000269|PubMed11956192, ECO0000269|PubMed12475640, ECO0000269|PubMed18298658, ECO0000269|PubMed18834968, ECO0000269|PubMed25419660, ECO0000269|PubMed30089812, ECO0000269|PubMed9582318, ECO0000269|PubMed9724729}.

Eci1: Human Uniprot function (Human ECI1): Able to isomerize both 3-cis and 3-trans double bonds into the 2-trans form in a range of enoyl-CoA species.{ECO0000269|PubMed7818490}.

Acaa1a: Human Entrez Gene Summary (Human ACAA1): This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. (provided by RefSeq, Jul 2008)

Acaa1b: Human Entrez Gene Summary (Human ACAA1): This gene encodes an enzyme operative in the beta-oxidation system of the peroxisomes. Deficiency of this enzyme leads to pseudo-Zellweger syndrome. Alternative splicing results in multiple transcript variants. (provided by RefSeq, Jul 2008)

No liver genes in male or female rats had estimated BMD median values <0.050 mg/kg. In male rats, the most sensitive upregulated genes with a calculated BMD were Acot2 (acyl-CoA thioesterase 2), Eci1 (enoyl-CoA delta isomerase 1), Loc100911558/Spink1l (serine peptidase inhibitor, Kazal type 1-like), Spink1 (serine peptidase inhibitor, Kazal type 1), Ehhadh (enoyl-CoA hydratase and 3-hydroxyacyl CoA dehydrogenase), Crot (carnitine O-octanoyltransferase), Acaa1a (acetyl-CoA acyltransferase 1A), and Acaa1b (acetyl-Coenzyme A acyltransferase 1B) with BMDs (BMD_L_s) of 1.012 (0.809), 1.013 (0.769), 1.270 (0.542), 1.270 (0.542), 1.280 (1.047), 1.411 (1.092), 1.874 (1.524), and 1.874 (1.524) mg/kg, respectively. The most sensitive genes exhibiting a decrease in expression were Myc (MYC proto-oncogene, bHLH transcription factor) and Zfp36 (zinc-finger protein 36) with BMDs (BMD_L_s) of 0.186 (0.103) and 0.368 (0.097) mg/kg, respectively.

In female rats, all 10 of the most sensitive liver genes were upregulated. These genes were Gdf15 (growth differentiation factor 15), Igfbp1 (insulin-like growth factor-binding protein 1), Eci1 (enoyl-CoA delta isomerase 1), Etfdh (electron transfer flavoprotein dehydrogenase), Cyp2b1 (cytochrome P450, family 2, subfamily b, polypeptide 1), Loc108348266/Cyp2b1 (cytochrome P450 2B1), Dhrs7 (dehydrogenase/reductase 7), Dhrs7l1 (dehydrogenase/reductase [SDR family] member 7-like 1), Slc27a2 (solute carrier family 27 member 2), and Vnn1 (vanin 1) with BMDs (BMD_L_s) of 17.724 (8.696), 18.792 (7.230), 32.546 (27.162), 34.846 (26.297), 35.483 (29.479), 35.483 (29.479), 35.986 (10.630), 35.986 (10.630), 36.103 (26.571), and 37.026 (30.688) mg/kg, respectively.

None of the top 10 most sensitive kidney genes in male rats had estimated BMD median values <0.050 mg/kg. The most sensitive upregulated genes with a calculated BMD were Decr1 (2,4-dienoyl-CoA reductase 1), Vnn1 (vanin 1), Hmgcs2 (3-hydroxy-3-methylglutaryl-CoA synthase 2), Ehhadh (enoyl-CoA hydratase and 3-hydroxyacyl CoA dehydrogenase), Eci2 (enoyl-CoA delta isomerase 2), Acaa2 (acetyl-CoA acyltransferase 2), Acot1 (acyl-CoA thioesterase 1), Cyp4a1 (cytochrome P450, family 4, subfamily a, polypeptide 1), and Ech1 (enoyl-CoA hydratase 1) with BMDs (BMD_L_s) of 0.680 (0.505), 0.705 (0.488), 0.804 (0.541), 0.953 (0.671), 0.989 (0.643), 1.346 (0.539), 1.363 (0.938), 1.593 (1.021), and 2.055 (1.124) mg/kg, respectively. One gene, Acmsd (aminocarboxymuconate semialdehyde decarboxylase), was downregulated with a BMD (BMD_L_) of 0.775 (0.183) mg/kg.

The most sensitive kidney gene in female rats, exhibiting an increase in expression, was Plod3 (procollagen-lysine, 2-oxoglutarate 5-dioxygenase 3) with an estimated BMD median value <0.050 mg/kg. The most sensitive upregulated genes with a calculated BMD were Eci1 (enoyl-CoA delta isomerase 1), Vnn1 (vanin 1), Hmgcs2 (3-hydroxy-3-methylglutaryl-CoA synthase 2), Ehhadh (enoyl-CoA hydratase and 3-hydroxyacyl CoA dehydrogenase), Eci2 (enoyl-CoA delta isomerase 2), Acaa1a (acetyl-CoA acyltransferase 1A), Acaa1b (acetyl-Coenzyme A acyltransferase 1B), Ech1 (enoyl-CoA hydratase 1), and Acaa2 (acetyl-CoA acyltransferase 2) with BMDs (BMD_L_s) of 9.486 (7.353), 10.025 (7.993), 11.644 (9.266), 12.212 (9.437), 12.789 (9.488), 13.850 (11.009), 13.850 (11.009), 19.820 (14.141), and 22.339 (13.614) mg/kg, respectively. None of the top 10 most sensitive kidney genes in female rats were downregulated.