# Background

6:1 Fluorotelomer alcohol (6:1 FTOH) (CASRN: 375-82-6, U.S. Environmental Protection Agency [EPA] Chemical Dashboard: DTXSID00190950,^1^ PubChem CID: 550386,^2^ European Committee Number: 206-796-8^3^) is a member of the per- and polyfluoroalkyl class of compounds that are associated with numerous toxicological effects.^4^ There is widespread human exposure to this class of compounds.^5,6^ The predicted upper 95th percentile human exposure to 6:1 FTOH is 0.0000806 mg/kg body weight/day.^7^ A review of the existing literature failed to identify any in vivo toxicological information on 6:1 FTOH, and according to the EPA Chemical Dashboard, no quantitative risk assessment values or quantitative hazard values exist for this test article.^8^ Publicly available information on 6:1 FTOH can be found in PubChem^2^ and the EPA Chemical Dashboard.^1^

Recent studies have demonstrated that short-term in vivo gavage studies coupled with transcriptomics on select target organs can be used to estimate a biological potency that provides a reasonable approximation of toxicological potency in long-term guideline toxicological assessments.^9^ To estimate biological potency and gain insight into the nature of biological changes elicited by 6:1 FTOH, the National Institute of Environmental Health Sciences performed a short-term in vivo biological potency study of male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. The results of this study are presented in this report.