# Appendix C Transcriptomic Quality Control and Empirical False Discovery Rate

## C.1 Gene Expression Quality Control

Figure C-1

A Principal Component Analysis of the Normalized Data from the Liver of Male Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each dose group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than dose-related changes, which indicates any technical batch-related effects are minimal.

Figure C-2

A Principal Component Analysis of the Normalized Data from the Liver of Female Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each dose group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than dose-related changes, which indicates any technical batch-related effects are minimal.

Figure C-3

A Principal Component Analysis of the Normalized Data from the Kidney of Male Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each dose group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than dose-related changes, which indicates any technical batch-related effects are minimal.

Figure C-4

A Principal Component Analysis of the Normalized Data from the Kidney of Female Rats

A principal component analysis (PCA) plot enables visualization of global transcriptional changes in two dimensions, with each plot showing a different angle on the basis of the principal components plotted. Global transcript data are shown for individual animals (dots) within each dose group (designated by color). Dots that are spatially closer to each other indicate more similarity in global expression profiles; dots that are farther apart indicate dissimilarity in global expression profiles for those animals. The data represented in the plot are those employed in dose response modeling (i.e., if outliers were identified in the quality control process, they were removed from the data set and are not present in the plot). Visual inspection does not suggest subgrouping of the data other than dose-related changes, which indicates any technical batch-related effects are minimal.

## C.2 Empirical False Discovery Rate

### C.2.1 Methods

Empirical false discovery assessment was performed to evaluate the performance of the benchmark dose (BMD) analysis technique and underlining probe/pathway filtering criteria. Toward this goal, 20 computationally generated data sets were used with this study design (each data set containing 10 vehicle control replicates and 5 replicates per dose), and equivalent BMD analysis was performed using the same parameter configurations. The 20 data sets were generated from the original 6:1 fluorotelomer alcohol (6:1 FTOH) study data, along with data from three other chemicals that were studied in parallel under a similar protocol.^26-28^

For a given group (tissue per sex combination), up to 40 vehicle control samples from the original studies (10 replicates × 4 chemicals) were used for this analysis. The previously identified outlier vehicle control samples and overflow plate control samples exhibiting a batch effect were excluded from this analysis.

Each computationally generated sample was created by randomly mixing the normalized expression signal from two randomly selected vehicle control samples using a weighted average approach. The weights utilized during per-probe mixing were randomly simulated from uniform (0,1) distribution. A total of 55 samples (10 vehicle control samples + 45 dosed samples [9 doses × 5 replicates]) were computationally generated per data set and assigned to either vehicle control or 1 of the 9 dosed groups that were separated by approximately half-log spacing, consistent with the dose spacing used in the original studies. For each group, 20 such data sets were generated. Because each of the 20 generated data sets used in the empirical false discovery analysis was derived from actual vehicle control samples, none of the data sets should have any true dose-responsive genes.

Each data set was then analyzed using the same parameter settings and significance criteria that were implemented in the original study. At the gene level, genes that passed the following criteria were considered false positive discoveries: fold change ≥|2|, Williams’s trend p value ≤0.05, global goodness-of-fit p value >0.1, BMD upper confidence limit/BMD lower confidence limit (BMD_U_/BMD_L_) ≤40, and BMD <highest dose tested. Categorical analysis on Gene Ontology (GO) gene sets was performed using the genes that passed the gene-level criteria with maximum absolute fold change ≥1.5. At the gene set GO level, GO biological processes that passed the following criteria were considered false positive discoveries: ≥3 genes that pass all filters, totaling at least 5% of the genes in a gene set.

False positive discovery rates were assessed for each computationally generated data set using the following equations:

False Positive Gene Rate = (# False Positive Entrez Gene IDs)/(2 , 680) × 100 (1)

False Positive GO Biological Process Rate = (# False Positive GO Biological Processes)/(5 , 667) × 100 (2)

where 2,680 is the number of unique Entrez Gene IDs on the rat S1500+ platform and 5,667 is the number of GO biological processes that have at least three genes in rat S1500+.

Mean and median false discovery rates across all 20 computationally generated data sets were calculated for each tissue per sex in the study.

### C.2.2 Results

The number of false positives for genes and GO biological processes are given in Table C-1. Mean and median false positive rates were <0.1% for genes and <0.5% for GO biological processes for all tissue per sex group (Figure C-5 and Figure C-6). The maximum false positive rates for any of the 80 computationally generated control data sets were 0.3% (gene) and 4.4% (GO biological process).

Figure C-5

Boxplots of the False Positive Gene Rate for Each Tissue per Sex Combination

Each boxplot displays the distribution of the false positive rates for 20 computationally generated data sets.

Figure C-6

Boxplots of the False Positive Gene Ontology Biological Process Rate for Each Tissue per Sex Combination

Each boxplot displays the distribution of the false positive rates for 20 computationally generated data sets.

Table C-1 Number of False Positives

Generated Data Set | # False Positive Genes | | | | # False Positive GO Biological Process
Generated Data Set | Kidney Female | Kidney Male | Liver Female | Liver Male | Kidney Female | Kidney Male | Liver Female | Liver Male
01 | 3 | 0 | 0 | 0 | 0 | 0 | 0 | 0
02 | 4 | 0 | 0 | 0 | 2 | 1 | 0 | 0
03 | 0 | 2 | 0 | 0 | 0 | 1 | 1 | 0
04 | 2 | 1 | 0 | 0 | 0 | 0 | 0 | 0
05 | 2 | 3 | 0 | 0 | 0 | 0 | 0 | 0
06 | 1 | 0 | 0 | 3 | 0 | 0 | 1 | 0
07 | 1 | 6 | 0 | 0 | 0 | 18 | 0 | 0
08 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
09 | 3 | 0 | 0 | 0 | 0 | 0 | 0 | 0
10 | 0 | 0 | 0 | 0 | 0 | 0 | 0 | 0
11 | 0 | 1 | 0 | 1 | 0 | 0 | 0 | 0
12 | 1 | 4 | 0 | 3 | 1 | 147 | 0 | 0
13 | 0 | 2 | 0 | 0 | 0 | 2 | 0 | 0
14 | 1 | 0 | 0 | 2 | 0 | 0 | 0 | 0
15 | 0 | 3 | 0 | 0 | 0 | 2 | 0 | 0
16 | 0 | 1 | 1 | 0 | 0 | 0 | 0 | 0
17 | 0 | 0 | 1 | 0 | 0 | 0 | 0 | 0
18 | 0 | 2 | 0 | 0 | 0 | 0 | 0 | 0
19 | 1 | 0 | 0 | 1 | 0 | 0 | 0 | 0
20 | 8 | 7 | 0 | 0 | 5 | 248 | 0 | 0

GO = Gene Ontology.