# Appendix B Animal Identifiers

Table B-1 Animal Numbers and FASTQ Data File Names

Animal Number | Sex | Group | Dose (mg/kg) | Survived to Study Termination | Tissue | FASTQ File ID
321 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-321
321 | Male | Vehicle control | 0 | Yes | Liver | Plate2-321
322 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-322
322 | Male | Vehicle control | 0 | Yes | Liver | Plate2-322
323 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-323
323 | Male | Vehicle control | 0 | Yes | Liver | Plate2-323
324 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-324
324 | Male | Vehicle control | 0 | Yes | Liver | Plate2-324
325 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-325
325 | Male | Vehicle control | 0 | Yes | Liver | Plate2-325
326 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-326
326 | Male | Vehicle control | 0 | Yes | Liver | Plate2-326
327 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-327
327 | Male | Vehicle control | 0 | Yes | Liver | Plate4-327
328 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-328
328 | Male | Vehicle control | 0 | Yes | Liver | Plate2-328
329 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-329
329 | Male | Vehicle control | 0 | Yes | Liver | Plate2-329
330 | Male | Vehicle control | 0 | Yes | Kidney | Plate6-330
330 | Male | Vehicle control | 0 | Yes | Liver | Plate2-330
331 | Female | Vehicle control | 0 | Yes | Kidney | Plate6-331
331 | Female | Vehicle control | 0 | Yes | Liver | Plate2-331
332 | Female | Vehicle control | 0 | Yes | Kidney | Plate6-332
332 | Female | Vehicle control | 0 | Yes | Liver | Plate2-332
333 | Female | Vehicle control | 0 | Yes | Kidney | Plate6-333
333 | Female | Vehicle control | 0 | Yes | Liver | Plate2-333
334 | Female | Vehicle control | 0 | Yes | Kidney | Plate8-334^a^
334 | Female | Vehicle control | 0 | Yes | Liver | Plate4-334
335 | Female | Vehicle control | 0 | Yes | Kidney | Plate8-335^a^
335 | Female | Vehicle control | 0 | Yes | Liver | Plate4-335
336 | Female | Vehicle control | 0 | Yes | Kidney | Plate6-336
336 | Female | Vehicle control | 0 | Yes | Liver | Plate2-336
337 | Female | Vehicle control | 0 | Yes | Kidney | Plate6-337
337 | Female | Vehicle control | 0 | Yes | Liver | Plate2-337
338 | Female | Vehicle control | 0 | Yes | Kidney | Plate6-338
338 | Female | Vehicle control | 0 | Yes | Liver | Plate2-338
339 | Female | Vehicle control | 0 | Yes | Kidney | Plate6-339
339 | Female | Vehicle control | 0 | Yes | Liver | Plate4-339
340 | Female | Vehicle control | 0 | Yes | Kidney | Plate6-340
340 | Female | Vehicle control | 0 | Yes | Liver | Plate2-340
341 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-341
341 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-341
342 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-342
342 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-342
343 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-343
343 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-343
344 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-344
344 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-344
345 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-345
345 | Male | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-345
346 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-346
346 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-346
347 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-347
347 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-347
348 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate8-348^a^
348 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-348
349 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-349
349 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate2-349
350 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Kidney | Plate6-350
350 | Female | 6:1 Fluorotelomer alcohol | 0.15 | Yes | Liver | Plate4-350
351 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate6-351
351 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-351
352 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate6-352
352 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-352
353 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate6-353
353 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-353
354 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate6-354
354 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-354
355 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate6-355
355 | Male | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-355
356 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate8-356^a^
356 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-356
357 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate8-357^a^
357 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-357
358 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate6-358
358 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-358
359 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate8-359^a^
359 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate4-359
360 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Kidney | Plate6-360
360 | Female | 6:1 Fluorotelomer alcohol | 0.5 | Yes | Liver | Plate2-360
361 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-361
361 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-361
362 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-362
362 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-362
363 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate8-363^a^
363 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-363
364 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-364
364 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-364
365 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-365
365 | Male | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-365
366 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-366
366 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-366
367 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-367
367 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-367
368 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-368
368 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-368
369 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-369
369 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate2-369
370 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Kidney | Plate6-370
370 | Female | 6:1 Fluorotelomer alcohol | 1.4 | Yes | Liver | Plate4-370
371 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate8-371^a^
371 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-371
372 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate6-372
372 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-372
373 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate6-373
373 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-373
374 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate6-374
374 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-374
375 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate8-375^a^
375 | Male | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-375
376 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate6-376
376 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-376
377 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate6-377
377 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate4-377
378 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate6-378
378 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-378^b^
379 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate6-379
379 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-379
380 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Kidney | Plate6-380
380 | Female | 6:1 Fluorotelomer alcohol | 4.0 | Yes | Liver | Plate2-380
381 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-381
381 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate2-381
382 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-382
382 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate2-382
383 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-383
383 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate4-383
384 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-384
384 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate2-384
385 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-385
385 | Male | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate2-385
386 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-386
386 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate2-386
387 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-387
387 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate2-387
388 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-388
388 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate2-388
389 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-389
389 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate2-389
390 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Kidney | Plate6-390
390 | Female | 6:1 Fluorotelomer alcohol | 12.0 | Yes | Liver | Plate4-390
391 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate6-391
391 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate2-391
392 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate6-392
392 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate2-392
393 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate6-393
393 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate2-393
394 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate6-394
394 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate2-394
395 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate8-395^a^
395 | Male | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate4-395
396 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate8-396^c^
396 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate2-396
397 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate6-397
397 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate2-397
398 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate6-398
398 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate2-398
399 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate6-399
399 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate4-399
400 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Kidney | Plate6-400
400 | Female | 6:1 Fluorotelomer alcohol | 37.0 | Yes | Liver | Plate2-400
401 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-401
401 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate4-401
402 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-402
402 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-402
403 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-403
403 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-403
404 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-404
404 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-404
405 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-405
405 | Male | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-405
406 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-406
406 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-406
407 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-407
407 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-407
408 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-408
408 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-408
409 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate8-409^a^
409 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-409
410 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Kidney | Plate6-410
410 | Female | 6:1 Fluorotelomer alcohol | 111.0 | Yes | Liver | Plate2-410
411 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate6-411
411 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate2-411
412 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate8-412^a^
412 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate2-412
413 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate6-413
413 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate2-413^b^
414 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate6-414
414 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate4-414
415 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate6-415
415 | Male | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate4-415
416 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate6-416
416 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate2-416
417 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate6-417
417 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate2-417
418 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate8-418^a^
418 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate2-418
419 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate8-419^a^
419 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate2-419
420 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Kidney | Plate6-420
420 | Female | 6:1 Fluorotelomer alcohol | 333.0 | Yes | Liver | Plate2-420
421 | Male | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Kidney | Plate8-421^a^
421 | Male | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Liver | Plate2-421^b^
422 | Male | 6:1 Fluorotelomer alcohol | 1,000.0 | No | None | NA
423 | Male | 6:1 Fluorotelomer alcohol | 1,000.0 | No | None | NA
424 | Male | 6:1 Fluorotelomer alcohol | 1,000.0 | No | None | NA
425 | Male | 6:1 Fluorotelomer alcohol | 1,000.0 | No | None | NA
426 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Kidney | Plate6-426
426 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Liver | Plate2-426
427 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Kidney | Plate6-427
427 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Liver | Plate2-427
428 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Kidney | Plate6-428
428 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Liver | Plate2-428
429 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Kidney | Plate6-429
429 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Liver | Plate4-429
430 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Kidney | Plate6-430
430 | Female | 6:1 Fluorotelomer alcohol | 1,000.0 | Yes | Liver | Plate2-430

NA = no transcriptomics data collected for selected animal.

^a^ Removed due to plate/batch effect.

^b^ Removed due to principal component analysis/hierarchical cluster analysis outlier.

^c^ Removed due to quality control fail.