# Appendix A Internal Dose Assessment

## A.1 Quantitation of 6:1 Fluorotelomer Alcohol in Plasma

Quantification of 6:1 fluorotelomer alcohol (6:1 FTOH) in plasma samples was completed by MRIGlobal (Kansas City, MO). A high-performance liquid chromatography-tandem mass spectrometry (LC-MS/MS) method was developed to determine 6:1 FTOH concentrations in rat plasma. A six-point matrix calibration curve, in the range of 10–160 ng/mL, was prepared by adding 10 μL of an appropriate spiking solution of 6:1 FTOH in methanol to 50 μL of control matrix (adult male Sprague Dawley rat plasma). Quality control (QC) samples were prepared similarly at a target concentration of 50 ng/mL in plasma. Blanks and study samples were prepared like standards, except 10 μL of methanol was used in place of spiking solution. To each sample, 100 μL of prechilled solution containing 250 ng 2-perfluorohexyl-[1,1-2H2]-[1,2-13C2]-ethanol/mL (internal standard) in methanol was added, mixed for 1 minute, and allowed to stand at 4°C for 10 minutes. All samples were centrifuged at approximately 18,000 × g for 10 minutes and supernatants were collected for analysis.

All samples were analyzed using a Sciex Exion AC LC coupled to an API 4000 MS/MS (Framingham, MA). An Agilent Zorbax Eclipse Plus C18 column (2.1 × 150 mm, 5 µm) was used with mobile phases A (water) and B (methanol). A flow rate of 0.3 mL/min was run with a linear gradient of 80%–100% B in 4 minutes and held for 4 minutes. The electrospray ion source was operated in negative ion mode with a source temperature of 400°C and an ion spray voltage of −4,500 V. Transition ranges monitored were m/z 349 to 169 (quantitation ion) and 349 to 309 (confirmation ion) for 6:1 FTOH, and m/z 367 to 306 for the internal standard.

A linear regression with 1/X weighting was used to relate peak area ratio of analyte to internal standard and analyte concentration. Calibration curves were linear (r > 0.99). The limit of detection (LOD; 2.9 ng/mL) was estimated as three times the standard deviation of the lower limit of quantitation (LOQ; 10.0 ng/mL), expressed as concentration. For QC samples, the accuracy measured as percent relative error was within ±27.8% of the nominal concentration with relative standard deviations ≤4.7%. The concentrations (ng/mL) of 6:1 FTOH in study samples were calculated using peak area ratios and the regression equation. All values above LOD were reported.