# Publication Details

Publisher: National Institute of Environmental Health Sciences

Publishing Location: Research Triangle Park, NC

ISSN: 2768-5632

DOI: https://doi.org/10.22427/NIEHS-11

Report Series: NIEHS Report Series

Report Series Number: 11

Official citation: Panzacchi S, Belpoggi F, Bua L, Bucher JR, Cora MC, De Angelis L, Falcioni L, Gnudi F, Mandrioli D, Manservigi M, Manzoli I, Masten SA, Menghetti I, Mutlu E, Roberts GK, Shipkowski KA, Sills RC, Stout MD, Strollo V, Tibaldi E, Tracy JW, Vornoli A, Waidyanatha S. 2024. NIEHS report on the toxicity studies of nicotine bitartrate dihydrate (CASRN 6019-06-3) administered in drinking water to Sprague Dawley rats and Swiss mice. Research Triangle Park, NC: National Institute of Environmental Health Sciences. NIEHS Report 11.